# Appendix J Chemical Characterization and Dose Formulation Studies

## J.1 Procurement and Characterization

### J.1.1 Tetrabromobisphenol A

Tetrabromobisphenol A was obtained from Albemarle Corporation (Baton Rouge, LA) in three lots (25317K-1, C16263X, and 25337XX-8). Lot 25317K-1 was used during the 3-month studies; lots 25317K-1 and C16263X were combined into one lot and renamed lot M032607KA, which was used in the 2-year studies; lot 25337XX-8 was used for dose formulation development studies performed at the analytical chemistry laboratory at Midwest Research Institute (Kansas City, MO) and was not used in any of the animal studies. Identity and purity analyses were conducted by the analytical chemistry laboratory, and identity was confirmed by the study laboratory at Battelle Columbus Operations (Columbus, OH). Reports on analyses performed in support of the tetrabromobisphenol A studies are on file at the National Institute of Environmental Health Sciences.

Lots 25317K-1 and M032607KA of the test chemical, a white, crystalline powder, were identified as tetrabromobisphenol A by the analytical chemistry laboratory using infrared (IR) and proton nuclear magnetic resonance (NMR) spectroscopy; identity was confirmed by the study laboratory using IR spectroscopy. All spectra were consistent with the literature spectra^180,181^ and the structure of tetrabromobisphenol A. Representative IR and NMR spectra are presented in Figure J-1 and Figure J-2.

For lot 25317K-1 and combined lot M032607KA, the analytical chemistry laboratory determined the melting points using differential scanning calorimetry (DSC) with a Perkin-Elmer diamond differential scanning calorimeter (Perkin-Elmer, Norwalk, CT); the purity was determined using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection by system A.

1. A) The system included an HPLC instrument (Waters Corporation, Milford, MA) with UV detection, an Alltech Nucleosil C_18_ column, (250 mm × 4.6 mm, 5 μm particle size), (Alltech, Inc., Deerfield, IL), a mobile phase of A) aqueous 18 mM ammonium acetate with 0.5% acetic acid and B) acetonitrile with 0.5% acetic acid, isocratic, 30%A:70%B, UV detection at 254 and 290 nm, and a flow rate of 1.0 mL/minute.

For lot 25317K-1, the DSC results indicated high purity and were in agreement with the manufacturer’s certificate of analysis; HPLC/UV analysis indicated one major peak and one impurity detected at both 254 and 290 nm with areas of 0.7% and 0.8% relative to the total peak area, respectively. The overall purity of lot 25317K-1 was determined to be greater than 99%.

For lot M032607KA, the DSC results indicated high purity and were in agreement with the manufacturer’s certificate of analysis; HPLC/UV analysis indicated one major peak and one impurity detected at both 254 and 290 nm with areas of 0.8% and 1.1% relative to the total peak area, respectively. The impurity was determined to be tribromobisphenol A by liquid chromatography/mass spectrometry, based on the isotopic pattern in the mass spectrum indicating the presence of three bromine atoms and the m/z of 460.9 ([M-H]^−^), consistent with a mass of 461.8. However, the positions of bromination were not determined. Tribromobisphenol A is listed as an impurity in the US Patent issued to Albemarle Corporation for the manufacturing of tetrabromobisphenol A; the positions of bromination are not specified in the patent. The overall purity of lot M032607KA was determined to be approximately 99%.

To ensure stability, the bulk chemical was stored in sealed glass bottles protected from light at room temperature. Periodic reanalyses of the bulk chemical were performed by the study laboratory twice during the 3-month studies and seven times during the 2-year studies using HPLC/UV by system B. No degradation of the test chemical was detected.

1. B) The system included an HPLC UV instrument (Waters Corporation or Agilent Inc., Palo Alto, CA), a Nucleosil C_18_ column, (250 mm × 4.6 mm, 5 μm particle size) (Alltech, Inc.), a mobile phase of 70:30 acetonitrile:water (containing 0.5% acetic acid); isocratic, with UV detection at 290 nm, and a flow rate of 1.0 mL/minute.

### J.1.2 Corn Oil

National Formulary-grade corn oil was obtained in multiple lots from Spectrum Chemicals and Laboratory Products (Gardena, CA) and from Sigma-Aldrich (St. Louis, MO) and was used as the vehicle in the 3-month and 2-year studies. Periodic analyses of the corn oil vehicle performed by the study laboratory using potentiometric titration demonstrated peroxide concentrations less than the rejection level of 3 mEq/kg.

## J.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing tetrabromobisphenol A with corn oil to give the required concentrations (Table J-1). The dose formulations were prepared monthly during the 3-month studies and approximately every 6 weeks during the 2-year studies. Dose formulations were stored in sealed glass bottles for up to 42 days at room temperature.

Homogeneity studies of 0.5 and 600 mg/mL formulations and stability studies of a 0.5 mg/mL formulation were performed by the analytical chemistry laboratory using HPLC/UV by a system similar to system B, without acetic acid in the mobile phase. Homogeneity was confirmed, and stability was confirmed for at least 42 days for formulations stored in sealed glass vials, protected from light, at temperatures up to 25°C, and for at least 3 hours under simulated animal room conditions.

Prior to the 3-month studies, homogeneity studies of 1, 2, 50, 100, 200, and 400 mg/mL formulations were performed by the study laboratory using HPLC/UV by system B; gavageability studies of 200 and 400 mg/mL formulations were also performed. Homogeneity was confirmed for all of the formulations; gavageability was confirmed only for the 200 mg/mL formulation. Additional homogeneity studies were performed on 10 mg/mL dose formulations and gavageability studies on 100 and 200 mg/mL dose formulations. Homogeneity and gavageability were confirmed. Prior to the 2-year studies, homogeneity studies of 25, 50, and 100 mg/mL dose formulations were performed by the study laboratory using HPLC/UV by system B. Homogeneity was confirmed.

Periodic analyses of the dose formulations of tetrabromobisphenol A were conducted by the study laboratory using HPLC/UV by a system similar to system B. During the 3-month studies, the dose formulations were analyzed three times; all 15 of the dose formulations for rats and all 15 for mice were within 10% of the target concentrations (Table J-2). Animal room samples of these dose formulations were also analyzed; all 15 for rats and all 15 for mice were within 10% of the target concentrations. During the 2-year studies, the dose formulations were analyzed approximately every 3 months (Table J-3); of the dose formulations analyzed and used during the studies, all 72 for rats and all 45 for mice were within 10% of the target concentrations. Animal room samples were also analyzed; seven of nine animal room samples for rats and eight of nine for mice were within 10% of the target concentrations.

Table J-1 Preparation and Storage of Dose Formulations in the Gavage Studies of Tetrabromobisphenol A

Three-month Studies | Two-year Studies
Preparation
Dose formulations were prepared by adding the appropriate amount of tetrabromobisphenol A directly into a calibrated glass beaker, adding enough corn oil to wet the test article, and stirring with a spatula to form a smooth slurry. The spatula and sides of the beaker were rinsed with corn oil, diluted to the final volume with corn oil, and stirred using an overhead stirrer with a vigorous vortex for approximately 15 minutes and scraping the bottom of the beaker with a spatula. Dose formulations were prepared monthly. | Same as the 3-month studies. Dose formulations were prepared approximately every 6 weeks.
Chemical Lot Number
25317K-1 | M032607KA
Maximum Storage Time
42 days | 42 days
Storage Conditions
Stored in sealed glass bottles protected from light at room temperature. | Stored in sealed glass bottles protected from light at room temperature.
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)

Table J-2 Results of Analyses of Dose Formulations Administered to F344/NTac Rats and B6C3F1/N Mice in the Three-month Gavage Studies of Tetrabromobisphenol A

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
November 30, 2005 | December 1-2, 2005 | 2 | 1.954 | –2
| | 10 | 9.552^b^ | –5
| | 20 | 19.31 | –3
| | 100 | 96.12 | –4
| December 5-6, 2005 | 200 | 198.8^c^ | –1
| January 10-11, 2006^d^ | 2 | 1.915 | –4
| | 10 | 9.933 | –1
| | 20 | 19.60 | –2
| | 100 | 96.14 | –4
| | 200 | 199.2 | 0
January 19, 2006 | January 24-25, 2006 | 2 | 1.914 | –4
| | 10 | 9.816 | –2
| | 20 | 19.15 | –4
| | 100 | 93.12 | –7
| | 200 | 197.2 | –1
| February 27-28, 2006^d^ | 2 | 1.937 | –3
| | 10 | 9.591 | –4
| | 20 | 19.56 | –2
| | 100 | 97.30 | –3
| | 200 | 197.0 | –2
February 13, 2006 | February 14-16, 2006 | 2 | 1.918 | –4
| | 10 | 9.768 | –2
| | 20 | 19.45 | –3
| | 100 | 92.97 | –7
| | 200 | 197.7 | –1
| March 23-24, 2006^d^ | 2 | 1.890 | –6
| | 10 | 9.506 | –5
| | 20 | 19.07 | –5
| | 100 | 94.15 | –6
| | 200 | 190.5 | –5
Mice
November 30, 2005 | December 1-2, 2005 | 1 | 0.9492 | –5
| | 5 | 4.658 | –7
| | 10 | 9.552^b^ | –5
| | 50 | 48.45 | –3
| | 100 | 96.12 | –4
| January 10-11, 2006^d^ | 1 | 0.9626 | –4
| | 5 | 4.762 | –5
| | 10 | 9.906 | –1
| | 50 | 49.32 | –1
| | 100 | 97.53 | –3
January 19, 2006 | January 24-25, 2006 | 1 | 0.9433 | –6
| | 5 | 4.754 | –5
| | 10 | 9.816 | –2
| | 50 | 48.83 | –2
| | 100 | 93.12 | –7
| February 27-28, 2006^d^ | 1 | 0.9385 | –6
| | 5 | 4.756 | –5
| | 10 | 9.669 | –3
| | 50 | 48.12 | –4
| | 100 | 95.91 | –4
February 13, 2006 | February 14-16, 2006 | 1 | 0.9025 | –10
| | 5 | 4.519 | –10
| | 10 | 9.768 | –2
| | 50 | 48.46 | –3
| | 100 | 92.97 | –7
| March 23-24, 2006^d^ | 1 | 0.9655 | –4
| | 5 | 4.795 | –4
| | 10 | 9.594 | –4
| | 50 | 49.00 | –2
| | 100 | 96.53 | –3

^a^ Results of duplicate analyses. For rats, dosing volume=5 mL/kg; 2 mg/mL=10 mg/kg, 10 mg/mL=50 mg/kg, 20 mg/mL=100 mg/kg, 100 mg/mL=500 mg/kg, 200 mg/mL=1,000 mg/kg. For mice, dosing volume=10 mL/kg; 1 mg/mL=10 mg/kg, 5 mg/mL=50 mg/kg, 10 mg/mL=100 mg/kg, 50 mg/mL=500 mg/kg, and 100 mg/mL=1,000 mg/kg.

^b^ Results of twelve analyses.

^c^ Results of four analyses.

^d^ Animal room samples.

Table J-3 Results of Analyses of Dose Formulations Administered to Wistar Han Rats and B6C3F1/N Mice in the Two-year Gavage Studies of Tetrabromobisphenol A

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
July 12, 2007 | July 13, 2007 | 50 | 48.2 | –4
| | 50 | 47.7 | –5
| | 100 | 94.9 | –5
| | 100 | 93.9 | –6
| | 200 | 195 | –3
| | 200 | 192 | –4
| August 21, 2007^b^ | 50 | 47.2 | –6
| | 100 | 118 | 18
| | 200 | 195 | –3
July 19, 2007 | July 23, 2007 | 200 | 191 | –5
| | 200 | 198 | –1
October 9, 2007 | October 10, 2007 | 50 | 50.6 | +1
| | 50 | 47.6 | –5
| | 100 | 92.1 | –8
| | 100 | 96.3 | –4
| | 200 | 193 | –4
| | 200 | 193 | –4
| | 200 | 192 | –4
| | 200 | 188 | –6
January 2, 2008 | January 3, 2008 | 50 | 47.5 | –5
| | 50 | 47.0 | –6
| | 100 | 96.5 | –4
| | 100 | 96.1 | –4
| | 200 | 193 | –4
| | 200 | 201 | +1
| | 200 | 202 | +1
| | 200 | 198 | –1
April 22, 2008 | April 23, 2008 | 50 | 47.6 | –5
| | 50 | 46.8 | –6
| | 200 | 192 | –4
| | 200 | 184 | –8
| | 200 | 187 | –7
| | 200 | 187 | –7
| May 29, 2008^b^ | 50 | 47.2 | –6
| | 200 | 192 | –4
April 28, 2008 | April 28, 2008 | 100 | 98.3 | –2
| | 100 | 96.8 | –3
| May 30, 2008^b^ | 100 | 94.4 | –6
July 15, 2008 | July 16, 2008 | 50 | 48.1 | –4
| | 50 | 45.8 | –8
| | 100 | 91.4 | –9
| | 100 | 91.9 | –8
| | 200 | 194 | –3
| | 200 | 197 | –2
| | 200 | 189 | –6
| | 200 | 190 | –5
October 7, 2008 | October 8, 2008 | 50 | 46.3 | –7
| | 100 | 91.7 | –8
| | 100 | 92.9 | –7
| | 200 | 216 | +8
| | 200 | 210 | +5
| | 200 | 219 | +10
October 20, 2008 | October 22, 2008 | 50 | 47.3 | –5
| | 200 | 212 | +6
January 27, 2009 | January 28, 2009 | 50 | 47.7 | –5
| | 50 | 46.2 | –8
| | 100 | 93.7 | –6
| | 100 | 94.2 | –6
| | 200 | 199 | –1
| | 200 | 200 | 0
| | 200 | 194 | –3
| | 200 | 207 | +4
| March 4-5, 2009^b^ | 50 | 48.3 | –3
| | 100 | 92.3 | –8
| | 200 | 225 | +13
April 21, 2009 | April 23, 2009 | 50 | 47.5 | –5
| | 50 | 47.6 | –5
| | 100 | 93.9 | –6
| | 100 | 96.5 | –4
| | 200 | 197 | –2
| | 200 | 199 | –1
| | 200 | 196 | –2
| | 200 | 198 | –1
July 1, 2009 | July 2, 2009 | 50 | 46.7 | –7
| | 50 | 47.6 | –5
| | 100 | 93.6 | –6
| | 100 | 91.8 | –8
| | 200 | 193 | –4
| | 200 | 193 | –4
| | 200 | 190 | –5
| | 200 | 193 | –3
Mice
July 12, 2007 | July 13, 2007 | 25 | 24.3 | –3
| | 50 | 48.2 | –4
| | 50 | 47.7 | –5
| | 100 | 94.9 | –5
| | 100 | 93.9 | –6
| August 21, 2007^b^ | 25 | 25.2 | +1
| | 50 | 48.5 | –3
| | 100 | 94.8 | –5
October 9, 2007 | October 10, 2007 | 25 | 24.9 | 0
| | 50 | 50.6 | +1
| | 50 | 47.6 | –5
| | 100 | 92.1 | –8
| | 100 | 96.3 | –4
January 2, 2008 | January 3, 2008 | 25 | 24.3 | –3
| | 50 | 47.5 | –5
| | 50 | 47.0 | –6
| | 100 | 96.5 | –4
| | 100 | 96.1 | –4
April 22, 2008 | April 23, 2008 | 25 | 23.8 | –5
| | 50 | 47.6 | –5
| | 50 | 46.8 | –6
| May 29, 2008^b^ | 25 | 24.3 | –3
| | 50 | 48.7 | –3
April 28, 2008 | April 28, 2008 | 100 | 98.3 | –2
| | 100 | 96.8 | –3
| May 30, 2008^b^ | 100 | 96.2 | –4
July 15, 2008 | July 16, 2008 | 25 | 24.1 | –4
| | 50 | 48.1 | –4
| | 50 | 45.8 | –8
| | 100 | 91.4 | –9
| | 100 | 91.9 | –8
October 7, 2008 | October 8, 2008 | 25 | 23.4 | –6
| | 50 | 46.3 | –7
| | 100 | 91.7 | –8
| | 100 | 92.9 | –7
October 20, 2008 | October 22, 2008 | 50 | 47.3 | –6
January 27, 2009 | January 28, 2009 | 25 | 24.3 | –3
| | 50 | 47.7 | –5
| | 50 | 46.2 | –8
| | 100 | 93.7 | –6
| | 100 | 94.2 | –6
| March 4-5, 2009^b^ | 25 | 23.4 | –6
| | 50 | 47.1 | –6
| | 100 | 89.3 | –11
April 21, 2009 | April 23, 2009 | 25 | 24.3 | –3
| | 50 | 47.5 | –5
| | 50 | 47.6 | –5
| | 100 | 93.9 | –6
| | 100 | 96.5 | –4
July 1, 2009 | July 2, 2009 | 25 | 23.9 | –4
| | 50 | 46.7 | –7
| | 50 | 47.6 | –5
| | 100 | 93.6 | –6
| | 100 | 91.8 | –8

^a^ Results of duplicate analyses. For rats, dosing volume=5 mL/kg; 50 mg/mL=250 mg/kg, 100 mg/mL=500 mg/kg, 200 mg/mL=1,000 mg/kg. For mice, dosing volume=10 mL/kg; 25 mg/mL=250 mg/kg, 50 mg/mL=500 mg/kg, and 100 mg/mL=1,000 mg/kg.

^b^ Animal room samples.

Figure J-1

Infrared Absorption Spectrum of Tetrabromobisphenol A

Figure J-2

Proton Nuclear Magnetic Resonance Spectrum of Tetrabromobisphenol A