# Appendix I Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table I-1 Summary of Reproductive Tissue Evaluations for Male F344/NTac Rats in the Three-month Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 100 mg/kg | 500 mg/kg | 1,000 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 345 ± 5 | 352 ± 7 | 339 ± 5 | 337 ± 6
L. Cauda epididymis | 0.1394 ± 0.0025 | 0.1428 ± 0.0036 | 0.1358 ± 0.0036 | 0.1397 ± 0.0046
L. Epididymis | 0.4201 ± 0.0069 | 0.4277 ± 0.0039 | 0.4194 ± 0.0064 | 0.4192 ± 0.0062
L. Testis | 1.4766 ± 0.0242 | 1.5395 ± 0.0191 | 1.4783 ± 0.0247 | 1.4904 ± 0.0200
Spermatid measurements
Spermatid heads (10^6^/testis) | 160.25 ± 8.04 | 175.25 ± 5.68 | 173.25 ± 7.85 | 168.63 ± 4.16
Spermatid heads (10^6^/g testis) | 131.76 ± 7.01 | 138.33 ± 4.52 | 144.09 ± 5.29 | 140.47 ± 3.31
Epididymal spermatozoal measurements
Sperm motility (%) | 82.0 ± 0.7 | 82.5 ± 0.4 | 82.8 ± 0.6 | 82.1 ± 0.5
Sperm (10^6^/cauda epididymis) | 89.7 ± 7.4 | 83.5 ± 5.0 | 88.8 ± 4.7 | 82.9 ± 6.7
Sperm (10^6^/g cauda epididymis) | 644 ± 53 | 585 ± 35 | 653 ± 31 | 596 ± 50

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table I-2 Estrous Cycle Characterization for Female F344/NTac Rats in the Three-month Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 100 mg/kg | 500 mg/kg | 1,000 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 185 ± 2 | 186 ± 5 | 189 ± 4 | 187 ± 3
Proportion of regular cycling females^b^ | 10/10 | 10/10 | 10/10 | 10/10
Estrous cycle length (days) | 5.0 ± 0.00 | 4.9 ± 0.07 | 4.9 ± 0.08 | 5.0 ± 0.00
Estrous stages (% of cycle)
Diestrus | 61.7 | 57.5 | 55.8 | 60.8
Proestrus | 16.7 | 15.0 | 13.3 | 15.0
Estrus | 20.8 | 25.0 | 26.7 | 23.3
Metestrus | 0.8 | 1.7 | 4.2 | 0.8
Uncertain diagnoses | 0.0 | 0.8 | 0.0 | 0.0

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated dosed females spent significantly more time in extended estrus than did females in the vehicle control group (100 mg/kg, P = 0.008; 500 and 1,000 mg/kg, P < 0.001).

^b^ Number of females with a regular cycle/number of females cycling.

Table I-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female F344/NTac Rats in the Three-month Gavage Study of Tetrabromobisphenol A

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | 0.124 | –
Overall Tests | 100 mg/kg vs. Vehicle Controls | 0.208 | –
Overall Tests | 500 mg/kg vs. Vehicle Controls | 0.34 | –
Overall Tests | 1,000 mg/kg vs. Vehicle Controls | 0.095 | –
Extended Estrus | Overall | ˂0.001 | –
Extended Estrus | 100 mg/kg vs. Vehicle Controls | 0.008 | –
Extended Estrus | 500 mg/kg vs. Vehicle Controls | ˂0.001 | –
Extended Estrus | 1,000 mg/kg vs. Vehicle Controls | ˂0.001 | –
Extended Diestrus | Overall | 0.0275 | –
Extended Diestrus | 100 mg/kg vs. Vehicle Controls | 0.318 | N
Extended Diestrus | 500 mg/kg vs. Vehicle Controls | 0.2 | N
Extended Diestrus | 1,000 mg/kg vs. Vehicle Controls | 0.366 | N
Extended Metestrus | Overall | 1 | –
Extended Metestrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Extended Metestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Extended Metestrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | Overall | 1 | –
Extended Proestrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Skipped Estrus | Overall | 1 | –
Skipped Estrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Skipped Estrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Skipped Estrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Skipped Diestrus | Overall | 1 | –
Skipped Diestrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Skipped Diestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Skipped Diestrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Summary of Significant Groups
Extended Estrus | 100 mg/kg vs. Vehicle Controls | 0.008 | –
Extended Estrus | 500 mg/kg vs. Vehicle Controls | ˂0.001 | –
Extended Estrus | 1,000 mg/kg vs. Vehicle Controls | ˂0.001 | –

^a^ N means that the dosed group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the vehicle control group.

Table I-4 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 100 mg/kg | 500 mg/kg | 1,000 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 37.4 ± 0.9 | 36.2 ± 1.0 | 37.1 ± 0.9 | 35.2 ± 1.2
L. Cauda epididymis | 0.0159 ± 0.0009 | 0.0159 ± 0.0009 | 0.0171 ± 0.0014 | 0.0183 ± 0.0030
L. Epididymis | 0.0446 ± 0.0014 | 0.0438 ± 0.0014 | 0.0445 ± 0.0011 | 0.0454 ± 0.0026
L. Testis | 0.1114 ± 0.0021 | 0.1104 ± 0.0016 | 0.1130 ± 0.0021 | 0.1075 ± 0.0020
Spermatid measurements
Spermatid heads (10^6^/testis) | 21.53 ± 0.81 | 21.90 ± 0.69 | 22.92 ± 0.67 | 21.26 ± 0.94
Spermatid heads (10^6^/g testis) | 223.35 ± 7.23 | 218.24 ± 8.63 | 217.09 ± 6.38 | 212.52 ± 8.03
Epididymal spermatozoal measurements
Sperm motility (%) | 83.8 ± 0.4 | 85.3 ± 0.4 | 84.3 ± 1.0 | 84.5 ± 0. 5
Sperm (10^6^/cauda epididymis) | 18.3 ± 1.7 | 15.7 ± 2.1 | 15.7 ± 2.8 | 14.8 ± 1.9
Sperm (10^6^/g cauda epididymis) | 1,152 ± 100 | 1,005 ± 137 | 976 ± 174 | 909 ± 154

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table I-5 Estrous Cycle Characterization for Female Mice in the Three-month Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 100 mg/kg | 500 mg/kg | 1,000 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 27.5 ± 0.6 | 26.2 ± 0.7 | 29.2 ± 0.7 | 27.7 ± 0.6
Proportion of regular cycling females^b^ | 9/10 | 8/10 | 9/9 | 9/10
Estrous cycle length (days) | 4.2 ± 0.12 | 3.9 ± 0.14 | 3.9 ± 0.06^c^ | 4.1 ± 0.11
Estrous stages (% of cycle)
Diestrus | 30.0 | 35.8 | 31.7 | 37.5
Proestrus | 0.0 | 0.0 | 0.0 | 0.0
Estrus | 47.5 | 41.7 | 44.2 | 40.0
Metestrus | 21.7 | 21.7 | 24.2 | 22.5
Uncertain diagnoses | 0.8 | 0.8 | 0.0 | 0.0

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated dosed females did not have significantly more extended estrus or diestrus than the vehicle controls.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.

Table I-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Mice in the Three-month Gavage Study of Tetrabromobisphenol A

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | 0.042 | –
Overall Tests | 100 mg/kg vs. Vehicle Controls | 0.232 | –
Overall Tests | 500 mg/kg vs. Vehicle Controls | 0.039 | N
Overall Tests | 1,000 mg/kg vs. Vehicle Controls | 0.159 | N
Extended Estrus | Overall | 0.581
Extended Estrus | 100 mg/kg vs. Vehicle Controls | 0.77 | N
Extended Estrus | 500 mg/kg vs. Vehicle Controls | 0.351 | N
Extended Estrus | 1,000 mg/kg vs. Vehicle Controls | 0.351 | N
Extended Diestrus | Overall | 0.202 | –
Extended Diestrus | 100 mg/kg vs. Vehicle Controls | 0.703 | –
Extended Diestrus | 500 mg/kg vs. Vehicle Controls | 0.05 | –
Extended Diestrus | 1,000 mg/kg vs. Vehicle Controls | 0.405 | –
Extended Metestrus | Overall | 1 | –
Extended Metestrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Extended Metestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Extended Metestrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | Overall | 1 | –
Extended Proestrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Skipped Estrus | Overall | 1 | –
Skipped Estrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Skipped Estrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Skipped Estrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Skipped Diestrus | Overall | 1 | –
Skipped Diestrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Skipped Diestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Skipped Diestrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Summary of Significant Groups
Overall Tests | 500 mg/kg vs. Vehicle Controls | 0.039 | N

^a^ N means that the dosed group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the vehicle control group.

Figure I-1

Vaginal Cytology Plots for Female F344/NTac Rats in the Three-month Gavage Study of Tetrabromobisphenol A

D = diestrus, P = proestrus, E = estrus, M = metestrus, IC = insufficient number of cells to determine stage.

Figure I-2

Vaginal Cytology Plots for Female Mice in the Three-month Gavage Study of Tetrabromobisphenol A

D = diestrus, E = estrus, M = metestrus, IC = insufficient number of cells to determine stage.