# Appendix H Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table H-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/NTac Rats in the Three-month Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 10 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg | 1,000 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 345 ± 5 | 354 ± 6 | 350 ± 7 | 352 ± 7 | 339 ± 5 | 337 ± 6
Heart
Absolute | 0.95 ± 0.02 | 1.01 ± 0.03 | 1.02 ± 0.02 | 0.95 ± 0.02 | 0.97 ± 0.02 | 0.97 ± 0.02
Relative | 2.75 ± 0.04 | 2.83 ± 0.06 | 2.91 ± 0.04 | 2.70 ± 0.05 | 2.88 ± 0.04 | 2.89 ± 0.06
R. Kidney
Absolute | 0.94 ± 0.02 | 0.95 ± 0.02 | 0.96 ± 0.02 | 0.92 ± 0.02 | 0.92 ± 0.03 | 0.92 ± 0.02
Relative | 2.72 ± 0.04 | 2.67 ± 0.05 | 2.74 ± 0.03 | 2.61 ± 0.05 | 2.71 ± 0.05 | 2.72 ± 0.05
Liver
Absolute | 11.88 ± 0.26 | 12.04 ± 0.34 | 11.74 ± 0.30 | 11.89 ± 0.28 | 12.98 ± 0.22** | 13.24 ± 0.27**
Relative | 34.40 ± 0.35 | 33.93 ± 0.48 | 33.55 ± 0.30 | 33.81 ± 0.33 | 38.31 ± 0.23** | 39.25 ± 0.30**
Lung
Absolute | 1.92 ± 0.06 | 2.11 ± 0.13 | 2.26 ± 0.12 | 2.02 ± 0.09 | 2.01 ± 0.11 | 1.91 ± 0.09
Relative | 5.56 ± 0.18 | 5.99 ± 0.40 | 6.46 ± 0.28 | 5.77 ± 0.27 | 5.92 ± 0.27 | 5.65 ± 0.20
Spleen
Absolute | 0.660 ± 0.011 | 0.673 ± 0.017 | 0.655 ± 0.010 | 0.647 ± 0.008 | 0.584 ± 0.011** | 0.602 ± 0.017**
Relative | 1.92 ± 0.03 | 1.90 ± 0.03 | 1.87 ± 0.03 | 1.84 ± 0.03 | 1.72 ± 0.02** | 1.79 ± 0.04**
R. Testis
Absolute | 1.414 ± 0.025 | 1.460 ± 0.029 | 1.422 ± 0.023 | 1.443 ± 0.016 | 1.413 ± 0.019 | 1.438 ± 0.029
Relative | 4.102 ± 0.074 | 4.123 ± 0.060 | 4.072 ± 0.056 | 4.111 ± 0.061 | 4.175 ± 0.056 | 4.267 ± 0.061
Thymus
Absolute | 0.338 ± 0.015 | 0.340 ± 0.013 | 0.370 ± 0.013 | 0.337 ± 0.011 | 0.327 ± 0.010 | 0.291 ± 0.012*
Relative | 0.979 ± 0.041 | 0.959 ± 0.027 | 1.056 ± 0.026 | 0.957 ± 0.026 | 0.969 ± 0.033 | 0.863 ± 0.037
Female
Necropsy body wt | 185 ± 2 | 189 ± 4 | 191 ± 2 | 186 ± 5 | 189 ± 4 | 187 ± 3
Heart
Absolute | 0.66 ± 0.01 | 0.63 ± 0.01 | 0.67 ± 0.02 | 0.65 ± 0.02 | 0.63 ± 0.02 | 0.63 ± 0.01
Relative | 3.60 ± 0.08 | 3.36 ± 0.05 | 3.50 ± 0.11 | 3.48 ± 0.09 | 3.31 ± 0.06* | 3.34 ± 0.04
R. Kidney
Absolute | 0.57 ± 0.01 | 0.57 ± 0.01 | 0.59 ± 0.01 | 0.59 ± 0.02 | 0.56 ± 0.01 | 0.57 ± 0.01
Relative | 3.09 ± 0.03 | 3.04 ± 0.03 | 3.12 ± 0.04 | 3.15 ± 0.06 | 2.97 ± 0.03 | 3.02 ± 0.04
Liver
Absolute | 5.82 ± 0.10 | 6.04 ± 0.18 | 6.08 ± 0.11 | 6.01 ± 0.18 | 6.44 ± 0.14** | 6.60 ± 0.10**
Relative | 31.48 ± 0.31 | 31.93 ± 0.44 | 31.84 ± 0.32 | 32.34 ± 0.35 | 34.13 ± 0.42** | 35.25 ± 0.36**
Lung
Absolute | 1.42 ± 0.03 | 1.40 ± 0.04 | 1.36 ± 0.08 | 1.34 ± 0.05 | 1.24 ± 0.05 | 1.31 ± 0.06
Relative | 7.70 ± 0.19 | 7.45 ± 0.31 | 7.15 ± 0.42 | 7.23 ± 0.29 | 6.56 ± 0.28* | 6.95 ± 0.24
Spleen
Absolute | 0.462 ± 0.010 | 0.456 ± 0.012 | 0.478 ± 0.010 | 0.489 ± 0.017 | 0.447 ± 0.008 | 0.443 ± 0.008
Relative | 2.50 ± 0.04 | 2.41 ± 0.04 | 2.51 ± 0.05 | 2.64 ± 0.09 | 2.37 ± 0.06 | 2.37 ± 0.05
Thymus
Absolute | 0.253 ± 0.013 | 0.243 ± 0.011 | 0.268 ± 0.010 | 0.247 ± 0.012 | 0.242 ± 0.011 | 0.238 ± 0.004
Relative | 1.371 ± 0.067 | 1.287 ± 0.062 | 1.402 ± 0.043 | 1.332 ± 0.061 | 1.280 ± 0.045 | 1.274 ± 0.030

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table H-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Wistar Han Rats at the Three-month Interim Evaluation in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 1,000 mg/kg
n | 10 | 10
Male
Necropsy body wt | 399 ± 8 | 394 ± 14
Heart
Absolute | 1.25 ± 0.05 | 1.24 ± 0.05
Relative | 3.14 ± 0.10 | 3.17 ± 0.11
R. Kidney
Absolute | 1.27 ± 0.02 | 1.27 ± 0.04
Relative | 3.19 ± 0.05 | 3.24 ± 0.05
Liver
Absolute | 15.59 ± 0.52 | 16.73 ± 0.67
Relative | 39.04 ± 0.76 | 42.50 ± 0.78**
Lung
Absolute | 2.37 ± 0.14 | 2.14 ± 0.11
Relative | 5.93 ± 0.31 | 5.49 ± 0.30
R. Testis
Absolute | 1.871 ± 0.052 | 1.895 ± 0.040
Relative | 4.704 ± 0.151 | 4.865 ± 0.188
Thymus
Absolute | 0.468 ± 0.023 | 0.377 ± 0.012**
Relative | 1.178 ± 0.063 | 0.970 ± 0.046*
Female
Necropsy body wt | 242 ± 7 | 236 ± 5
Heart
Absolute | 0.77 ± 0.03 | 0.78 ± 0.03
Relative | 3.18 ± 0.05 | 3.29 ± 0.07
R. Kidney
Absolute | 0.84 ± 0.03 | 0.80 ± 0.03
Relative | 3.49 ± 0.06 | 3.38 ± 0.10
Liver
Absolute | 8.39 ± 0.28 | 8.73 ± 0.25
Relative | 34.77 ± 0.81 | 36.92 ± 0.43*
Lung
Absolute | 1.47 ± 0.07 | 1.38 ± 0.08
Relative | 6.05 ± 0.13 | 5.83 ± 0.24
Thymus
Absolute | 0.383 ± 0.023 | 0.311 ± 0.016*
Relative | 1.579 ± 0.072 | 1.317 ± 0.060*

* Significantly different (P ≤ 0.05) from the vehicle control group by a t-test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table H-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 10 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg | 1,000 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 37.4 ± 0.9 | 34.7 ± 0.7 | 38.4 ± 0.6 | 36.2 ± 1.0 | 37.1 ± 0.9 | 35.2 ± 1.2
Heart
Absolute | 0.17 ± 0.01 | 0.16 ± 0.01 | 0.19 ± 0.01 | 0.17 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.01
Relative | 4.52 ± 0.19 | 4.71 ± 0.20 | 4.89 ± 0.19 | 4.73 ± 0.16 | 4.22 ± 0.13 | 4.43 ± 0.15
R. Kidney
Absolute | 0.28 ± 0.00 | 0.27 ± 0.01 | 0.29 ± 0.01 | 0.29 ± 0.01 | 0.27 ± 0.01 | 0.24 ± 0.01**
Relative | 7.42 ± 0.15 | 7.75 ± 0.14 | 7.54 ± 0.14 | 7.91 ± 0.30 | 7.22 ± 0.23 | 6.72 ± 0.16*
Liver
Absolute | 1.44 ± 0.06 | 1.42 ± 0.04 | 1.59 ± 0.03 | 1.43 ± 0.03 | 1.61 ± 0.03** | 1.60 ± 0.06*
Relative | 38.33 ± 0.74 | 40.91 ± 0.50* | 41.42 ± 0.57* | 39.65 ± 0.67* | 43.66 ± 1.02** | 45.43 ± 0.81**
Lung
Absolute | 0.26 ± 0.02 | 0.25 ± 0.02 | 0.27 ± 0.02 | 0.24 ± 0.02 | 0.22 ± 0.01 | 0.23 ± 0.02
Relative | 6.95 ± 0.51 | 7.17 ± 0.47 | 6.97 ± 0.41 | 6.65 ± 0.48 | 6.00 ± 0.35 | 6.56 ± 0.30
Spleen
Absolute | 0.064 ± 0.001 | 0.063 ± 0.002 | 0.069 ± 0.002 | 0.066 ± 0.002 | 0.069 ± 0.002* | 0.069 ± 0.002*
Relative | 1.71 ± 0.05 | 1.81 ± 0.06 | 1.80 ± 0.04 | 1.85 ± 0.07 | 1.88 ± 0.06 | 1.98 ± 0.08**
R. Testis
Absolute | 0.118 ± 0.002 | 0.112 ± 0.002 | 0.112 ± 0.002 | 0.118 ± 0.002 | 0.121 ± 0.002 | 0.113 ± 0.002
Relative | 3.180 ± 0.075 | 3.247 ± 0.081 | 2.915 ± 0.061 | 3.274 ± 0.087 | 3.269 ± 0.094 | 3.236 ± 0.076
Thymus
Absolute | 0.049 ± 0.003 | 0.041 ± 0.002 | 0.055 ± 0.003 | 0.046 ± 0.004 | 0.047 ± 0.002 | 0.047 ± 0.003
Relative | 1.323 ± 0.070 | 1.171 ± 0.050 | 1.419 ± 0.069 | 1.276 ± 0.088 | 1.263 ± 0.051 | 1.339 ± 0.070
Female
Necropsy body wt | 27.5 ± 0.6 | 29.3 ± 1.0 | 28.6 ± 0.7 | 26.2 ± 0.7 | 29.2 ± 0.7 | 27.7 ± 0.6
Heart
Absolute | 0.14 ± 0.01 | 0.16 ± 0.01 | 0.14 ± 0.01 | 0.15 ± 0.01 | 0.15 ± 0.01 | 0.15 ± 0.01
Relative | 5.26 ± 0.22 | 5.38 ± 0.17 | 4.91 ± 0.25 | 5.67 ± 0.16 | 5.08 ± 0.21 | 5.49 ± 0.28
R. Kidney
Absolute | 0.16 ± 0.00 | 0.17 ± 0.00 | 0.17 ± 0.00 | 0.16 ± 0.00 | 0.17 ± 0.01 | 0.17 ± 0.00
Relative | 5.89 ± 0.12 | 5.87 ± 0.17 | 5.88 ± 0.15 | 6.15 ± 0.13 | 5.80 ± 0.11 | 5.96 ± 0.08
Liver
Absolute | 1.10 ± 0.03 | 1.15 ± 0.04 | 1.16 ± 0.03 | 1.09 ± 0.04 | 1.18 ± 0.03 | 1.24 ± 0.04*
Relative | 40.18 ± 1.05 | 39.31 ± 0.75 | 40.77 ± 1.06 | 41.76 ± 0.40 | 40.34 ± 0.59 | 44.85 ± 0.64**
Lung
Absolute | 0.29 ± 0.01 | 0.29 ± 0.01 | 0.27 ± 0.02 | 0.29 ± 0.02 | 0.31 ± 0.01 | 0.28 ± 0.02
Relative | 10.61 ± 0.33 | 10.03 ± 0.58 | 9.47 ± 0.51 | 11.23 ± 0.47 | 10.61 ± 0.64 | 10.00 ± 0.64
Spleen
Absolute | 0.079 ± 0.002 | 0.089 ± 0.005 | 0.084 ± 0.003 | 0.078 ± 0.002 | 0.088 ± 0.003 | 0.091 ± 0.005
Relative | 2.86 ± 0.08 | 3.05 ± 0.15 | 2.96 ± 0.13 | 2.97 ± 0.06 | 3.00 ± 0.05 | 3.27 ± 0.12*
Thymus
Absolute | 0.048 ± 0.002 | 0.052 ± 0.003 | 0.051 ± 0.002 | 0.047 ± 0.002 | 0.052 ± 0.004 | 0.050 ± 0.002
Relative | 1.749 ± 0.054 | 1.761 ± 0.109 | 1.792 ± 0.057 | 1.796 ± 0.055 | 1.779 ± 0.124 | 1.818 ± 0.049

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).