# Appendix G Liver Enzyme Results

Table G-1 Liver Enzyme Activities for F344/NTac Rats in the Three-month Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 10 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg | 1,000 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
Day 23 | 0.967 ± 0.033 | 0.995 ± 0.043 | 0.693 ± 0.060** | 0.561 ± 0.016** | 0.671 ± 0.015** | 0.673 ± 0.029**
Week 14 | 0.781 ± 0.028 | 0.802 ± 0.027 | 0.613 ± 0.040 | 0.629 ± 0.034 | 0.787 ± 0.039 | 0.997 ± 0.046
7-Ethoxyresorufin-O-deethylase (EROD) (pmol/minute per mg microsomal protein)
Day 23 | 42.4 ± 1.9 | 41.1 ± 2.7 | 28.0 ± 4.0* | 21.7 ± 1.0** | 24.2 ± 0.8** | 22.8 ± 1.6**
Week 14 | 36.8 ± 1.6 | 36.6 ± 1.1 | 27.5 ± 1.8 | 38.1 ± 0.8 | 50.3 ± 1.8** | 66.5 ± 2.4**
7-Pentoxyresorufin-O-dealkylase (PROD) (pmol/minute per mg microsomal protein)
Day 23 | 8.5 ± 0.2 | 8.3 ± 0.4 | 5.8 ± 0.5** | 5.1 ± 0.3** | 6.2 ± 0.5* | 10.1 ± 1.7
Week 14 | 8.4 ± 0.3 | 7.8 ± 0.3 | 6.2 ± 0.5 | 7.2 ± 0.3 | 108.6 ± 7.4* | 196.7 ± 11.2**
UDP-Glucuronosyl transferase (pmol/minute per mg microsomal protein)
Day 23 | 4.75 ± 0.15 | 3.50 ± 0.14** | 3.06 ± 0.25** | 2.63 ± 0.16** | 2.92 ± 0.14** | 3.16 ± 0.26**
Week 14 | 3.34 ± 0.13 | 3.55 ± 0.15 | 2.83 ± 0.14 | 3.02 ± 0.19 | 3.94 ± 0.20 | 4.20 ± 0.21
Female
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
Day 23 | 1.125 ± 0.044 | 1.013 ± 0.045 | 0.633 ± 0.033** | 0.613 ± 0.026** | 0.795 ± 0.050** | 0.841 ± 0.046**
Week 14 | 0.873 ± 0.030 | 0.856 ± 0.021 | 0.664 ± 0.020** | 0.629 ± 0.038** | 0.855 ± 0.040 | 0.961 ± 0.038
7-Ethoxyresorufin-O-deethylase (EROD) (pmol/minute per mg microsomal protein)
Day 23 | 70.8 ± 1.9 | 64.8 ± 2.3 | 39.7 ± 2.5** | 54.1 ± 1.8** | 64.6 ± 3.1 | 62.1 ± 2.7
Week 14 | 80.2 ± 2.8 | 75.3 ± 2.1 | 59.4 ± 1.3** | 53.1 ± 2.7** | 77.6 ± 4.7 | 84.1 ± 4.2
7-Pentoxyresorufin-O-dealkylase (PROD) (pmol/minute per mg microsomal protein)
Day 23 | 8.0 ± 0.3 | 7.2 ± 0.3 | 4.4 ± 0.2** | 5.5 ± 0.2** | 7.3 ± 0.5 | 9.4 ± 1.6
Week 14 | 7.1 ± 0.4 | 6.9 ± 0.3 | 5.3 ± 0.2 | 5.3 ± 0.3 | 26.8 ± 4.2** | 56.0 ± 6.5**
UDP-Glucuronosyl transferase (pmol/minute per mg microsomal protein)
Day 23 | 3.77 ± 0.14 | 3.34 ± 0.16 | 2.48 ± 0.13** | 2.23 ± 0.07** | 2.41 ± 0.09** | 2.21 ± 0.10**
Week 14 | 4.03 ± 0.16 | 3.95 ± 0.09 | 3.45 ± 0.11** | 2.96 ± 0.08** | 2.86 ± 0.07** | 2.76 ± 0.05**

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P≤0.01.

^a^ Data are given as mean ± standard error. Statistical tests are performed on unrounded data.

Table G-2 Liver Enzyme Activities for Mice in the Three-month Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 10 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg | 1,000 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
| 0.952 ± 0.096 | 0.886 ± 0.071 | 0.883 ± 0.089 | 0.787 ± 0.058 | 0.719 ± 0.045* | 0.665 ± 0.061*
7-Ethoxyresorufin-O-deethylase (EROD) (pmol/minute per mg microsomal protein)
| 207.5 ± 14.4 | 203.5 ± 9.3 | 204.4 ± 13.4 | 195.7 ± 7.7 | 167.1 ± 7.0* | 131.1 ± 9.2**
7-Pentoxyresorufin-O-dealkylase (PROD) (pmol/minute per mg microsomal protein)
| 10.5 ± 0.8 | 9.4 ± 0.4 | 9.2 ± 0.9 | 9.0 ± 0.6 | 7.8 ± 0.4** | 6.4 ± 0.4**
UDP-Glucuronosyl transferase (pmol/minute per mg microsomal protein)
| 2.27 ± 0.19 | 2.12 ± 0.10 | 1.97 ± 0.12 | 2.02 ± 0.12 | 1.95 ± 0.13 | 2.49 ± 0.13
Female
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
| 0.543 ± 0.042 | 0.609 ± 0.032 | 0.483 ± 0.031 | 0.523 ± 0.020 | 0.627 ± 0.023 | 0.527 ± 0.029
7-Ethoxyresorufin-O-deethylase (EROD) (pmol/minute per mg microsomal protein)
| 98.5 ± 5.5 | 110.4 ± 6.1 | 86.2 ± 4.4 | 96.2 ± 2.0 | 109.0 ± 5.4 | 88.8 ± 4.7
7-Pentoxyresorufin-O-dealkylase (PROD) (pmol/minute per mg microsomal protein)
| 13.9 ± 0.7 | 15.4 ± 0.6 | 12.6 ± 0.5 | 12.4 ± 0.5 | 12.8 ± 0.6 | 9.9 ± 0.7**
UDP-Glucuronosyl transferase (pmol/minute per mg microsomal protein)
| 2.95 ± 0.22 | 2.59 ± 0.15 | 2.66 ± 0.13* | 2.89 ± 0.10 | 2.87 ± 0.15 | 2.84 ± 0.18

* Significantly different (P ≤ 0.05) from the vehicle control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are given as mean ± standard error. Statistical tests are performed on unrounded data.