# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for F344/NTac Rats in the Three-month Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 10 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
Hematology
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%)
Day 23 | 53.1 ± 1.6 | 53.5 ± 1.8 | 50.4 ± 1.3 | 52.9 ± 1.4 | 47.7 ± 0.7** | 47.8 ± 0.9**
Week 14 | 46.9 ± 0.3 | 47.6 ± 0.4 | 47.5 ± 0.5 | 46.8 ± 0.5 | 46.3 ± 0.4 | 45.7 ± 0.5
Hemoglobin (g/dL)
Day 23 | 16.4 ± 0.5 | 16.5 ± 0.5 | 15.5 ± 0.3 | 16.3 ± 0.4 | 14.8 ± 0.1** | 14.9 ± 0.2**
Week 14 | 14.6 ± 0.1 | 14.6 ± 0.1 | 14.6 ± 0.2 | 14.6 ± 0.2 | 14.4 ± 0.1 | 14.0 ± 0.1**
Erythrocytes (10^6^/μL)
Day 23 | 8.78 ± 0.23 | 8.86 ± 0.26 | 8.36 ± 0.20 | 8.74 ± 0.21 | 8.05 ± 0.08** | 8.04 ± 0.13**
Week 14 | 9.10 ± 0.06 | 9.22 ± 0.09 | 9.27 ± 0.08 | 9.13 ± 0.12 | 9.04 ± 0.07 | 8.81 ± 0.09*
Reticulocytes (10^6^/μL)
Day 23 | 0.32 ± 0.02 | 0.31 ± 0.02 | 0.33 ± 0.01 | 0.36 ± 0.02 | 0.27 ± 0.02 | 0.34 ± 0.01
Week 14 | 0.21 ± 0.00 | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.19 ± 0.01 | 0.20 ± 0.01 | 0.22 ± 0.01
Mean cell volume (fL)
Day 23 | 60.4 ± 0.4 | 60.3 ± 0.3 | 60.2 ± 0.3 | 60.5 ± 0.3 | 59.2 ± 0.4 | 59.5 ± 0.4
Week 14 | 51.6 ± 0.2 | 51.7 ± 0.2 | 51.2 ± 0.2 | 51.2 ± 0.3 | 51.3 ± 0.2 | 51.9 ± 0.2
Mean cell hemoglobin (pg)
Day 23 | 18.6 ± 0.2 | 18.7 ± 0.1 | 18.5 ± 0.1 | 18.7 ± 0.1 | 18.4 ± 0.1 | 18.5 ± 0.1
Week 14 | 16.1 ± 0.1 | 15.9 ± 0.1 | 15.7 ± 0.1 | 16.0 ± 0.1 | 15.9 ± 0.1 | 15.9 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 23 | 30.9 ± 0.2 | 31.0 ± 0.2 | 30.8 ± 0.2 | 30.8 ± 0.1 | 31.1 ± 0.3 | 31.1 ± 0.2
Week 14 | 31.2 ± 0.2 | 30.8 ± 0.2 | 30.7 ± 0.2 | 31.2 ± 0.2 | 31.0 ± 0.1 | 30.7 ± 0.2
Platelets (10^3^/μL)
Day 23 | 975 ± 33 | 1,034 ± 23 | 1,023 ± 24 | 939 ± 46 | 994 ± 23 | 956 ± 16
Week 14 | 783 ± 32 | 845 ± 15 | 841 ± 29 | 852 ± 11 | 794 ± 20 | 858 ± 12
Leukocytes (10^3^/μL)
Day 23 | 8.47 ± 0.38 | 8.53 ± 0.27 | 8.35 ± 0.28 | 8.19 ± 0.20 | 8.11 ± 0.27 | 7.32 ± 0.32*
Week 14 | 8.62 ± 0.27 | 9.24 ± 0.48 | 9.64 ± 0.42 | 8.63 ± 0.32 | 8.80 ± 0.34 | 8.95 ± 0.40
Segmented neutrophils (10^3^/μL)
Day 23 | 1.44 ± 0.11 | 1.66 ± 0.09 | 1.58 ± 0.11 | 1.47 ± 0.06 | 1.48 ± 0.08 | 1.20 ± 0.09
Week 14 | 1.64 ± 0.17 | 1.44 ± 0.09 | 1.55 ± 0.11 | 1.46 ± 0.07 | 1.56 ± 0.12 | 1.32 ± 0.12
Lymphocytes (10^3^/μL)
Day 23 | 6.59 ± 0.30 | 6.41 ± 0.20 | 6.35 ± 0.21 | 6.25 ± 0.22 | 6.24 ± 0.28 | 5.80 ± 0.25
Week 14 | 6.64 ± 0.26 | 7.50 ± 0.41 | 7.75 ± 0.40 | 6.87 ± 0.29 | 6.90 ± 0.30 | 7.32 ± 0.31
Monocytes (10^3^/μL)
Day 23 | 0.25 ± 0.02 | 0.25 ± 0.02 | 0.25 ± 0.02 | 0.27 ± 0.02 | 0.25 ± 0.02 | 0.19 ± 0.01
Week 14 | 0.20 ± 0.02 | 0.20 ± 0.01 | 0.21 ± 0.01 | 0.21 ± 0.03 | 0.22 ± 0.01 | 0.22 ± 0.02
Basophils (10^3^/μL)
Day 23 | 0.138 ± 0.021 | 0.157 ± 0.021 | 0.126 ± 0.016 | 0.138 ± 0.023 | 0.100 ± 0.013 | 0.088 ± 0.009
Week 14 | 0.048 ± 0.003 | 0.051 ± 0.005 | 0.058 ± 0.007 | 0.042 ± 0.004 | 0.048 ± 0.005 | 0.052 ± 0.006
Eosinophils (10^3^/μL)
Day 23 | 0.05 ± 0.00 | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.05 ± 0.00 | 0.04 ± 0.00
Week 14 | 0.09 ± 0.02 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.00 | 0.08 ± 0.02 | 0.05 ± 0.01**
Clinical Chemistry
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 8.4 ± 0.5 | 9.6 ± 0.6 | 10.0 ± 0.5* | 10.6 ± 0.5**^b^ | 10.9 ± 0.6** | 10.2 ± 0.4**^b^
Day 23 | 10.3 ± 0.3^c^ | 11.0 ± 0.6^b^ | 10.7 ± 0.5 | 10.6 ± 0.6^b^ | 11.5 ± 0.3 | 11.8 ± 0.9
Week 14 | 12.6 ± 0.7 | 12.9 ± 0.7 | 11.9 ± 0.5 | 12.1 ± 0.4 | 11.5 ± 0.5 | 11.1 ± 0.7
Creatinine (mg/dL)
Day 4 | 0.49 ± 0.01 | 0.50 ± 0.02 | 0.51 ± 0.01 | 0.49 ± 0.01^b^ | 0.49 ± 0.01 | 0.50 ± 0.00^b^
Day 23 | 0.59 ± 0.02^b^ | 0.64 ± 0.04^b^ | 0.59 ± 0.01 | 0.61 ± 0.03 | 0.56 ± 0.02 | 0.57 ± 0.02
Week 14 | 0.65 ± 0.02 | 0.68 ± 0.02 | 0.64 ± 0.02 | 0.68 ± 0.01 | 0.63 ± 0.02 | 0.62 ± 0.01
Glucose (mg/dL)
Day 4 | 130 ± 1 | 124 ± 2 | 133 ± 2 | 133 ± 3^b^ | 133 ± 3 | 137 ± 2^b^
Day 23 | 195 ± 8^c^ | 176 ± 6^b^ | 180 ± 5 | 195 ± 4^b^ | 177 ± 6 | 185 ± 7
Week 14 | 230 ± 8 | 223 ± 8 | 235 ± 5 | 246 ± 5 | 217 ± 8 | 214 ± 8
Total protein (g/dL)
Day 4 | 5.7 ± 0.0 | 5.7 ± 0.1 | 5.8 ± 0.1 | 5.8 ± 0.1^b^ | 5.7 ± 0.1 | 5.8 ± 0.1^b^
Day 23 | 6.2 ± 0.1^c^ | 6.6 ± 0.1^b^ | 6.3 ± 0.1 | 6.4 ± 0.0^b^ | 6.2 ± 0.0 | 6.3 ± 0.1
Week 14 | 7.1 ± 0.0 | 7.3 ± 0.1 | 7.0 ± 0.1 | 7.1 ± 0.1 | 7.4 ± 0.1** | 7.3 ± 0.1**
Albumin (g/dL)
Day 4 | 4.0 ± 0.0 | 4.1 ± 0.0 | 4.2 ± 0.0 | 4.1 ± 0.0^b^ | 4.1 ± 0.0 | 4.2 ± 0.1^b^
Day 23 | 4.2 ± 0.1^c^ | 4.4 ± 0.1*^b^ | 4.3 ± 0.0 | 4.3 ± 0.0^b^ | 4.2 ± 0.0 | 4.3 ± 0.0
Week 14 | 4.6 ± 0.0 | 4.7 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.1 | 4.9 ± 0.0** | 4.9 ± 0.0**
Cholesterol (mg/dL)
Day 4 | 91 ± 2 | 94 ± 2 | 91 ± 2 | 89 ± 4 | 93 ± 2 | 99 ± 3
Day 23 | 88 ± 4 | 94 ± 4 | 86 ± 3 | 95 ± 3 | 88 ± 2 | 89 ± 3
Week 14 | 76 ± 1 | 76 ± 2 | 74 ± 3 | 79 ± 2 | 79 ± 1 | 75 ± 2
Alanine aminotransferase (IU/L)
Day 4 | 64 ± 1 | 66 ± 3 | 65 ± 2 | 64 ± 2 | 70 ± 2 | 67 ± 2
Day 23 | 60 ± 2 | 55 ± 3 | 52 ± 1* | 57 ± 3 | 50 ± 1** | 53 ± 2
Week 14 | 87 ± 5b | 89 ± 6^b^ | 77 ± 5^b^ | 62 ± 3** | 57 ± 2** | 56 ± 2**
Alkaline phosphatase (IU/L)
Day 4 | 647 ± 11 | 674 ± 33 | 639 ± 10 | 644 ± 16 | 678 ± 15 | 661 ± 18
Day 23 | 507 ± 19^b^ | 538 ± 21^b^ | 507 ± 9 | 543 ± 14 | 505 ± 9 | 508 ± 16
Week 14 | 283 ± 4 | 281 ± 6 | 278 ± 5 | 260 ± 6 | 363 ± 11** | 360 ± 11**
Creatine kinase (IU/L)
Day 4 | 353 ± 70 | 450 ± 111 | 343 ± 34 | 304 ± 31^b^ | 439 ± 59 | 282 ± 36^b^
Day 23 | 252 ± 18^c^ | 259 ± 21^b^ | 214 ± 21 | 223 ± 15^b^ | 248 ± 26 | 236 ± 29
Week 14 | 264 ± 125 | 283 ± 120 | 237 ± 103 | 116 ± 8 | 153 ± 19 | 156 ± 17
Sorbitol dehydrogenase (IU/L)
Day 4 | 15 ± 1 | 14 ± 1 | 15 ± 1 | 15 ± 1 | 14 ± 3 | 12 ± 1
Day 23 | 14 ± 1^b^ | 14 ± 1 | 12 ± 1 | 13 ± 1 | 13 ± 0 | 12 ± 1
Week 14 | 30 ± 1^b^ | 31 ± 1^b^ | 28 ± 1^b^ | 27 ± 1* | 23 ± 1** | 20 ± 1**
Bile acids (µmol/L)
Day 4 | 13.5 ± 1.2 | 13.7 ± 1.6 | 16.0 ± 2.4 | 11.9 ± 1.0 | 25.7 ± 2.5** | 31.6 ± 5.6**
Day 23 | 6.4 ± 0.5^b^ | 8.7 ± 1.0^b^ | 8.4 ± 1.8 | 7.0 ± 0.8 | 11.9 ± 2.6* | 16.8 ± 2.4**
Week 14 | 15.2 ± 1.7 | 22.9 ± 3.5 | 19.5 ± 2.2 | 23.7 ± 2.6 | 14.7 ± 4.0 | 8.6 ± 2.6
Total thyroxine (μg/dL)
Day 4 | 6.13 ± 0.18 | 5.94 ± 0.19 | 6.12 ± 0.14 | 5.56 ± 0.17 | 4.78 ± 0.18** | 4.49 ± 0.30**
Day 23 | 5.11 ± 0.31 | 5.71 ± 0.34 | 5.52 ± 0.27 | 4.72 ± 0.22 | 3.35 ± 0.19** | 3.78 ± 0.22**^d^
Week 14 | 4.66 ± 0.16 | 4.78 ± 0.25 | 4.61 ± 0.13 | 3.67 ± 0.21** | 3.08 ± 0.12** | 2.80 ± 0.13**
Total triiodothyronine (μg/dL)
Day 23 | 151.2 ± 6.2 | 190.9 ± 14.7 | 167.6 ± 6.8 | 184.4 ± 7.5* | 164.4 ± 9.7 | 199.6 ± 10.6**^d^
Week 14 | 105.9 ± 5.6^c^ | 109.4 ± 8.2^b^ | 106.7 ± 6.7^b^ | 96.7 ± 5.5 | 97.6 ± 4.5 | 102.4 ± 5.2
Thyroid stimulating hormone (ng/dL)
Day 4 | 5.37 ± 0.39^b^ | 5.70 ± 0.29 | 5.06 ± 0.43 | 4.80 ± 0.35^b^ | 4.84 ± 0.35^b^ | 4.78 ± 0.22^b^
Day 23 | 7.41 ± 0.43 | 8.10 ± 0.54^b^ | 8.49 ± 0.49 | 6.95 ± 0.41 | 6.22 ± 0.30 | 6.50 ± 0.33^d^
Week 14 | 8.04 ± 0.42 | 7.94 ± 0.49 | 8.19 ± 0.37 | 7.83 ± 0.42 | 5.99 ± 0.29** | 7.38 ± 0.34*
Female
Hematology
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%)
Day 23 | 56.0 ± 2.0 | 56.2 ± 1.8 | 56.0 ± 2.1 | 52.2 ± 1.6 | 51.6 ± 0.8 | 53.4 ± 1.7
Week 14 | 46.3 ± 0.5 | 45.7 ± 0.6 | 46.4 ± 0.3 | 45.9 ± 0.5 | 44.5 ± 0.4** | 44.7 ± 0.4**
Hemoglobin (g/dL)
Day 23 | 17.7 ± 0.6 | 17.7 ± 0.5 | 17.5 ± 0.6 | 16.5 ± 0.5 | 16.1 ± 0.2 | 16.7 ± 0.5
Week 14 | 14.5 ± 0.1 | 14.6 ± 0.2 | 14.5 ± 0.1 | 14.4 ± 0.2 | 13.9 ± 0.1** | 14.0 ± 0.1**
Erythrocytes (10^6^/μL)
Day 23 | 9.49 ± 0.32 | 9.52 ± 0.28 | 9.43 ± 0.32 | 8.86 ± 0.28 | 8.87 ± 0.16 | 9.05 ± 0.27
Week 14 | 8.57 ± 0.07 | 8.44 ± 0.12 | 8.51 ± 0.05 | 8.37 ± 0.09 | 8.21 ± 0.06** | 8.31 ± 0.06*
Reticulocytes (10^6^/μL)
Day 23 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.20 ± 0.01 | 0.22 ± 0.01
Week 14 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.21 ± 0.01 | 0.20 ± 0.01 | 0.19 ± 0.01 | 0.18 ± 0.01
Mean cell volume (fL)
Day 23 | 59.0 ± 0.2 | 59.0 ± 0.3 | 59.3 ± 0.4 | 59.0 ± 0.2 | 58.2 ± 0.2 | 59.0 ± 0.3
Week 14 | 54.1 ± 0.2 | 54.1 ± 0.2 | 54.6 ± 0.2 | 54.8 ± 0.2 | 54.2 ± 0.1 | 53.8 ± 0.3
Mean cell hemoglobin (pg)
Day 23 | 18.6 ± 0.1 | 18.6 ± 0.1 | 18.6 ± 0.1 | 18.6 ± 0.1 | 18.2 ± 0.1* | 18.5 ± 0.1
Week 14 | 17.0 ± 0.1 | 17.3 ± 0.1 | 17.1 ± 0.1 | 17.1 ± 0.1 | 16.9 ± 0.1 | 16.8 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 23 | 31.6 ± 0.1 | 31.5 ± 0.1 | 31.3 ± 0.2 | 31.6 ± 0.1 | 31.2 ± 0.1 | 31.3 ± 0.2
Week 14 | 31.4 ± 0.2 | 31.9 ± 0.2 | 31.3 ± 0.1 | 31.3 ± 0.2 | 31.2 ± 0.1 | 31.3 ± 0.2
Platelets (10^3^/μL)
Day 23 | 862 ± 41 | 866 ± 48 | 837 ± 38 | 910 ± 30 | 924 ± 19 | 918 ± 51
Week 14 | 862 ± 12 | 853 ± 16 | 832 ± 28 | 862 ± 28 | 875 ± 20 | 856 ± 27
Leukocytes (10^3^/μL)
Day 23 | 8.84 ± 0.43 | 9.39 ± 0.47 | 9.08 ± 0.51 | 8.46 ± 0.37 | 9.58 ± 0.57 | 7.19 ± 0.37
Week 14 | 8.55 ± 0.34 | 8.29 ± 0.32 | 8.18 ± 0.49 | 9.19 ± 0.38 | 8.41 ± 0.37 | 8.44 ± 0.43
Segmented neutrophils (10^3^/μL)
Day 23 | 1.35 ± 0.08 | 1.45 ± 0.11 | 1.36 ± 0.11 | 1.12 ± 0.10 | 1.33 ± 0.13 | 1.09 ± 0.07
Week 14 | 1.34 ± 0.10 | 1.39 ± 0.08 | 1.36 ± 0.08 | 1.67 ± 0.11 | 1.35 ± 0.07 | 1.30 ± 0.11
Lymphocytes (10^3^/μL)
Day 23 | 6.98 ± 0.38 | 7.45 ± 0.38 | 7.26 ± 0.54 | 6.95 ± 0.37 | 7.79 ± 0.48 | 5.75 ± 0.30
Week 14 | 6.84 ± 0.26 | 6.52 ± 0.27 | 6.47 ± 0.42 | 7.08 ± 0.32 | 6.72 ± 0.33 | 6.78 ± 0.31
Monocytes (10^3^/μL)
Day 23 | 0.22 ± 0.02 | 0.23 ± 0.02 | 0.22 ± 0.02 | 0.19 ± 0.03 | 0.22 ± 0.02 | 0.17 ± 0.03
Week 14 | 0.23 ± 0.01 | 0.23 ± 0.02 | 0.23 ± 0.02 | 0.28 ± 0.02 | 0.24 ± 0.02 | 0.22 ± 0.02
Basophils (10^3^/μL)
Day 23 | 0.206 ± 0.023 | 0.191 ± 0.028 | 0.145 ± 0.027 | 0.118 ± 0.018 | 0.164 ± 0.025 | 0.109 ± 0.011**
Week 14 | 0.071 ± 0.010 | 0.070 ± 0.005 | 0.060 ± 0.007 | 0.079 ± 0.012 | 0.044 ± 0.004 | 0.059 ± 0.010
Eosinophils (10^3^/μL)
Day 23 | 0.09 ± 0.01 | 0.07 ± 0.00 | 0.09 ± 0.02 | 0.08 ± 0.02 | 0.08 ± 0.01 | 0.07 ± 0.01
Week 14 | 0.07 ± 0.01 | 0.09 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.00 | 0.07 ± 0.01
Clinical Chemistry
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 23 | 8 | 10 | 10 | 9 | 10 | 10
Week 14 | 10 | 9 | 10 | 10 | 9 | 10
Urea nitrogen (mg/dL)
Day 4 | 11.0 ± 0.7^e^ | 8.8 ± 0.7 | 9.8 ± 0.7^b^ | 8.9 ± 0.7^c^ | 7.8 ± 0.5*^f^ | 10.1 ± 0.7^e^
Day 23 | 13.6 ± 0.5 | 11.7 ± 0.7^e^ | 13.4 ± 0.5^e^ | 11.6 ± 0.6 | 13.0 ± 0.6^c^ | 12.8 ± 0.7^g^
Week 14 | 13.0 ± 0.4 | 14.7 ± 0.3 | 12.5 ± 0.5 | 13.2 ± 0.4 | 11.6 ± 0.6 | 13.2 ± 0.4
Creatinine (mg/dL)
Day 4 | 0.44 ± 0.03^e^ | 0.45 ± 0.02 | 0.41 ± 0.03^b^ | 0.44 ± 0.02^c^ | 0.48 ± 0.03^f^ | 0.43 ± 0.04^e^
Day 23 | 0.55 ± 0.02 | 0.51 ± 0.01^e^ | 0.54 ± 0.02^e^ | 0.52 ± 0.01 | 0.54 ± 0.02^c^ | 0.56 ± 0.02^g^
Week 14 | 0.68 ± 0.01 | 0.67 ± 0.02 | 0.66 ± 0.02 | 0.66 ± 0.02 | 0.68 ± 0.01 | 0.69 ± 0.01
Glucose (mg/dL)
Day 4 | 121 ± 4^e^ | 125 ± 2 | 120 ± 3^b^ | 123 ± 2^c^ | 132 ± 5^f^ | 124 ± 3^e^
Day 23 | 179 ± 5 | 181 ± 8^e^ | 187 ± 5^d^ | 174 ± 5 | 182 ± 6^c^ | 173 ± 6^g^
Week 14 | 213 ± 5 | 214 ± 7 | 221 ± 6 | 200 ± 7 | 204 ± 6 | 191 ± 6*
Total protein (g/dL)
Day 4 | 6.0 ± 0.1^e^ | 5.7 ± 0.1^b^ | 5.9 ± 0.1^b^ | 5.8 ± 0.1^c^ | 5.8 ± 0.1^e^ | 5.9 ± 0.1^e^
Day 23 | 6.3 ± 0.1 | 6.3 ± 0.1^e^ | 6.5 ± 0.1^e^ | 6.2 ± 0.1 | 6.2 ± 0.1^c^ | 6.3 ± 0.2^g^
Week 14 | 7.1 ± 0.1 | 7.0 ± 0.1 | 7.1 ± 0.1 | 7.2 ± 0.1 | 7.2 ± 0.1 | 7.4 ± 0.1**
Albumin (g/dL)
Day 4 | 4.4 ± 0.1^e^ | 4.2 ± 0.1 | 4.3 ± 0.1^b^ | 4.3 ± 0.1^c^ | 4.3 ± 0.1^f^ | 4.3 ± 0.1^e^
Day 23 | 4.5 ± 0.1 | 4.5 ± 0.1^e^ | 4.7 ± 0.1^e^ | 4.5 ± 0.1 | 4.5 ± 0.1^c^ | 4.6 ± 0.1^g^
Week 14 | 4.9 ± 0.1 | 4.8 ± 0.1 | 4.9 ± 0.1 | 4.9 ± 0.1 | 5.0 ± 0.1 | 5.1 ± 0.1
Cholesterol (mg/dL)
Day 4 | 105 ± 3 | 98 ± 2 | 96 ± 8 | 102 ± 2 | 99 ± 2 | 107 ± 2
Day 23 | 95 ± 4 | 95 ± 5^c^ | 95 ± 4^c^ | 88 ± 3 | 88 ± 2 | 93 ± 3^b^
Week 14 | 82 ± 2 | 79 ± 2 | 83 ± 2 | 78 ± 2 | 83 ± 3 | 85 ± 2
Alanine aminotransferase (IU/L)
Day 4 | 58 ± 2 | 59 ± 2 | 55 ± 2 | 61 ± 2 | 61 ± 3 | 62 ± 1
Day 23 | 49 ± 1 | 49 ± 1^c^ | 47 ± 2^c^ | 46 ± 1 | 52 ± 1 | 52 ± 1^b^
Week 14 | 68 ± 4 | 65 ± 6 | 57 ± 2 | 56 ± 2* | 47 ± 1** | 58 ± 6**
Alkaline phosphatase (IU/L)
Day 4 | 589 ± 11 | 588 ± 15 | 593 ± 17 | 627 ± 22 | 665 ± 23* | 665 ± 20**
Day 23 | 423 ± 10 | 441 ± 12^c^ | 419 ± 17^c^ | 409 ± 8 | 443 ± 13 | 472 ± 10*^b^
Week 14 | 300 ± 10 | 314 ± 17 | 259 ± 7 | 238 ± 8** | 272 ± 10 | 282 ± 12
Creatine kinase (IU/L)
Day 4 | 426 ± 49^e^ | 614 ± 209 | 426 ± 104^b^ | 363 ± 49^c^ | 443 ± 99^f^ | 369 ± 40^e^
Day 23 | 163 ± 18 | 167 ± 14^e^ | 209 ± 16^e^ | 173 ± 19 | 176 ± 16^c^ | 215 ± 18^g^
Week 14 | 155 ± 37 | 105 ± 14 | 91 ± 8 | 120 ± 28 | 134 ± 24 | 203 ± 75
Sorbitol dehydrogenase (IU/L)
Day 4 | 11 ± 1 | 12 ± 1 | 14 ± 1 | 13 ± 1 | 14 ± 1 | 14 ± 1
Day 23 | 13 ± 1 | 11 ± 1c | 13 ± 1^c^ | 11 ± 0 | 11 ± 1 | 13 ± 1^b^
Week 14 | 22 ± 1 | 20 ± 2 | 17 ± 1* | 19 ± 1 | 15 ± 1** | 21 ± 3
Bile acids (µmol/L)
Day 4 | 7.2 ± 0.7 | 10.9 ± 1.4 | 13.9 ± 1.7 | 8.7 ± 1.1 | 40.5 ± 7.3** | 26.6 ± 7.7**
Day 23 | 8.1 ± 1.4 | 9.3 ± 1.4^c^ | 6.0 ± 1.0^c^ | 7.9 ± 2.5 | 18.1 ± 2.9 | 12.0 ± 1.0^b^
Week 14 | 30.3 ± 3.0 | 26.0 ± 3.4 | 27.4 ± 4.0 | 19.3 ± 2.5* | 20.2 ± 2.5* | 14.7 ± 1.8**
Total thyroxine (μg/dL)
Day 4 | 5.52 ± 0.16 | 5.63 ± 0.12 | 5.18 ± 0.22 | 4.52 ± 0.18** | 4.05 ± 0.27** | 3.87 ± 0.30**
Day 23 | 4.26 ± 0.25^d^ | 4.51 ± 0.26 | 4.05 ± 0.25 | 3.75 ± 0.30^d^ | 2.56 ± 0.25** | 2.64 ± 0.21**
Week 14 | 3.33 ± 0.22 | 3.58 ± 0.17^d^ | 3.07 ± 0.20 | 2.76 ± 0.19 | 1.83 ± 0.15**^d^ | 1.66 ± 0.10**
Total triiodothyronine (μg/dL)
Day 23 | 180.4 ± 8.1^d^ | 177.5 ± 11.9 | 180.5 ± 12.1 | 167.1 ± 5.5^d^ | 143.8 ± 3.7** | 168.1 ± 7.2
Week 14 | 116.2 ± 6.9^b^ | 115.8 ± 8.5 | 115.9 ± 10.7 | 128.3 ± 8.3 | 117.7 ± 7.2 | 113.1 ± 8.2^b^
Thyroid stimulating hormone (ng/dL)
Day 4 | 4.95 ± 0.48 | 5.00 ± 0.36 | 4.65 ± 0.29 | 4.77 ± 0.27 | 4.26 ± 0.18 | 3.89 ± 0.09*
Day 23 | 5.26 ± 0.29^b^ | 6.46 ± 0.42^b^ | 5.85 ± 0.33 | 5.16 ± 0.17^d^ | 5.06 ± 0.23 | 4.89 ± 0.18
Week 14 | 7.36 ± 0.39 | 7.47 ± 0.69^d^ | 7.79 ± 0.47 | 8.87 ± 0.64 | 7.65 ± 0.39^d^ | 7.00 ± 0.46

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 8.

^d^ n = 10.

^e^ n = 7.

^f^ n = 4.

^g^ n = 5.

Table F-2 Hematology Data for Mice in the Three-month Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 10 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg | 1,000 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Hematocrit (%) | 47.3 ± 0.9 | 45.7 ± 0.6 | 45.5 ± 0.7 | 46.1 ± 0.4 | 45.2 ± 0.3 | 45.6 ± 0.3
Hemoglobin (g/dL) | 15.9 ± 0.3 | 15.5 ± 0.2 | 15.3 ± 0.2 | 15.6 ± 0.2 | 15.3 ± 0.1 | 15.3 ± 0.1
Erythrocytes (10^6^/µL) | 10.63 ± 0.18 | 10.30 ± 0.14 | 10.18 ± 0.14 | 10.42 ± 0.09 | 10.26 ± 0.09 | 10.39 ± 0.05
Reticulocytes (10^6^/µL) | 0.28 ± 0.01 | 0.27 ± 0.01 | 0.27 ± 0.01 | 0.27 ± 0.01 | 0.28 ± 0.01 | 0.27 ± 0.01
Mean cell volume (fL) | 44.5 ± 0.2 | 44.3 ± 0.1 | 44.6 ± 0.3 | 44.2 ± 0.2 | 44.1 ± 0.2 | 44.0 ± 0.1
Mean cell hemoglobin (pg) | 15.0 ± 0.0 | 15.0 ± 0.1 | 15.0 ± 0.1 | 15.0 ± 0.1 | 14.9 ± 0.1 | 14.8 ± 0.1*
Mean cell hemoglobin concentration (g/dL) | 33.7 ± 0.1 | 33.9 ± 0.1 | 33.7 ± 0.1 | 34.0 ± 0.1 | 33.8 ± 0.1 | 33.6 ± 0.1
Platelets (10^3^/µL) | 1,053 ± 70 | 1,128 ± 51 | 1,086 ± 26 | 1,036 ± 67 | 1,213 ± 25* | 1,230 ± 20**
Leukocytes (10^3^/µL) | 4.60 ± 0.25 | 4.25 ± 0.20 | 4.25 ± 0.34 | 4.26 ± 0.38 | 4.62 ± 0.47 | 5.09 ± 0.44
Segmented neutrophils (10^3^/µL) | 0.70 ± 0.05 | 0.68 ± 0.05 | 0.63 ± 0.06 | 0.63 ± 0.06 | 0.69 ± 0.05 | 0.69 ± 0.07
Lymphocytes (10^3^/µL) | 3.68 ± 0.22 | 3.40 ± 0.17 | 3.43 ± 0.28 | 3.44 ± 0.35 | 3.72 ± 0.39 | 4.21 ± 0.37
Monocytes (10^3^/µL) | 0.10 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.10 ± 0.02 | 0.09 ± 0.01
Basophils (10^3^/µL) | 0.017 ± 0.003 | 0.015 ± 0.003 | 0.011 ± 0.002 | 0.017 ± 0.003 | 0.015 ± 0.003 | 0.019 ± 0.003
Eosinophils (10^3^/µL) | 0.11 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.02 | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.01
Female
Hematocrit (%) | 48.2 ± 0.7 | 50.2 ± 1.1 | 47.7 ± 0.6 | 49.4 ± 0.6 | 49.5 ± 1.0 | 47.6 ± 1.0
Hemoglobin (g/dL) | 16.4 ± 0.2 | 17.1 ± 0.3 | 16.2 ± 0.2 | 16.7 ± 0.2 | 16.9 ± 0.3 | 16.1 ± 0.3
Erythrocytes (10^6^/µL) | 10.67 ± 0.18 | 11.13 ± 0.22 | 10.57 ± 0.15 | 10.96 ± 0.11 | 11.00 ± 0.22 | 10.67 ± 0.19
Reticulocytes (10^6^/µL) | 0.27 ± 0.01 | 0.35 ± 0.01** | 0.31 ± 0.02 | 0.29 ± 0.01 | 0.28 ± 0.01 | 0.27 ± 0.02
Mean cell volume (fL) | 45.2 ± 0.3 | 45.1 ± 0.2 | 45.1 ± 0.2 | 45.1 ± 0.2 | 45.0 ± 0.1 | 44.6 ± 0.2
Mean cell hemoglobin (pg) | 15.4 ± 0.1 | 15.4 ± 0.1 | 15.3 ± 0.1 | 15.3 ± 0.1 | 15.4 ± 0.1 | 15.1 ± 0.1*
Mean cell hemoglobin concentration (g/dL) | 34.1 ± 0.2 | 34.1 ± 0.2 | 34.0 ± 0.1 | 33.9 ± 0.1 | 34.2 ± 0.2 | 33.8 ± 0.1
Platelets (10^3^/µL) | 697 ± 59 | 677 ± 80 | 796 ± 77 | 668 ± 41 | 709 ± 83 | 849 ± 91
Leukocytes (10^3^/µL) | 2.81 ± 0.26 | 2.94 ± 0.21 | 3.42 ± 0.29 | 3.38 ± 0.27 | 3.38 ± 0.42 | 3.28 ± 0.34
Segmented neutrophils (10^3^/µL) | 0.30 ± 0.07 | 0.29 ± 0.03 | 0.40 ± 0.09 | 0.37 ± 0.05 | 0.32 ± 0.06 | 0.33 ± 0.04
Lymphocytes (10^3^/µL) | 2.39 ± 0.20 | 2.56 ± 0.18 | 2.84 ± 0.21 | 2.87 ± 0.23 | 2.91 ± 0.35 | 2.85 ± 0.30
Monocytes (10^3^/µL) | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.00 | 0.05 ± 0.01 | 0.05 ± 0.01
Basophils (10^3^/µL) | 0.007 ± 0.002 | 0.009 ± 0.003 | 0.013 ± 0.003 | 0.010 ± 0.004 | 0.012 ± 0.003 | 0.008 ± 0.002
Eosinophils (10^3^/µL) | 0.07 ± 0.03 | 0.04 ± 0.02 | 0.11 ± 0.03 | 0.08 ± 0.03 | 0.08 ± 0.02 | 0.04 ± 0.02

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.