# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

Tetrabromobisphenol A was tested for bacterial mutagenicity in two independent tests. In the first, testing was performed as reported by Mortelmans et al.^77^ using a different lot of chemical than was used in the NTP animal studies. Briefly, tetrabromobisphenol A was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA98, TA100, TA1535, and TA1537 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37ºC. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37ºC.

In the second bacterial mutagenicity test, a sample of lot M032607KA of tetrabromobisphenol A that was used in the 2-year studies was sent to the testing laboratory for assessment of mutagenicity in S. typhimurium strains TA98 and TA100 and in Escherichia coli strain WP2 uvrA/pKM101. Incubation in either buffer or S9 mix (from induced Sprague Dawley rat liver) and plating on minimal glucose agar plates was carried out as described above. Histidine-independent (for the S. typhimurium strains) or tryptophan-independent (for the E. coli strain) mutant colonies arising on these plates were counted following incubation for 2 days at 37ºC.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of at least five doses of tetrabromobisphenol A. The high dose was limited by experimental design to 10,000 (first test) or 6,000 (second test) µg/plate. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold-increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

## E.2 Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.^179^ At the end of the 3-month toxicity study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in each of five animals per dose group. In addition, the percentage of polychromatic (immature) erythrocytes (PCEs) in a population of 1,000 erythrocytes in the peripheral blood was scored for each dose group as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the vehicle control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Results of the 3-month studies were accepted without repeat tests, because additional test data could not be obtained. Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## E.3 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgement of the overall evidence for activity of the chemical in an assay.

## E.4 Results

Tetrabromobisphenol A was tested for bacterial mutagenicity in two independent assays and results were negative in both assays. In the first assay, tetrabromobisphenol A (100 to 10,000 µg/plate) showed no evidence of mutagenicity in S. typhimurium strains TA98, TA100, TA1535, or TA1537, with or without exogenous metabolic activation from induced hamster or rat liver S9^77^ (Table E-1). In the second assay, conducted with the same lot of tetrabromobisphenol A that was used in the 2-year studies, no mutagenic activity was detected in S. typhimurium strains TA98 or TA100 or in E. coli strain WP2 uvrA; all tests were conducted with and without rat liver S9, and the highest concentration tested was 6,000 µg/plate (Table E-2). In vivo, no increases in micronucleated NCEs were observed in male or female B6C3F1/N mice following 3 months of administration of tetrabromobisphenol A by gavage over a dose range of 10 to 1,000 mg/kg (Table E-3). In addition, no significant changes in the percentage of circulating polychromatic (immature) erythrocytes were observed in dosed mice, suggesting that tetrabromobisphenol A did not induce bone marrow toxicity over the dose range tested.

Table E-1 Mutagenicity of Tetrabromobisphenol A in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% hamster S9 | With 10% hamster S9 | With 10% rat S9 | With 10% rat S9
TA100
| 0 | 105 ± 5 | 93 ± 4 | 104 ± 3 | 87 ± 3 | 112 ± 2 | 94 ± 9
| 100 | 99 ± 13 | 99 ± 13 | 95 ± 5 | 107 ± 4 | 125 ± 7 | 115 ± 9
| 333 | 110 ± 6^b^ | 74 ± 2^b^ | 91 ± 20 | 85 ± 6 | 114 ± 6 | 93 ± 10
| 1,000 | 90 ± 9^b^ | 78 ± 3^b^ | 86 ± 8^b^ | 69 ± 4^b^ | 97 ± 4^b^ | 84 ± 3^b^
| 3,333 | 88 ± 3^b^ | 79 ± 5^b^ | 79 ± 11^b^ | 79 ± 4^b^ | 92 ± 3^b^ | 96 ± 6^b^
| 10,000 | 100 ± 2^b^ | 76 ± 3^b^ | 98 ± 9^b^ | 77 ± 9^b^ | 78 ± 8^b^ | 90 ± 5^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control^c^ | | 372 ± 10 | 345 ± 18 | 1,521 ± 83 | 1,133 ± 40 | 645 ± 9 | 441 ± 9
TA1535
| 0 | 27 ± 3 | 28 ± 4 | 10 ± 2 | 6 ± 0 | 10 ± 1 | 10 ± 1
| 100 | 23 ± 2 | 26 ± 1 | 12 ± 1 | 9 ± 2 | 8 ± 2 | 8 ± 2
| 333 | 22 ± 1^b^ | 24 ± 3^b^ | 9 ± 2 | 8 ± 1 | 7 ± 1 | 7 ± 1
| 1,000 | 14 ± 2^b^ | 20 ± 1^b^ | 8 ± 1^b^ | 8 ± 1^b^ | 5 ± 2^b^ | 4 ± 0^b^
| 3,333 | 18 ± 1^b^ | 25 ± 3^b^ | 8 ± 3^b^ | 7 ± 1^b^ | 7 ± 1^b^ | 6 ± 1^b^
| 10,000 | 17 ± 3^b^ | 24 ± 2^b^ | 7 ± 1^b^ | 6 ± 1^b^ | 6 ± 0b | 9 ± 2^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 274 ± 13 | 324 ± 21 | 344 ± 9 | 452 ± 10 | 159 ± 20 | 187 ± 10
TA1537
| 0 | 4 ± 1 | 7 ± 3 | 5 ± 1 | 6 ± 2 | 6 ± 1 | 3 ± 1
| 100 | 4 ± 1 | 5 ± 0 | 6 ± 2 | 10 ± 3 | 8 ± 1 | 10 ± 3
| 333 | 4 ± 1^b^ | 4 ± 0^b^ | 4 ± 1 | 5 ± 1 | 8 ± 1 | 8 ± 1
| 1,000 | 3 ± 0^b^ | 4 ± 1^b^ | 4 ± 1^b^ | 5 ± 2^b^ | 3 ± 0^b^ | 7 ± 1^b^
| 3,333 | 4 ± 1^b^ | 4 ± 1^b^ | 3 ± 0^b^ | 4 ± 1^b^ | 3 ± 0^b^ | 4 ± 0^b^
| 10,000 | 4 ± 1^b^ | 3 ± 1^b^ | 4 ± 0^b^ | 7 ± 1^b^ | 5 ± 1^b^ | 6 ± 1^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 192 ± 6 | 154 ± 24 | 342 ± 12 | 339 ± 18 | 108 ± 4 | 105 ± 6
TA98
| 0 | 19 ± 1 | 15 ± 2 | 17 ± 1 | 30 ± 1 | 25 ± 2 | 25 ± 4
| 100 | 18 ± 1 | 14 ± 1 | 28 ± 3 | 35 ± 3 | 26 ± 7 | 38 ± 3
| 333 | 16 ± 1^b^ | 12 ± 3^b^ | 24 ± 2 | 18 ± 1 | 24 ± 3 | 20 ± 5
| 1,000 | 12 ± 2^b^ | 12 ± 1^b^ | 13 ± 0^b^ | 20 ± 3^b^ | 17 ± 3^b^ | 20 ± 3^b^
| 3,333 | 15 ± 3^b^ | 12 ± 2^b^ | 11 ± 1^b^ | 15 ± 2^b^ | 15 ± 2^b^ | 15 ± 3^b^
| 10,000 | 16 ± 2^b^ | 11 ± 0^b^ | 14 ± 3^b^ | 23 ± 3^b^ | 16 ± 1^b^ | 13 ± 1^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 844 ± 37 | 354 ± 31 | 1,665 ± 37 | 1,444 ± 62 | 541 ± 11 | 404 ± 30

^a^ Study performed at SRI International. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol and these data are presented by Mortelmans et al.^77^ 0 μg/plate was the solvent control.

^b^ Precipitate on plate.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA1537), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-2 Mutagenicity of Tetrabromobisphenol A in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% rat S9 | With 10% rat S9
TA100
| 0 | 69 ± 3 | 87 ± 7 | 91 ± 9 | 87 ± 1
| 50 | 62 ± 2 | 59 ± 4 | 74 ± 3 | –
| 100 | 54 ± 2 | 48 ± 4 | 70 ± 2 | 85 ± 4
| 250 | 37 ± 2^b^ | 42 ± 7 | 62 ± 7 | 68 ± 4
| 500 | 37 ± 8^b^ | 33 ± 5^b^ | 43 ± 4 | 55 ± 3
| 1,000 | 14 ± 0^c^ | 26 ± 4^b^ | 52 ± 5 | 49 ± 3
| 3,000 | 20 ± 7^c^ | 49 ± 3^b^ | 53 ± 8^b^ | 33 ± 4^b^
| 6,000 | – | – | – | 58 ± 6^b^
Trial summary | | Negative | Negative | Negative | Negative
Positive control^d^ | | 470 ± 10 | 524 ± 14 | 750 ± 21 | 491 ± 34
TA98
| 0 | 18 ± 4 | 20 ± 2 | 23 ± 4 | 16 ± 2
| 50 | 15 ± 1 | 21 ± 2 | 24 ± 4 | –
| 100 | 11 ± 1 | 16 ± 3 | 23 ± 4 | 24 ± 3
| 250 | 13 ± 1 | 13 ± 2 | 21 ± 1 | 18 ± 4
| 500 | 6 ± 1^b^ | 12 ± 1^b^ | 15 ± 1 | 15 ± 1
| 1,000 | 9 ± 2^b^ | 9 ± 4^b^ | 21 ± 2 | 14 ± 2
| 3,000 | 8 ± 1^b^ | 12 ± 5^b^ | 12 ± 1^b^ | 8 ± 1^b^
| 6,000 | – | – | – | 8 ± 0^b^
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 528 ± 31 | 629 ± 17 | 1,878 ± 79 | 1,078 ± 55
Escherichia coli WP2 uvrA/pKM101 (analogous to TA102)
| 0 | 138 ± 8 | 128 ± 8 | 118 ± 6 | 187 ± 11
| 50 | – | 166 ± 13 | 119 ± 5 | –
| 100 | 112 ± 2 | 155 ± 13 | 113 ± 9 | 165 ± 4
| 250 | 114 ± 3^b^ | 161 ± 9 | 103 ± 11 | 184 ± 13
| 500 | 112 ± 15^b^ | 127 ± 27 | 121 ± 12^b^ | 159 ± 6
| 1,000 | 95 ± 4^b^ | 102 ± 4 | 78 ± 6^b^ | 131 ± 3
| 3,000 | 120 ± 9^b^ | 94 ± 8^b^ | 98 ± 8^b^ | 117 ± 8^b^
| 6,000 | 143 ± 2^b^ | – | – | 122 ± 9^b^
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 1,450 ± 73 | 1,123 ± 65 | 1,399 ± 20 | 1,286 ± 39

^a^ Study was performed at ILS, Inc., using lot M032607KA. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ Precipitate on plate.

^c^ Slight toxicity and precipitate on plate.

^d^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Treatment with Tetrabromobisphenol A by Gavage for Three Months^a^

| Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Corn oil^d^ | 0 | 5 | 1.70 ± 0.75 | – | 2.54 ± 0.31
Tetrabromobisphenol A | 10 | 5 | 1.20 ± 0.30 | 0.7426 | 2.98 ± 0.38
| 50 | 5 | 1.70 ± 0.82 | 0.5000 | 2.72 ± 0.25
| 100 | 5 | 2.90 ± 0.68 | 0.1072 | 3.04 ± 0.32
| 500 | 5 | 2.50 ± 0.76 | 0.1932 | 3.88 ± 0.40
| 1,000 | 5 | 1.90 ± 0.24 | 0.4075 | 2.70 ± 0.37
| | | P = 0.334^e^
Female
Corn oil | 0 | 5 | 1.00 ± 0.27 | – | 3.16 ± 0.25
Tetrabromobisphenol A | 10 | 5 | 1.60 ± 0.51 | 0.1195 | 2.90 ± 0.47
| 50 | 5 | 1.20 ± 0.41 | 0.3348 | 3.34 ± 0.56
| 100 | 5 | 1.10 ± 0.29 | 0.4136 | 2.84 ± 0.14
| 500 | 5 | 1.60 ± 0.19 | 0.1195 | 2.98 ± 0.16
| 1,000 | 5 | 1.20 ± 0.41 | 0.3348 | 2.30 ± 0.31
| | | P = 0.431

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^179^ NCE=normochromatic erythrocyte; PCE=polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at P ≤ 0.005.

^d^ Vehicle control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.