# Appendix D Summary of Lesions in Female Mice in the Two-year Gavage Study of Tetrabromobisphenol A

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths | – | – | – | –
Accidental death | – | – | – | 1
Moribund | 6 | 8 | 3 | 7
Natural deaths | 4 | 11 | 11 | 38
Survivors
Terminal kill | 40 | 31 | 36 | 4
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (47) | (49) | (50) | (50)
Intestine large, cecum | (48) | (46) | (45) | (21)
Leiomyoma | – | 1 (2%) | – | –
Intestine large, colon | (50) | (48) | (50) | (43)
Intestine large, rectum | (50) | (50) | (50) | (41)
Adenoma | – | – | 1 (2%) | –
Intestine small, duodenum | (47) | (46) | (42) | (18)
Adenoma | 1 (2%) | – | – | –
Carcinoma | – | 1 (2%) | – | –
Intestine small, ileum | (48) | (46) | (45) | (19)
Intestine small, jejunum | (48) | (47) | (43) | (18)
Liver | (50) | (50) | (49) | (49)
Hemangioma | – | – | 2 (4%) | –
Hemangiosarcoma | – | 1 (2%) | – | –
Hepatocellular adenoma | 12 (24%) | 9 (18%) | 11 (22%) | 1 (2%)
Hepatocellular adenoma, multiple | 1 (2%) | 4 (8%) | 4 (8%) | –
Hepatocellular carcinoma | 2 (4%) | 3 (6%) | 5 (10%) | 1 (2%)
Hepatocellular carcinoma, multiple | – | 1 (2%) | – | –
Squamous cell carcinoma, metastatic, stomach, forestomach | – | 1 (2%) | – | –
Mesentery | (3) | (8) | (7) | (0)
Oral mucosa | (1) | (0) | (0) | (0)
Squamous cell carcinoma | 1 (100%) | – | – | –
Pancreas | (50) | (49) | (50) | (50)
Salivary glands | (50) | (48) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (48)
Squamous cell carcinoma | – | 1 (2%) | – | –
Squamous cell carcinoma, multiple | – | 1 (2%) | – | –
Stomach, glandular | (50) | (50) | (50) | (50)
Tongue | (1) | (0) | (0) | (0)
Squamous cell papilloma | 1 (100%) | – | – | –
Tooth | (1) | (1) | (1) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (49) | (50)
Heart | (50) | (50) | (50) | (50)
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (50)
Adrenal medulla | (50) | (50) | (49) | (50)
Pheochromocytoma benign | 1 (2%) | – | – | –
Islets, pancreatic | (50) | (49) | (50) | (50)
Parathyroid gland | (34) | (41) | (42) | (43)
Pituitary gland | (50) | (50) | (50) | (49)
Pars distalis, adenoma | 1 (2%) | – | – | –
Pars intermedia, adenoma | – | – | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, carcinoma | – | – | 1 (2%) | –
Follicular cell, adenoma | – | – | 1 (2%) | –
General Body System
Peritoneum | (0) | (1) | (0) | (0)
Genital System
Clitoral gland | (50) | (50) | (49) | (48)
Ovary | (50) | (50) | (50) | (47)
Cystadenoma | 2 (4%) | – | 1 (2%) | 2 (4%)
Granulosa cell tumor malignant | – | – | 1 (2%) | –
Luteoma | – | 1 (2%) | – | –
Oviduct | (1) | (0) | (1) | (0)
Uterus | (50) | (50) | (50) | (50)
Polyp stromal | – | 1 (2%) | 1 (2%) | –
Sarcoma stromal | 1 (2%) | – | 1 (2%) | –
Cervix, sarcoma stromal | 1 (2%) | – | – | –
Vagina | (0) | (1) | (0) | (0)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (1) | (5) | (3) | (1)
Pancreatic, granulosa cell tumor malignant, metastatic, ovary | – | – | 1 (33%) | –
Lymph node, mandibular | (50) | (48) | (48) | (46)
Lymph node, mesenteric | (50) | (50) | (50) | (47)
Spleen | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | – | – | –
Thymus | (50) | (50) | (48) | (50)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Fibroadenoma | – | – | 1 (2%) | –
Skin | (50) | (50) | (50) | (50)
Basal cell carcinoma | 1 (2%) | – | – | –
Fibrosarcoma | 1 (2%) | – | – | –
Fibrous histiocytoma | | 1 (2%) | – | –
Hemangioma | 1 (2%) | – | – | –
Schwannoma malignant | – | – | 1 (2%) | –
Squamous cell papilloma | – | – | – | 1 (2%)
Subcutaneous tissue, hemangiosarcoma | 1 (2%) | – | – | –
Subcutaneous tissue, sarcoma | | – | – | 1 (2%)
Subcutaneous tissue, schwannoma malignant | 1 (2%) | – | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibroma | 1 (2%) | – | – | –
Osteosarcoma | – | 1 (2%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 5 (10%) | 2 (4%) | 1 (2%) | –
Alveolar/bronchiolar carcinoma | 1 (2%) | – | – | –
Schwannoma malignant, metastatic, skin | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (49) | (50) | (50)
Adenoma | 2 (4%) | 6 (12%) | 3 (6%) | 1 (2%)
Carcinoma | 1 (2%) | 1 (2%) | 2 (4%) | –
Urinary System
Kidney | (50) | (50) | (50) | (47)
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | 2 (4%) | – | –
Leukemia mononuclear | – | 1 (2%) | – | –
Lymphoma malignant | 9 (18%) | 4 (8%) | 4 (8%) | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 32 | 32 | 28 | 6
Total primary neoplasms | 50 | 42 | 42 | 8
Total animals with benign neoplasms | 22 | 23 | 21 | 5
Total benign neoplasms | 28 | 24 | 27 | 5
Total animals with malignant neoplasms | 18 | 17 | 15 | 2
Total malignant neoplasms | 22 | 18 | 15 | 3
Total animals with metastatic neoplasms | – | 2 | 2 | –
Total metastatic neoplasms | – | 2 | 2 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg
Harderian Gland: Adenoma
Overall rate^b^ | 2/50 (4%) | 6/50 (12%) | 3/50 (6%)
Adjusted rate^c^ | 4.2% | 13.0% | 6.7%
Terminal rate^d^ | 1/40 (3%) | 4/31 (13%) | 2/36 (6%)
First incidence (days) | 438 | 556 | 669
Poly-3 test^e^ | P = 0.378 | P = 0.122 | P = 0.469
Harderian Gland: Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 7/50 (14%) | 4/50 (8%)
Adjusted rate | 6.3% | 15.2% | 8.8%
Terminal rate | 2/40 (5%) | 5/31 (16%) | 2/36 (6%)
First incidence (days) | 438 | 556 | 486
Poly-3 test | P = 0.393 | P = 0.143 | P = 0.472
Liver: Hepatocellular Adenoma
Overall rate | 13/50 (26%) | 13/50 (26%) | 15/49 (31%)
Adjusted rate | 27.3% | 28.2% | 33.8%
Terminal rate | 9/40 (23%) | 9/31 (29%) | 14/36 (39%)
First incidence (days) | 663 | 619 | 688
Poly-3 test | P = 0.289 | P = 0.552 | P = 0.326
Liver: Hepatocellular Carcinoma
Overall rate | 2/50 (4%) | 4/50 (8%) | 5/49 (10%)
Adjusted rate | 4.3% | 8.8% | 11.1%
Terminal rate | 2/40 (5%) | 3/31 (10%) | 3/36 (8%)
First incidence (days) | 729 (T) | 718 | 552
Poly-3 test | P = 0.154 | P = 0.322 | P = 0.200
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 15/50 (30%) | 14/50 (28%) | 18/49 (37%)
Adjusted rate | 31.5% | 30.4% | 39.7%
Terminal rate | 11/40 (28%) | 10/31 (32%) | 15/36 (42%)
First incidence (days) | 663 | 619 | 552
Poly-3 test | P = 0.237 | P = 0.543N | P = 0.271
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 5/50 (10%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 10.4% | 4.4% | 2.3%
Terminal rate | 3/40 (8%) | 2/31 (7%) | 1/36 (3%)
First incidence (days) | 563 | 729 (T) | 729 (T)
Poly-3 test | P = 0.070N | P = 0.239N | P = 0.120N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 6/50 (12%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 12.5% | 4.4% | 2.3%
Terminal rate | 3/40 (8%) | 2/31 (7%) | 1/36 (3%)
First incidence (days) | 563 | 729 (T) | 729 (T)
Poly-3 test | P = 0.034N | P = 0.152N | P = 0.069N
All Organs: Malignant Lymphoma
Overall rate | 9/50 (18%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 19.1% | 8.8% | 8.9%
Terminal rate | 9/40 (23%) | 3/31 (10%) | 3/36 (8%)
First incidence (days) | 729 (T) | 694 | 669
Poly-3 test | P = 0.089N | P = 0.128N | P = 0.135N
All Organs: Benign Neoplasms
Overall rate | 22/50 (44%) | 23/50 (46%) | 21/50 (42%)
Adjusted rate | 44.6% | 49.2% | 46.4%
Terminal rate | 15/40 (38%) | 17/31 (55%) | 18/36 (50%)
First incidence (days) | 438 | 556 | 624
Poly-3 test | P = 0.467 | P = 0.404 | P = 0.514
All Organs: Malignant Neoplasms
Overall rate | 18/50 (36%) | 17/50 (34%) | 15/50 (30%)
Adjusted rate | 37.3% | 36.0% | 32.0%
Terminal rate | 13/40 (33%) | 8/31 (26%) | 9/36 (25%)
First incidence (days) | 606 | 526 | 486
Poly-3 test | P = 0.333N | P = 0.530N | P = 0.371N
All Organs: Benign or Malignant Neoplasms
Overall rate | 32/50 (64%) | 32/50 (64%) | 28/50 (56%)
Adjusted rate | 64.0% | 66.2% | 59.3%
Terminal rate | 22/40 (55%) | 19/31 (61%) | 21/36 (58%)
First incidence (days) | 438 | 526 | 486
Poly-3 test | P = 0.359N | P = 0.495 | P = 0.392N

(T) Terminal kill.

^a^ Due to early mortality, lesion incidences for the 1,000 mg/kg group are not presented.

^b^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver and lung; for other tissues, denominator is number of animals necropsied.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal kill.

^e^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

Table D-3 Summary of the Incidence of Non-neoplastic Lesions in Female Mice in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths | – | – | – | –
Accidental death | – | – | – | 1
Moribund | 6 | 8 | 3 | 7
Natural deaths | 4 | 11 | 11 | 38
Survivors | – | – | – | –
Terminal kill | 40 | 31 | 36 | 4
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)
Periesophageal tissue, inflammation | – | – | – | 1 (2%)
Gallbladder | (47) | (49) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
Intestine large, cecum | (48) | (46) | (45) | (21)
Lymphoid tissue, hyperplasia | – | – | 1 (2%) | 1 (5%)
Intestine large, colon | (50) | (48) | (50) | (43)
Serosa, inflammation | 1 (2%) | – | – | –
Intestine large, rectum | (50) | (50) | (50) | (41)
Intestine small, duodenum | (47) | (46) | (42) | (18)
Perforation | – | – | – | 1 (6%)
Epithelium, vacuolization cytoplasmic | 1 (2%) | – | – | –
Intestine small, ileum | (48) | (46) | (45) | (19)
Ulcer | 1 (2%) | – | 1 (2%) | –
Intestine small, jejunum | (48) | (47) | (43) | (18)
Diverticulum | 1 (2%) | – | – | –
Epithelium, vacuolization cytoplasmic | 1 (2%) | – | – | –
Peyer’s patch, hyperplasia | 2 (4%) | – | – | –
Liver | (50) | (50) | (49) | (49)
Angiectasis | – | 1 (2%) | 3 (6%) | –
Basophilic focus | 8 (16%) | 3 (6%) | 3 (6%) | 1 (2%)
Clear cell focus | 3 (6%) | 4 (8%) | 3 (6%) | 2 (4%)
Eosinophilic focus | 11 (22%) | 16 (32%) | 11 (22%) | 1 (2%)
Fatty change | 6 (12%) | 1 (2%) | 1 (2%) | 2 (4%)
Fatty change, focal | – | 1 (2%) | 3 (6%) | –
Fibrosis | – | – | – | 1 (2%)
Hematopoietic cell proliferation | – | 2 (4%) | 1 (2%) | –
Infiltration cellular, lymphocyte | 1 (2%) | – | – | –
Infiltration cellular, polymorphonuclear | – | 1 (2%) | – | –
Inflammation, chronic active | – | 5 (10%) | 1 (2%) | –
Mineralization | – | – | 1 (2%) | –
Mixed cell focus | 4 (8%) | 3 (6%) | 3 (6%) | –
Tension lipidosis | 4 (8%) | 3 (6%) | 4 (8%) | 2 (4%)
Hepatocyte, atrophy | – | 1 (2%) | – | –
Hepatocyte, hypertrophy | – | – | 1 (2%) | –
Hepatocyte, necrosis | 3 (6%) | 1 (2%) | 1 (2%) | –
Mesentery | (3) | (8) | (7) | (0)
Degeneration, cystic | 1 (33%) | – | – | –
Inflammation, focal | – | 1 (13%) | – | –
Fat, inflammation | 1 (33%) | – | – | –
Fat, necrosis | 2 (67%) | 6 (75%) | 7 (100%) | –
Oral mucosa | (1) | (0) | (0) | (0)
Pancreas | (50) | (49) | (50) | (50)
Basophilic focus | – | – | 1 (2%) | –
Infiltration cellular, lymphocyte | – | – | 1 (2%) | –
Inflammation | 1 (2%) | – | – | –
Acinus, atrophy | – | – | – | 2 (4%)
Salivary glands | (50) | (48) | (50) | (50)
Atrophy | – | – | 1 (2%) | –
Stomach, forestomach | (50) | (50) | (50) | (48)
Foreign body | – | – | – | 1 (2%)
Hyperkeratosis | 2 (4%) | 2 (4%) | 1 (2%) | 1 (2%)
Infiltration cellular, mononuclear cell | 2 (4%) | 13 (26%) | 33 (66%) | 28 (58%)
Inflammation | 2 (4%) | 14 (28%) | 41 (82%) | 37 (77%)
Ulcer | 2 (4%) | 15 (30%) | 40 (80%) | 38 (79%)
Epithelium, dysplasia | – | – | 2 (4%) | –
Epithelium, hyperplasia | 4 (8%) | 16 (32%) | 39 (78%) | 39 (81%)
Epithelium, metaplasia, glandular | – | – | 2 (4%) | –
Stomach, glandular | (50) | (50) | (50) | (50)
Infiltration cellular, mononuclear cell | – | 1 (2%) | – | –
Mineralization | 1 (2%) | – | – | 1 (2%)
Epithelium, dysplasia | – | – | 1 (2%) | –
Serosa, infiltration cellular, lymphocyte | 1 (2%) | – | – | –
Tongue | (1) | (0) | (0) | (0)
Tooth | (1) | (1) | (1) | (0)
Dysplasia | 1 (100%) | 1 (100%) | 1 (100%) | –
Cardiovascular System
Blood vessel | (50) | (50) | (49) | (50)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 2 (4%) | 5 (10%) | 5 (10%) | –
Mineralization | – | 2 (4%) | 1 (2%) | –
Epicardium, inflammation | 2 (4%) | – | – | –
Valve, inflammation | 1 (2%) | 1 (2%) | 1 (2%) | –
Valve, pigmentation, hemosiderin | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (50)
Atrophy | – | 1 (2%) | – | –
Degeneration, cystic | 1 (2%) | – | – | –
Hematopoietic cell proliferation | – | 1 (2%) | – | –
Hyperplasia | 1 (2%) | – | – | –
Hypertrophy | 1 (2%) | – | – | –
Adrenal medulla | (50) | (50) | (49) | (50)
Hyperplasia | 1 (2%) | – | 1 (2%) | –
Islets, pancreatic | (50) | (49) | (50) | (50)
Hyperplasia | 1 (2%) | – | – | 1 (2%)
Parathyroid gland | (34) | (41) | (42) | (43)
Hyperplasia, focal | – | – | 1 (2%) | –
Pituitary gland | (50) | (50) | (50) | (49)
Pigmentation, hemosiderin | 1 (2%) | – | – | –
Pars distalis, hyperplasia | – | 1 (2%) | – | 1 (2%)
Thyroid gland | (50) | (50) | (50) | (50)
Infiltration cellular, lymphocyte | – | – | 1 (2%) | –
C-cell, hyperplasia | – | 1 (2%) | – | –
Follicle, cyst | – | 1 (2%) | – | –
Follicular cell, hyperplasia | 1 (2%) | – | – | –
General Body System
Peritoneum | (0) | (1) | (0) | (0)
Inflammation, suppurative | – | 1 (100%) | – | –
Genital System
Clitoral gland | (50) | (50) | (49) | (48)
Ovary | (50) | (50) | (50) | (47)
Angiectasis | – | 3 (6%) | 1 (2%) | 1 (2%)
Cyst | – | – | 2 (4%) | –
Hemorrhage | 2 (4%) | – | – | –
Inflammation | – | 2 (4%) | 2 (4%) | –
Thrombosis | – | 1 (2%) | 1 (2%) | –
Bursa, cyst | 2 (4%) | | 1 (2%) | 1 (2%)
Follicle, cyst | 7 (14%) | 6 (12%) | 4 (8%) | 1 (2%)
Periovarian tissue, necrosis | 1 (2%) | – | – | –
Oviduct | (1) | (0) | (1) | (0)
Inflammation | 1 (100%) | – | 1 (100%)
Uterus | (50) | (50) | (50) | (50)
Dilatation | – | – | 1 (2%) | –
Inflammation | 2 (4%) | 1 (2%) | – | –
Thrombosis | 1 (2%) | – | 1 (2%) | –
Cervix, inflammation | – | 1 (2%) | – | –
Endometrium, hyperplasia, cystic | 35 (70%) | 35 (70%) | 29 (58%) | 22 (44%)
Vagina | (0) | (1) | (0) | (0)
Epithelium, necrosis | – | 1 (100%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hyperplasia | 4 (8%) | 3 (6%) | 2 (4%)
Myeloid cell, hyperplasia | – | 3 (6%) | – | –
Lymph node | (1) | (5) | (3) | (1)
Mediastinal, hyperplasia, lymphoid | 1 (100%) | 1 (20%) | – | –
Mediastinal, inflammation | – | – | – | 1 (100%)
Mediastinal, necrosis, lymphoid | – | – | – | 1 (100%)
Renal, ectasia | – | – | 1 (33%) | –
Renal, hemorrhage | – | – | 1 (33%) | –
Lymph node, mandibular | (50) | (48) | (48) | (46)
Atrophy | – | – | – | 1 (2%)
Infiltration cellular, plasma cell | 1 (2%) | – | – | –
Lymph node, mesenteric | (50) | (50) | (50) | (47)
Atrophy | – | – | 1 (2%) | –
Ectasia | – | – | 1 (2%) | –
Hyperplasia, lymphoid | 1 (2%) | – | 1 (2%) | –
Spleen | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | 2 (4%) | –
Hematopoietic cell proliferation | 5 (10%) | 4 (8%) | 3 (6%) | 2 (4%)
Hyperplasia, lymphoid | 10 (20%) | 4 (8%) | 6 (12%) | 4 (8%)
Pigmentation, hemosiderin | 1 (2%) | 1 (2%) | – | –
Lymphoid follicle, atrophy | 2 (4%) | 1 (2%) | 1 (2%) | 3 (6%)
Thymus | (50) | (50) | (48) | (50)
Atrophy | 29 (58%) | 24 (48%) | 21 (44%) | 29 (58%)
Hyperplasia, lymphoid | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
Skin | (50) | (50) | (50) | (50)
Ulcer | 1 (2%) | – | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 31 (62%) | 19 (38%) | 10 (20%) | 6 (12%)
Osteopetrosis | 1 (2%) | – | – | –
Osteosclerosis | – | – | 1 (2%) | –
Joint, degeneration | 3 (6%) | 1 (2%) | 1 (2%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Infiltration cellular, mononuclear cell | – | – | 1 (2%) | –
Cerebrum, neuron, necrosis | – | 1 (2%) | – | –
Meninges, infiltration cellular, lymphocyte | – | – | 1 (2%) | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Foreign body | 1 (2%) | – | – | –
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Infiltration cellular, histiocyte | 2 (4%) | – | – | –
Infiltration cellular, lymphocyte | 1 (2%) | – | 1 (2%) | –
Inflammation | 1 (2%) | 1 (2%) | 1 (2%) | –
Pigmentation, hemosiderin | – | 1 (2%) | – | –
Alveolar epithelium, hyperplasia | 1 (2%) | – | 2 (4%) | 1 (2%)
Interstitium, fibrosis | – | 1 (2%) | – | –
Serosa, hyperplasia | – | – | 1 (2%) | –
Serosa, inflammation | 1 (2%) | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | 3 (6%) | 2 (4%) | –
Respiratory epithelium, hyperplasia | 8 (16%) | 3 (6%) | 1 (2%) | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | –
Cataract | – | – | 1 (2%) | –
Hemorrhage | – | 1 (2%) | – | –
Synechia | – | – | 1 (2%) | –
Cornea, inflammation | – | 2 (4%) | 2 (4%) | –
Harderian gland | (50) | (49) | (50) | (50)
Hyperplasia | – | 1 (2%) | 1 (2%) | –
Epithelium, hyperplasia | 1 (2%) | – | – | –
Urinary System
Kidney | (50) | (50) | (50) | (47)
Angiectasis | – | – | 1 (2%) | –
Infarct | 1 (2%) | – | – | –
Infiltration cellular, lymphocyte | 2 (4%) | – | 1 (2%) | –
Metaplasia, osseous | 1 (2%) | – | – | –
Nephropathy | 18 (36%) | 11 (22%) | 23 (46%) | 26 (55%)
Papilla, mineralization | 1 (2%) | – | 1 (2%) | –
Papilla, necrosis | 2 (4%) | – | – | –
Renal tubule, cyst | – | – | 2 (4%) | 2 (4%)
Renal tubule, mineralization | – | 3 (6%) | 1 (2%) | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.