# Appendix C Summary of Lesions in Male Mice in the Two-year Gavage Study of Tetrabromobisphenol A

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 25 mg/kg | 500 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | – | – | 1
Moribund | 9 | 10 | 6 | 12
Natural deaths | 8 | 14 | 5 | 25
Survivors
Died last week of study | 1 | 1 | – | –
Terminal kill | 32 | 25 | 39 | 12
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (49) | (46) | (50) | (49)
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Intestine large, cecum | (47) | (44) | (47) | (38)
Carcinoma | – | – | 1 (2%) | –
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Intestine large, colon | (47) | (46) | (50) | (40)
Adenoma | – | – | 1 (2%) | –
Carcinoma | – | – | 1 (2%) | –
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Intestine large, rectum | (47) | (46) | (50) | (41)
Intestine small, duodenum | (47) | (41) | (48) | (31)
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Intestine small, ileum | (47) | (43) | (50) | (40)
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Intestine small, jejunum | (47) | (44) | (49) | (38)
Adenoma | – | – | – | 1 (3%)
Adenoma, multiple | 1 (2%) | – | – | –
Carcinoma | 1 (2%) | 1 (2%) | 2 (4%) | 1 (3%)
Liver | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pancreas | – | 2 (4%) | – | –
Hemangioma | 2 (4%) | – | – | 1 (2%)
Hemangiosarcoma | – | 4 (8%) | 3 (6%) | 2 (4%)
Hepatoblastoma | 2 (4%) | 11 (22%) | 8 (16%) | 3 (6%)
Hepatocellular adenoma | 20 (40%) | 13 (26%) | 10 (20%) | 9 (18%)
Hepatocellular adenoma, multiple | 12 (24%) | 20 (40%) | 28 (56%) | 12 (24%)
Hepatocellular carcinoma | 9 (18%) | 11 (22%) | 12 (24%) | 7 (14%)
Hepatocellular carcinoma, multiple | 2 (4%) | 4 (8%) | 5 (10%) | 2 (4%)
Osteosarcoma, metastatic, skin | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Sarcoma | – | 1 (2%) | – | –
Mesentery | (3) | (3) | (4) | (2)
Carcinoma, metastatic, pancreas | – | 1 (33%) | – | –
Hemangiosarcoma | – | – | – | 1 (50%)
Fat, hepatocellular carcinoma, metastatic, liver | – | – | 1 (25%) | –
Pancreas | (50) | (50) | (50) | (50)
Acinus, carcinoma | – | 2 (4%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (49) | (50) | (49)
Squamous cell papilloma | 5 (10%) | – | 1 (2%) | –
Stomach, glandular | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Tooth | (14) | (9) | (9) | (2)
Odontoma | 2 (14%) | 1 (11%) | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma complex | – | 1 (2%) | – | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Parathyroid gland | (45) | (43) | (48) | (42)
Pituitary gland | (50) | (48) | (48) | (50)
Thyroid gland | (50) | (50) | (50) | (50)
Follicular cell, adenoma | – | 1 (2%) | – | –
General Body System
Peritoneum | (0) | (2) | (0) | (0)
Carcinoma, metastatic, pancreas | – | 1 (50%) | – | –
Genital System
Coagulating gland | (3) | (4) | (1) | (0)
Adenoma | – | 1 (25%) | – | –
Carcinoma, metastatic, pancreas | – | 2 (50%) | – | –
Granular cell tumor | 1 (33%) | – | – | –
Sarcoma, metastatic, skin | 1 (33%) | – | – | –
Epididymis | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pancreas | – | 2 (4%) | – | –
Preputial gland | (50) | (50) | (50) | (50)
Prostate | (50) | (50) | (50) | (50)
Seminal vesicle | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Testes | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | 2 (4%) | 1 (2%) | –
Lymph node | (3) | (0) | (2) | (0)
Hepatocellular carcinoma, metastatic, liver | – | – | 1 (50%) | –
Renal, sarcoma, metastatic, skin | 1 (33%) | – | – | –
Lymph node, mandibular | (50) | (50) | (50) | (49)
Lymph node, mesenteric | (50) | (49) | (50) | (49)
Carcinoma, metastatic, pancreas | – | 2 (4%) | – | –
Hemangiosarcoma, metastatic, spleen | – | – | 1 (2%) | –
Spleen | (50) | (48) | (50) | (49)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (2%) | – | – | –
Carcinoma, metastatic, pancreas | – | 2 (4%) | – | –
Hemangioma | – | – | 1 (2%) | –
Hemangiosarcoma | 1 (2%) | 3 (6%) | 4 (8%) | 3 (6%)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Thymus | (47) | (45) | (41) | (48)
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Integumentary System
Skin | (50) | (50) | (50) | (50)
Fibrous histiocytoma | – | 1 (2%) | – | 1 (2%)
Hemangiosarcoma | – | – | 2 (4%) | –
Keratoacanthoma | 1 (2%) | – | – | –
Melanoma benign | – | – | 1 (2%) | –
Osteosarcoma | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Sarcoma | 1 (2%) | – | – | –
Pinna, fibrous histiocytoma | – | 1 (2%) | – | –
Subcutaneous tissue, lipoma | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Vertebra, hemangiosarcoma | – | – | 1 (2%) | –
Skeletal muscle | (0) | (1) | (1) | (0)
Rhabdomyosarcoma | – | 1 (100%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Peripheral nerve | (0) | (0) | (0) | (2)
Spinal cord | (0) | (0) | (0) | (2)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 4 (8%) | 5 (10%) | 2 (4%) | 3 (6%)
Alveolar/bronchiolar adenoma, multiple | 2 (4%) | – | – | –
Alveolar/bronchiolar carcinoma | 4 (8%) | 4 (8%) | 7 (14%) | 2 (4%)
Carcinoma, metastatic, Harderian gland | 1 (2%) | – | – | –
Carcinoma, metastatic, pancreas | – | 2 (4%) | – | –
Hepatoblastoma, metastatic, liver | 1 (2%) | 2 (4%) | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | 5 (10%) | 5 (10%) | 4 (8%) | 2 (4%)
Osteosarcoma, metastatic, skin | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Sarcoma, metastatic, skin | 1 (2%) | – | – | –
Serosa, hemangiosarcoma | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Adenoma | 7 (14%) | 3 (6%) | 7 (14%) | 9 (18%)
Carcinoma | 1 (2%) | 1 (2%) | 2 (4%) | –
Urinary System
Kidney | (50) | (50) | (50) | (48)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (2%) | – | – | –
Hemangiosarcoma | – | – | – | 1 (2%)
Sarcoma, metastatic, skin | 1 (2%) | – | – | –
Renal tubule, adenoma | – | 1 (2%) | 1 (2%) | 2 (4%)
Urinary bladder | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pancreas | – | 1 (2%) | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | – | 2 (4%) | –
Leukemia granulocytic | – | – | – | 1 (2%)
Lymphoma malignant | 3 (6%) | 1 (2%) | 2 (4%) | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 47 | 48 | 48 | 33
Total primary neoplasms | 82 | 95 | 106 | 62
Total animals with benign neoplasms | 38 | 35 | 41 | 28
Total benign neoplasms | 58 | 45 | 52 | 38
Total animals with malignant neoplasms | 21 | 33 | 34 | 18
Total malignant neoplasms | 24 | 50 | 54 | 24
Total animals with metastatic neoplasms | 9 | 10 | 7 | 2
Total metastatic neoplasms | 13 | 40 | 8 | 2

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg
Harderian Gland: Adenoma
Overall rate^b^ | 7/50 (14%) | 3/50 (6%) | 7/50 (14%)
Adjusted rate^c^ | 16.1% | 7.0% | 15.3%
Terminal rate^d^ | 6/33 (18%) | 1/25 (4%) | 6/39 (15%)
First incidence (days) | 673 | 426 | 668
Poly-3 test^e^ | P = 0.534N | P = 0.161N | P = 0.572N
Harderian Gland: Carcinoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 2.3% | 2.4% | 4.4%
Terminal rate | 0/33 (0%) | 0/25 (0%) | 2/39 (5%)
First incidence (days) | 555 | 708 | 730 (T)
Poly-3 test | P = 0.393 | P = 0.750 | P = 0.514
Harderian Gland: Adenoma or Carcinoma
Overall rate | 8/50 (16%) | 4/50 (8%) | 9/50 (18%)
Adjusted rate | 18.2% | 9.3% | 19.7%
Terminal rate | 6/33 (18%) | 1/25 (4%) | 8/39 (21%)
First incidence (days) | 555 | 426 | 668
Poly-3 test | P = 0.470 | P = 0.186N | P = 0.537
Large Intestine (Cecum or Colon): Adenoma or Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 6.5%
Terminal rate | 0/33 (0%) | 0/25 (0%) | 3/39 (5%)
First incidence (days) | –^f^ | – | 513
Poly-3 test | P = 0.039 | –^g^ | P = 0.131
Liver: Hemangiosarcoma
Overall rate | 0/50 (0%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate | 0.0% | 9.5% | 6.6%
Terminal rate | 0/33 (0%) | 2/25 (8%) | 3/39 (8%)
First incidence (days) | – | 602 | 730 (T)
Poly-3 test | P = 0.134 | P = 0.057 | P = 0.128
Liver: Hepatocellular Adenoma
Overall rate | 32/50 (64%) | 33/50 (66%) | 38/50 (76%)
Adjusted rate | 70.1% | 73.4% | 79.2%
Terminal rate | 25/33 (76%) | 19/25 (76%) | 32/39 (82%)
First incidence (days) | 374 | 470 | 522
Poly-3 test | P = 0.172 | P = 0.451 | P = 0.208
Liver: Hepatocellular Carcinoma
Overall rate | 11/50 (22%) | 15/50 (30%) | 17/50 (34%)
Adjusted rate | 24.5% | 34.1% | 35.3%
Terminal rate | 6/33 (18%) | 7/25 (28%) | 9/39 (23%)
First incidence (days) | 521 | 589 | 513
Poly-3 test | P = 0.160 | P = 0.224 | P = 0.182
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 39/50 (78%) | 39/50 (78%) | 43/50 (86%)
Adjusted rate | 82.8% | 84.3% | 87.0%
Terminal rate | 28/33 (85%) | 21/25 (84%) | 33/39 (85%)
First incidence (days) | 374 | 470 | 513
Poly-3 test | P = 0.324 | P = 0.539 | P = 0.380
Liver: Hepatoblastoma
Overall rate | 2/50 (4%) | 11/50 (22%) | 8/50 (16%)
Adjusted rate | 4.6% | 25.6% | 17.6%
Terminal rate | 1/33 (3%) | 7/25 (28%) | 7/39 (18%)
First incidence (days) | 619 | 535 | 722
Poly-3 test | P = 0.065 | P = 0.006 | P = 0.052
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 12/50 (24%) | 24/50 (48%) | 20/50 (40%)
Adjusted rate | 26.8% | 52.8% | 41.5%
Terminal rate | 7/33 (21%) | 12/25 (48%) | 12/39 (31%)
First incidence (days) | 521 | 535 | 513
Poly-3 test | P = 0.099 | P = 0.008 | P = 0.099
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 39/50 (78%) | 42/50 (84%) | 43/50 (86%)
Adjusted rate | 82.8% | 88.8% | 87.0%
Terminal rate | 28/33 (85%) | 22/25 (88%) | 33/39 (85%)
First incidence (days) | 374 | 470 | 513
Poly-3 test | P = 0.325 | P = 0.284 | P = 0.380
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 6/50 (12%) | 5/50 (10%) | 2/50 (4%)
Adjusted rate | 13.8% | 11.7% | 4.4%
Terminal rate | 4/33 (12%) | 2/25 (8%) | 2/39 (5%)
First incidence (days) | 661 | 470 | 730 (T)
Poly-3 test | P = 0.093N | P = 0.512N | P = 0.119N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 7/50 (14%)
Adjusted rate | 9.0% | 9.4% | 15.4%
Terminal rate | 2/33 (6%) | 2/25 (8%) | 7/39 (18%)
First incidence (days) | 448 | 613 | 730 (T)
Poly-3 test | P = 0.215 | P = 0.620 | P = 0.277
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 10/50 (20%) | 9/50 (18%) | 9/50 (18%)
Adjusted rate | 22.4% | 20.6% | 19.8%
Terminal rate | 6/33 (18%) | 4/25 (16%) | 9/39 (23%)
First incidence (days) | 448 | 470 | 730 (T)
Poly-3 test | P = 0.431N | P = 0.524N | P = 0.482N
Spleen: Hemangiosarcoma
Overall rate | 1/50 (2%) | 3/48 (6%) | 4/50 (8%)
Adjusted rate | 2.3% | 7.3% | 8.8%
Terminal rate | 0/33 (0%) | 2/25 (8%) | 4/39 (10%)
First incidence (days) | 645 | 602 | 730 (T)
Poly-3 test | P = 0.149 | P = 0.283 | P = 0.193
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 5/50 (10%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 11.4% | 0.0% | 2.2%
Terminal rate | 3/33 (9%) | 0/25 (0%) | 1/39 (3%)
First incidence (days) | 448 | – | 730 (T)
Poly-3 test | P = 0.033N | P = 0.035N | P = 0.094N
All Organs: Hemangiosarcoma
Overall rate | 1/50 (2%) | 5/50 (10%) | 8/50 (16%)
Adjusted rate | 2.3% | 11.9% | 17.6%
Terminal rate | 0/33 (0%) | 3/25 (12%) | 8/39 (21%)
First incidence (days) | 645 | 602 | 730 (T)
Poly-3 test | P = 0.014 | P = 0.093 | P = 0.019
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 3/50 (6%) | 5/50 (10%) | 9/50 (18%)
Adjusted rate | 6.9% | 11.9% | 19.8%
Terminal rate | 2/33 (6%) | 3/25 (12%) | 9/39 (23%)
First incidence (days) | 645 | 602 | 730 (T)
Poly-3 test | P = 0.047 | P = 0.338 | P = 0.069
All Organs: Malignant Lymphoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 6.9% | 2.4% | 4.4%
Terminal rate | 2/33 (6%) | 0/25 (0%) | 2/39 (5%)
First incidence (days) | 699 | 526 | 730 (T)
Poly-3 test | P = 0.386N | P = 0.314N | P = 0.477N
All Organs: Benign Neoplasms
Overall rate | 38/50 (76%) | 35/50 (70%) | 41/50 (82%)
Adjusted rate | 81.7% | 76.5% | 85.1%
Terminal rate | 29/33 (88%) | 20/25 (80%) | 34/39 (87%)
First incidence (days) | 374 | 426 | 522
Poly-3 test | P = 0.369 | P = 0.353N | P = 0.428
All Organs: Malignant Neoplasms
Overall rate | 21/50 (42%) | 33/50 (66%) | 34/50 (68%)
Adjusted rate | 44.3% | 69.5% | 70.6%
Terminal rate | 10/33 (30%) | 15/25 (60%) | 26/39 (67%)
First incidence (days) | 448 | 470 | 513
Poly-3 test | P = 0.004 | P = 0.009 | P = 0.006
All Organs: Benign or Malignant Neoplasms
Overall rate | 47/50 (94%) | 48/50 (96%) | 48/50 (96%)
Adjusted rate | 95.3% | 97.6% | 97.2%
Terminal rate | 31/33 (94%) | 25/25 (100%) | 38/39 (97%)
First incidence (days) | 374 | 426 | 513
Poly-3 test | P = 0.401 | P = 0.465 | P = 0.517

(T) Terminal kill.

^a^ Due to early mortality, lesion incidences for the 1,000 mg/kg group are not presented.

^b^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, and spleen; for other tissues, denominator is number of animals necropsied.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal kill.

^e^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

^f^ Not applicable; no neoplasms in animal group.

^g^ Value of statistic cannot be computed.

Table C-3 Historical Incidence of Liver Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatoblastoma | Hepatocellular Carcinoma or Hepatoblastoma
Historical Incidence: Corn Oil Gavage Studies
Ginkgo biloba extract (March 2005) | 31/50 | 22/50 | 3/50 | 24/50
Indole-3-carbinol (April 2007) | 26/50 | 12/50 | 3/50 | 15/50
Kava kava extract (August 2004) | 27/50 | 20/50 | 0/50 | 20/50
N,N-Dimethyl-p-toluidine (October 2004) | 29/50 | 22/50 | 1/50 | 22/50
Tetrabromobisphenol A (August 2007) | 32/50 | 11/50 | 2/50 | 12/50
Total (%) | 145/250 (58.0%) | 87/250 (34.8%) | 9/250 (3.6%) | 93/250 (37.2%)
Mean ± standard deviation | 58.0% ± 5.1% | 34.8% ± 10.9% | 3.6% ± 2.6% | 37.2% ± 10.0%
Range | 52%-64% | 22%-44% | 0%-6% | 24%-48%
Overall Historical Incidence: All Routes
Total (%) | 594/949 (62.6%) | 348/949 (36.7%) | 40/949 (4.2%) | 371/949 (39.1%)
Mean ± standard deviation | 62.6% ± 9.1% | 36.7% ± 11.4% | 4.2% ± 3.5% | 39.1% ± 11.6%
Range | 48%-78% | 22%-56% | 0%-12% | 22%-54%

^a^ Data as of June 2013.

Table C-4 Historical Incidence of Large Intestine (Cecum or Colon) Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Adenoma or Carcinoma
Historical Incidence: Corn Oil Gavage Studies
Ginkgo biloba extract (March 2005) | 0/50
Indole-3-carbinol (April 2007) | 0/50
Kava kava extract (August 2004) | 0/50
N,N-Dimethyl-p-toluidine (October 2004) | 0/50
Tetrabromobisphenol A (August 2007) | 0/50
Total | 0/250
Overall Historical Incidence: All Routes
Total (%) | 4/950 (0.4%)
Mean ± standard deviation | 0.4% ± 0.8%
Range | 0%-2%

^a^ Data as of June 2013.

Table C-5 Historical Incidence of Hemangioma and Hemangiosarcoma in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Hemangioma | Hemangiosarcoma | Hemangioma or Hemangiosarcoma
Historical Incidence: Corn Oil Gavage Studies
Ginkgo biloba extract (March 2005) | 0/50 | 9/50 | 9/50
Indole-3-carbinol (April 2007) | 0/50 | 4/50 | 4/50
Kava kava extract (August 2004) | 2/50 | 6/50 | 8/50
N,N-Dimethyl-p-toluidine (October 2004) | 0/50 | 8/50 | 8/50
Tetrabromobisphenol A (August 2007) | 2/50 | 1/50 | 3/50
Total (%) | 4/250 (1.6%) | 28/250 (11.2%) | 32/250 (12.8%)
Mean ± standard deviation | 1.6% ± 2.2% | 11.2% ± 6.4% | 12.8% ± 5.4%
Range | 0%–4% | 2%–18% | 6%–18%
Overall Historical Incidence: All Routes
Total (%) | 13/950 (1.4%) | 92/950 (9.7%) | 105/950 (11.1%)
Mean ± standard deviation | 1.4% ± 1.5% | 9.7% ± 4.5% | 11.1% ± 4.2%
Range | 0%–4% | 2%–18% | 4%–18%

^a^ Data as of June 2013.

Table C-6 Summary of the Incidence of Non-neoplastic Lesions in Male Mice in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | – | – | 1
Moribund | 9 | 10 | 6 | 12
Natural deaths | 8 | 14 | 5 | 25
Survivors
Died last week of study | 1 | 1 | – | –
Terminal kill | 32 | 25 | 39 | 12
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)
Gallbladder | (49) | (46) | (50) | (49)
Pigmentation, hematoidin | 1 (2%) | – | – | –
Intestine large, cecum | (47) | (44) | (47) | (38)
Intestine large, colon | (47) | (46) | (50) | (40)
Diverticulum | – | – | 1 (2%) | –
Inflammation, chronic active | – | 1 (2%) | – | –
Intestine large, rectum | (47) | (46) | (50) | (41)
Intestine small, duodenum | (47) | (41) | (48) | (31)
Intestine small, ileum | (47) | (43) | (50) | (40)
Hyperplasia | 1 (2%) | – | – | –
Intestine small, jejunum | (47) | (44) | (49) | (38)
Diverticulum | – | 1 (2%) | – | –
Peyer’s patch, hyperplasia, lymphoid | – | – | 1 (2%) | 1 (3%)
Liver | (50) | (50) | (50) | (50)
Amyloid deposition | 1 (2%) | – | – | 1 (2%)
Angiectasis | – | – | 2 (4%) | 1 (2%)
Basophilic focus | 9 (18%) | 9 (18%) | 6 (12%) | 9 (18%)
Clear cell focus | 11 (22%) | 10 (20%) | 25 (50%) | 8 (16%)
Eosinophilic focus | 20 (40%) | 33 (66%) | 40 (80%) | 14 (28%)
Fatty change | 1 (2%) | 2 (4%) | 1 (2%) | –
Fatty change, focal | – | 1 (2%) | 2 (4%) | 1 (2%)
Fibrosis | – | 1 (2%) | – | –
Hemorrhage, chronic | – | – | 1 (2%) | –
Inflammation | 1 (2%) | – | – | –
Inflammation, granulomatous | | – | – | 1 (2%)
Mixed cell focus | 7 (14%) | 8 (16%) | 12 (24%) | 6 (12%)
Necrosis | 1 (2%) | 1 (2%) | – | 6 (12%)
Pigmentation | 1 (2%) | – | – | –
Tension lipidosis | 3 (6%) | – | 3 (6%) | 2 (4%)
Bile duct, cyst | – | – | 3 (6%) | 4 (8%)
Bile duct, cyst, multiple | – | – | – | 1 (2%)
Hepatocyte, atrophy | – | 1 (2%) | – | –
Hepatocyte, hypertrophy | 2 (4%) | – | – | –
Hepatocyte, necrosis | – | 2 (4%) | 1 (2%) | –
Kupffer cell, pigmentation | – | – | 2 (4%) | –
Oval cell, hyperplasia | – | – | 1 (2%) | –
Periportal, vacuolization cytoplasmic | – | – | 1 (2%) | 2 (4%)
Serosa, inflammation | – | – | 1 (2%) | –
Mesentery | (3) | (3) | (4) | (2)
Hemorrhage | – | – | 1 (25%) | –
Fat, necrosis | 2 (67%) | 2 (67%) | 2 (50%) | 1 (50%)
Pancreas | (50) | (50) | (50) | (50)
Basophilic focus | – | – | 1 (2%) | –
Acinus, atrophy | – | 1 (2%) | 1 (2%) | –
Arteriole, fibrosis | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (49) | (50) | (49)
Hyperkeratosis | – | – | 1 (2%) | 1 (2%)
Infiltration cellular, mononuclear cell | 5 (10%) | 8 (16%) | 21 (42%) | 27 (55%)
Inflammation | 9 (18%) | 10 (20%) | 20 (40%) | 26 (53%)
Ulcer | 9 (18%) | 9 (18%) | 19 (38%) | 28 (57%)
Epithelium, hyperplasia | 10 (20%) | 13 (27%) | 27 (54%) | 28 (57%)
Stomach, glandular | (50) | (50) | (50) | (50)
Cyst | 1 (2%) | – | – | –
Hyperplasia | 1 (2%) | – | 2 (4%) | 1 (2%)
Hyperplasia, focal | – | – | 1 (2%) | –
Tooth | (14) | (9) | (9) | (2)
Dysplasia | 11 (79%) | 8 (89%) | 9 (100%) | 2 (100%)
Inflammation | 1 (7%) | 1 (11%) | 1 (11%) | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | 2 (4%)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 24 (48%) | 20 (40%) | 18 (36%) | 8 (16%)
Inflammation | – | – | – | 1 (2%)
Mineralization | – | 2 (4%) | – | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Atrium, thrombosis | – | 1 (2%) | 1 (2%) | –
Myocardium, necrosis | 1 (2%) | – | – | –
Pericardium, fibrosis | 1 (2%) | – | – | –
Valve, degeneration | – | – | 1 (2%) | –
Valve, inflammation | 2 (4%) | 2 (4%) | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Amyloid deposition | 1 (2%) | – | – | 1 (2%)
Hyperplasia | 3 (6%) | 2 (4%) | 1 (2%) | 1 (2%)
Hypertrophy | 2 (4%) | – | – | –
Vacuolization cytoplasmic | – | 1 (2%) | – | –
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Hyperplasia | 1 (2%) | 2 (4%) | – | –
Parathyroid gland | (45) | (43) | (48) | (42)
Pituitary gland | (50) | (48) | (48) | (50)
Thyroid gland | (50) | (50) | (50) | (50)
Fibrosis | – | – | – | 1 (2%)
Inflammation | 1 (2%) | – | – | –
Follicle, cyst | – | 1 (2%) | 1 (2%) | –
General Body System
Peritoneum | (0) | (2) | (0) | (0)
Inflammation, suppurative | – | 1 (50%) | – | –
Genital System
Coagulating gland | (3) | (4) | (1) | (0)
Inflammation | – | – | 1 (100%) | –
Inflammation, chronic active | – | 1 (25%) | – | –
Epididymis | (50) | (50) | (50) | (50)
Degeneration | 1 (2%) | – | – | –
Granuloma sperm | – | – | 1 (2%) | –
Inflammation, chronic active | – | 1 (2%) | – | –
Preputial gland | (50) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | –
Ectasia | 2 (4%) | 2 (4%) | 1 (2%) | 5 (10%)
Inflammation | 3 (6%) | 2 (4%) | 3 (6%) | 4 (8%)
Prostate | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | 1 (2%) | –
Inflammation | – | 2 (4%) | 1 (2%) | 1 (2%)
Inflammation, chronic active | – | 1 (2%) | – | –
Epithelium, hyperplasia | 1 (2%) | – | – | –
Seminal vesicle | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)
Testes | (50) | (50) | (50) | (50)
Germinal epithelium, degeneration | 5 (10%) | 3 (6%) | 5 (10%) | 3 (6%)
Interstitial cell, hyperplasia | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | 1 (2%)
Hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Lymph node | (3) | (0) | (2) | (0)
Lymph node, mandibular | (50) | (50) | (50) | (49)
Hyperplasia, lymphoid | 1 (2%) | – | – | –
Lymph node, mesenteric | (50) | (49) | (50) | (49)
Atrophy | – | – | – | 1 (2%)
Hemorrhage | 1 (2%) | 1 (2%) | – | –
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | 4 (8%) | 2 (4%)
Infiltration cellular, histiocyte | – | – | 2 (4%) | –
Inflammation | – | 1 (2%) | – | 2 (4%)
Necrosis | – | 1 (2%) | – | –
Necrosis, lymphoid | – | – | – | 1 (2%)
Spleen | (50) | (48) | (50) | (49)
Amyloid deposition | 1 (2%) | – | – | 1 (2%)
Angiectasis | – | – | – | 1 (2%)
Fibrosis | – | – | – | 1 (2%)
Hematopoietic cell proliferation | 1 (2%) | 3 (6%) | – | 5 (10%)
Hyperplasia, lymphoid | – | 1 (2%) | – | 2 (4%)
Pigmentation, hemosiderin | – | 2 (4%) | – | –
Lymphoid follicle, atrophy | 3 (6%) | 2 (4%) | 1 (2%) | 6 (12%)
Thymus | (47) | (45) | (41) | (48)
Atrophy | 41 (87%) | 42 (93%) | 40 (98%) | 40 (83%)
Cyst | 1 (2%) | – | – | –
Hyperplasia, lymphoid | 1 (2%) | – | – | –
Thrombosis | – | 1 (2%) | – | –
Epithelial cell, hyperplasia | – | 1 (2%) | – | –
Integumentary System
Skin | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
Ulcer | 2 (4%) | 4 (8%) | 3 (6%) | 4 (8%)
Subcutaneous tissue, necrosis | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 1 (2%) | – | – | 1 (2%)
Fibrosis | – | – | – | 1 (2%)
Fibrous osteodystrophy | 1 (2%) | – | – | –
Femur, callus | – | 2 (4%) | – | –
Joint, degeneration | – | – | – | 4 (8%)
Vertebra, fracture | – | – | 1 (2%) | –
Skeletal muscle | (0) | (1) | (1) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | 1 (2%) | – | –
Peripheral nerve | (0) | (0) | (0) | (2)
Axon, sciatic, degeneration | – | – | – | 1 (50%)
Spinal cord | (0) | (0) | (0) | (2)
Axon, degeneration | – | – | – | 2 (100%)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Hemorrhage | 1 (2%) | – | – | –
Infiltration cellular, histiocyte | 1 (2%) | – | 1 (2%) | –
Inflammation | 1 (2%) | – | – | 2 (4%)
Pigmentation, hemosiderin | – | – | 1 (2%) | –
Thrombosis | 1 (2%) | – | – | –
Alveolar epithelium, hyperplasia | 5 (10%) | 1 (2%) | 6 (12%) | 2 (4%)
Alveolar epithelium, hypertrophy | 2 (4%) | – | 1 (2%) | 1 (2%)
Arteriole, thrombosis | – | – | 1 (2%) | –
Bronchiole, hyperplasia | – | 1 (2%) | – | –
Interstitium, fibrosis | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50)
Inflammation | 5 (10%) | 2 (4%) | 3 (6%) | 2 (4%)
Polyp, inflammatory | – | 1 (2%) | – | –
Respiratory epithelium, hyperplasia | 27 (54%) | 25 (50%) | 20 (40%) | 12 (24%)
Respiratory epithelium, necrosis | – | – | 1 (2%) | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | 1 (2%) | –
Cataract | 2 (4%) | – | 1 (2%) | 1 (2%)
Inflammation | 1 (2%) | – | – | 1 (2%)
Cornea, inflammation | 1 (2%) | 1 (2%) | 1 (2%) | –
Harderian gland | (50) | (50) | (50) | (50)
Fibrosis | 1 (2%) | – | – | –
Hyperplasia | 1 (2%) | 1 (2%) | – | 1 (2%)
Urinary System
Kidney | (50) | (50) | (50) | (48)
Cyst | 1 (2%) | – | – | –
Hydronephrosis | – | 3 (6%) | – | 1 (2%)
Infarct | – | 1 (2%) | – | –
Infiltration cellular, lymphocyte | – | 1 (2%) | 2 (4%) | –
Nephropathy | 41 (82%) | 30 (60%) | 32 (64%) | 42 (88%)
Glomerulus, amyloid deposition | 1 (2%) | – | – | 1 (2%)
Papilla, mineralization | – | – | 1 (2%) | –
Papilla, necrosis | 3 (6%) | 1 (2%) | – | –
Pelvis, inflammation | – | – | 1 (2%) | 1 (2%)
Renal tubule, cyst | 6 (12%) | 2 (4%) | 5 (10%) | 6 (13%)
Renal tubule, cyst, multiple | – | – | – | 1 (2%)
Renal tubule, cytoplasmic alteration | – | 20 (40%) | 47 (94%) | 46 (96%)
Renal tubule, inflammation | – | – | – | 4 (8%)
Renal tubule, mineralization | 1 (2%) | – | 1 (2%) | 2 (4%)
Renal tubule, necrosis | – | – | – | 4(8%)
Renal tubule, pigmentation | – | 5 (10%) | 1 (2%) | 2 (4%)
Urinary bladder | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)
Transitional epithelium, hyperplasia | 1 (2%) | 1 (2%) | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.