# Appendix B Summary of Lesions in Female Wistar Han Rats in the Two-year Gavage Study of Tetrabromobisphenol A

Table B-1 Summary of the Incidence of Neoplasms in Female Rats in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month Interim Evaluation | 10 | – | – | 10
Early deaths
Accidental deaths | 3 | – | – | 4
Moribund | 8 | 14 | 15 | 10
Natural deaths | 4 | 2 | 6 | 3
Survivors
Died last week of study | 1 | – | – | 1
Terminal kill | 34 | 34 | 29 | 32
Animals examined microscopically | 60 | 50 | 50 | 60
Systems Examined at 3 Months with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (50) | (49) | (50) | (50)
Intestine large, cecum | (50) | (49) | (50) | (50)
Leiomyoma | – | – | 1 (2%) | –
Intestine large, colon | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | –
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small | (0) | (1) | (0) | (0)
Leiomyosarcoma, metastatic, uterus | – | 1 (100%) | – | –
Intestine small, duodenum | (50) | (50) | (50) | (50)
Leiomyosarcoma | 1 (2%) | – | – | –
Intestine small, ileum | (50) | (49) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Leiomyoma | – | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | – | 3 (6%) | 2 (4%)
Hepatocellular adenoma | 1 (2%) | 2 (4%) | – | 1 (2%)
Malignant mixed Müllerian tumor, metastatic, uterus | – | 2 (4%) | – | –
Mesentery | (2) | (8) | (5) | (4)
Adenocarcinoma, metastatic, uterus | – | 1 (13%) | 2 (40%) | 2 (50%)
Leiomyosarcoma, metastatic, stomach, glandular | – | – | 1 (20%) | –
Leiomyosarcoma, metastatic, uterus | – | 1 (13%) | – | –
Malignant mixed Müllerian tumor, metastatic, uterus | – | 2 (25%) | – | –
Pancreas | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | 3 (6%) | 1 (2%) | 3 (6%)
Granulosa cell tumor malignant, metastatic, ovary | 1 (2%) | – | – | –
Leiomyosarcoma, metastatic, uterus | – | 1 (2%) | – | –
Malignant mixed Müllerian tumor, metastatic, uterus | – | 3 (6%) | – | –
Salivary glands | (50) | (48) | (49) | (49)
Stomach, forestomach | (50) | (50) | (50) | (50)
Stomach, glandular | (50) | (50) | (50) | (50)
Leiomyosarcoma | 1 (2%) | – | 1 (2%) | –
Malignant mixed Müllerian tumor, metastatic, uterus | – | 1 (2%) | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Endocardium, schwannoma benign | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | –
Adenoma | 1 (2%) | – | – | 1 (2%)
Carcinoma | 1 (2%) | – | – | –
Adrenal medulla | (49) | (50) | (50) | (50)
Pheochromocytoma benign | 2 (4%) | – | – | –
Pheochromocytoma malignant | – | – | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Parathyroid gland | (48) | (39) | (48) | (49)
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, adenoma | 20 (40%) | 25 (50%) | 18 (36%) | 16 (32%)
Pars distalis, adenoma, multiple | 1 (2%) | 2 (4%) | – | –
Pars distalis, carcinoma | – | – | – | 1 (2%)
Pars intermedia, adenoma | 4 (8%) | 1 (2%) | – | 1 (2%)
Thyroid gland | (50) | (48) | (50) | (50)
Bilateral, C-cell, adenoma | 1 (2%) | – | – | –
Bilateral, follicular cell, adenoma | 1 (2%) | – | – | –
C-cell, adenoma | 6 (12%) | 9 (19%) | 5 (10%) | 3 (6%)
Follicular cell, adenoma | 2 (4%) | 3 (6%) | 2 (4%) | –
General Body System
None
Genital System
Clitoral gland | (50) | (50) | (50) | (50)
Ovary | (50) | (49) | (50) | (49)
Adenocarcinoma | – | – | – | 1 (2%)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | 1 (2%) | 1 (2%)
Granulosa cell tumor malignant | 1 (2%) | – | – | –
Malignant mixed Müllerian tumor, metastatic, uterus | – | 1 (2%) | – | –
Sex cord stromal tumor, benign, mixed cell | 2 (4%) | – | – | 1 (2%)
Uterus | (50) | (50) | (50) | (50)
Adenocarcinoma | 2 (4%) | 3 (6%) | 7 (14%) | 9 (18%)
Adenocarcinoma, multiple | 1 (2%) | – | 1 (2%)
Adenoma | – | – | 3 (6%) | 4 (8%)
Leiomyosarcoma | – | 1 (2%) | – | –
Malignant mixed Müllerian tumor | – | 4 (8%) | – | 2 (4%)
Polyp stromal | 2 (4%) | 4 (8%) | 3 (6%) | 1 (2%)
Sarcoma stromal | – | 2 (4%) | – | 1 (2%)
Cervix, sarcoma stromal | – | – | 1 (2%) | –
Cervix, squamous cell carcinoma | – | 1 (2%) | – | –
Vagina | (1) | (1) | (1) | (1)
Granular cell tumor malignant | – | 1 (100%) | – | –
Leiomyoma | 1 (100%) | – | – | –
Polyp | – | – | – | 1 (100%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (0) | (1) | (1) | (0)
Lymph node, mandibular | (50) | (48) | (49) | (49)
Lymph node, mediastinal | (0) | (0) | (1) | (0)
Adenocarcinoma, metastatic, uterus | – | – | 1 (100%) | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | 1 (2%) | 1 (2%)
Malignant mixed Müllerian tumor, metastatic, uterus | – | 1 (2%) | – | –
Thymus | (50) | (50) | (49) | (50)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | –
Sarcoma | 1 (2%) | – | – | –
Thymoma benign | 1 (2%) | – | 2 (4%) | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenocarcinoma | 1 (2%) | – | – | 3 (6%)
Adenoma | 3 (6%) | 5 (10%) | 2 (4%) | –
Adenoma, multiple | 1 (2%) | – | – | –
Fibroadenoma | 7 (14%) | 12 (24%) | 6 (12%) | 11 (22%)
Fibroadenoma, multiple | 1 (2%) | 3 (6%) | 2 (4%) | –
Skin | (50) | (50) | (50) | (50)
Basal cell adenoma | – | 1 (2%) | – | –
Basal cell carcinoma | – | 1 (2%) | – | –
Fibroma | – | 1 (2%) | – | –
Squamous cell papilloma | – | 1 (2%) | 1 (2%) | –
Subcutaneous tissue, adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | –
Subcutaneous tissue, hemangiosarcoma | 1 (2%) | – | – | –
Subcutaneous tissue, lipoma | – | – | 1 (2%) | –
Subcutaneous tissue, malignant mixed Müllerian tumor, metastatic, uterus | – | 2 (4%) | – | –
Subcutaneous tissue, sarcoma | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (0) | (2) | (1) | (1)
Adenocarcinoma, metastatic, uterus | – | 1 (50%) | 1 (100%) | –
Leiomyosarcoma, metastatic, uterus | – | 1 (50%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Ependymoma malignant | – | – | 1 (2%) | –
Glioma malignant, mixed cell | – | – | 2 (4%) | –
Granular cell tumor benign | – | 1 (2%) | – | –
Peripheral nerve | (0) | (1) | (0) | (0)
Spinal cord | (0) | (1) | (0) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | 1 (2%) | 4 (8%) | 1 (2%) | 4 (8%)
Alveolar/bronchiolar adenoma | – | – | – | 2 (4%)
Carcinoma, metastatic, adrenal cortex | 1 (2%) | – | – | –
Granulosa cell tumor malignant, metastatic, ovary | 1 (2%) | – | – | –
Malignant mixed Müllerian tumor, metastatic, uterus | – | 1 (2%) | – | –
Olfactory neuroblastoma, metastatic, nose | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (50)
Olfactory neuroblastoma | 1 (2%) | – | – | –
Trachea | (50) | (49) | (50) | (50)
Special Senses System
Eye | (50) | (48) | (49) | (49)
Harderian gland | (50) | (48) | (49) | (49)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | 2 (4%) | – | 1 (2%)
Lipoma | – | – | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | –
Granulosa cell tumor malignant, metastatic, ovary | 1 (2%) | – | – | –
Malignant mixed Müllerian tumor, metastatic, uterus | – | 1 (2%) | – | –
Transitional epithelium, papilloma | 1 (2%) | – | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Leukemia mononuclear | – | – | 1 (2%) | –
Neoplasm Summary
Total animals with primary neoplasms^c^
Two-year study | 40 | 43 | 39 | 38
Total primary neoplasms
Two-year study | 71 | 84 | 62 | 61
Total animals with benign neoplasms
Two-year study | 38 | 38 | 34 | 30
Total benign neoplasms
Two-year study | 59 | 70 | 48 | 43
Total animals with malignant neoplasms
Two-year study | 10 | 13 | 12 | 14
Total malignant neoplasms
Two-year study | 12 | 14 | 14 | 18
Total animals with metastatic neoplasms
Two-year study | 4 | 7 | 4 | 4
Total metastatic neoplasms
Two-year study | 6 | 36 | 12 | 14

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Rats in the Two-year Gavage Study of Tetrabromobisphenol A

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Mammary Gland: Fibroadenoma
Overall rate^a^ | 8/50 (16%) | 15/50 (30%) | 8/50 (16%) | 11/50 (22%)
Adjusted rate^b^ | 18.7% | 34.0% | 19.2% | 25.4%
Terminal rate^c^ | 6/34 (18%) | 12/34 (35%) | 3/29 (10%) | 7/33 (21%)
First incidence (days) | 713 | 658 | 243 | 462
Poly-3 test^d^ | P = 0.477 | P = 0.082 | P = 0.585 | P = 0.310
Mammary Gland: Adenoma
Overall rate | 4/50 (8%) | 5/50 (10%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 9.3% | 11.3% | 5.2% | 0.0%
Terminal rate | 3/34 (9%) | 1/34 (3%) | 1/29 (3%) | 0/33 (0%)
First incidence (days) | 726 | 624 | 637 | –^e^
Poly-3 test | P = 0.028N | P = 0.522 | P = 0.385N | P = 0.063N
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 12/50 (24%) | 20/50 (40%) | 10/50 (20%) | 11/50 (22%)
Adjusted rate | 28.0% | 44.5% | 23.8% | 25.4%
Terminal rate | 9/34 (27%) | 13/34 (38%) | 4/29 (14%) | 7/33 (21%)
First incidence (days) | 713 | 624 | 243 | 462
Poly-3 test | P = 0.191N | P = 0.079 | P = 0.423N | P = 0.489N
Mammary Gland: Carcinoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 2.3% | 0.0% | 0.0% | 7.1%
Terminal rate | 0/34 (0%) | 0/34 (0%) | 0/29 (0%) | 2/33 (6%)
First incidence (days) | 726 | – | – | 625
Poly-3 test | P = 0.080 | P = 0.497N | P = 0.522N | P = 0.300
Mammary Gland: Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 5/50 (10%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 9.3% | 11.3% | 5.2% | 7.1%
Terminal rate | 3/34 (9%) | 1/34 (3%) | 1/29 (3%) | 2/33 (6%)
First incidence (days) | 726 | 624 | 637 | 625
Poly-3 test | P = 0.339N | P = 0.522 | P = 0.385N | P = 0.508N
Mammary Gland: Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 12/50 (24%) | 20/50 (40%) | 10/50 (20%) | 14/50 (28%)
Adjusted rate | 28.0% | 44.5% | 23.8% | 32.1%
Terminal rate | 9/34 (27%) | 13/34 (38%) | 4/29 (14%) | 9/33 (27%)
First incidence (days) | 713 | 624 | 243 | 462
Poly-3 test | P = 0.448N | P = 0.079 | P = 0.423N | P = 0.429
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 21/50 (42%) | 27/50 (54%) | 18/50 (36%) | 16/50 (32%)
Adjusted rate | 44.3% | 58.1% | 42.8% | 36.4%
Terminal rate | 10/34 (29%) | 18/34 (53%) | 9/29 (31%) | 11/33 (33%)
First incidence (days) | 364 | 492 | 488 | 531
Poly-3 test | P = 0.119N | P = 0.127 | P = 0.527N | P = 0.288N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 21/50 (42%) | 27/50 (54%) | 18/50 (36%) | 17/50 (34%)
Adjusted rate | 44.3% | 58.1% | 42.8% | 38.7%
Terminal rate | 10/34 (29%) | 18/34 (53%) | 9/29 (31%) | 12/33 (36%)
First incidence (days) | 364 | 492 | 488 | 531
Poly-3 test | P = 0.172N | P = 0.127 | P = 0.527N | P = 0.369N
Pituitary Gland (Pars Intermedia): Adenoma
Overall rate | 4/50 (8%) | 1/50 (2%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 9.4% | 2.3% | 0.0% | 2.4%
Terminal rate | 4/34 (12%) | 1/34 (3%) | 0/29 (0%) | 1/33 (3%)
First incidence (days) | 728 (T) | 728 (T) | – | 728 (T)
Poly-3 test | P = 0.109N | P = 0.173N | P = 0.075N | P = 0.185N
Skin: Squamous Cell Papilloma, Basal Cell Adenoma, or Basal Cell Carcinoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 0.0% | 6.8% | 2.6% | 0.0%
Terminal rate | 0/34 (0%) | 2/34 (6%) | 0/29 (0%) | 0/33 (0%)
First incidence (days) | – | 383 | 636 | –
Poly-3 test | P = 0.376N | P = 0.125 | P = 0.480 | –^f^
Thyroid Gland (Follicular Cell): Adenoma
Overall rate | 3/50 (6%) | 3/48 (6%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 7.0% | 7.1% | 5.2% | 0.0%
Terminal rate | 2/34 (6%) | 3/34 (9%) | 1/29 (3%) | 0/33 (0%)
First incidence (days) | 662 | 728 (T) | 639 | –
Poly-3 test | P = 0.077N | P = 0.657 | P = 0.549N | P = 0.123N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 7/50 (14%) | 9/48 (19%) | 5/50 (10%) | 3/50 (6%)
Adjusted rate | 16.3% | 21.0% | 12.6% | 7.1%
Terminal rate | 5/34 (15%) | 7/34 (21%) | 3/29 (10%) | 2/33 (6%)
First incidence (days) | 713 | 624 | 496 | 614
Poly-3 test | P = 0.074N | P = 0.393 | P = 0.436N | P = 0.162N
Uterus: Stromal Polyp (Original Transverse Review)
Overall rate | 2/50 (4%) | 4/50 (8%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 4.7% | 9.2% | 7.8% | 2.4%
Terminal rate | 2/34 (6%) | 3/34 (9%) | 3/29 (10%) | 0/33 (0%)
First incidence (days) | 728 (T) | 693 | 728 (T) | 614
Poly-3 test | P = 0.304N | P = 0.346 | P = 0.450 | P = 0.505N
Uterus: Stromal Polyp (Residual Longitudinal Review)
Overall rate | 5/50 (10%) | 7/50 (14%) | 8/50 (16%) | 8/50 (16%)
Adjusted rate | 11.7% | 15.9% | 20.5% | 18.5%
Terminal rate | 4/34 (12%) | 5/34 (15%) | 6/29 (21%) | 5/33 (15%)
First incidence (days) | 725 | 636 | 607 | 442
Poly-3 test | P = 0.241 | P = 0.398 | P = 0.216 | P = 0.282
Uterus: Stromal Polyp (Original Transverse and Residual Longitudinal Reviews)
Overall rate | 5/50 (10%) | 9/50 (18%) | 9/50 (18%) | 8/50 (16%)
Adjusted rate | 11.7% | 20.5% | 23.0% | 18.5%
Terminal rate | 4/34 (12%) | 7/34 (21%) | 7/29 (24%) | 5/33 (15%)
First incidence (days) | 725 | 636 | 607 | 442
Poly-3 test | P = 0.307 | P = 0.206 | P = 0.141 | P = 0.282
Uterus: Stromal Polyp, Stromal Sarcoma, or Leiomyosarcoma (Original Transverse Review)
Overall rate | 2/50 (4%) | 7/50 (14%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 4.7% | 15.7% | 7.8% | 4.7%
Terminal rate | 2/34 (6%) | 4/34 (12%) | 3/29 (10%) | 0/33 (0%)
First incidence (days) | 728 (T) | 527 | 728 (T) | 614
Poly-3 test | P = 0.332N | P = 0.089 | P = 0.450 | P = 0.691
Uterus: Stromal Polyp, Stromal Sarcoma, or Leiomyosarcoma (Residual Longitudinal Review)
Overall rate | 5/50 (10%) | 7/50 (14%) | 8/50 (16%) | 8/50 (16%)
Adjusted rate | 11.7% | 15.9% | 20.5% | 18.5%
Terminal rate | 4/34 (12%) | 5/34 (15%) | 6/29 (21%) | 5/33 (15%)
First incidence (days) | 725 | 636 | 607 | 442
Poly-3 test | P = 0.241 | P = 0.398 | P = 0.216 | P = 0.282
Uterus: Stromal Polyp, Stromal Sarcoma, or Leiomyosarcoma (Original Transverse and Residual Longitudinal Reviews)
Overall rate | 5/50 (10%) | 12/50 (24%) | 9/50 (18%) | 9/50 (18%)
Adjusted rate | 11.7% | 26.7% | 23.0% | 20.7%
Terminal rate | 4/34 (12%) | 8/34 (24%) | 7/29 (24%) | 5/33 (15%)
First incidence (days) | 725 | 527 | 607 | 442
Poly-3 test | P = 0.314 | P = 0.064 | P = 0.141 | P = 0.199
Uterus: Adenoma (Original Transverse Review)
Overall rate | 0/50 (0%) | 0/50 (0%) | 3/50 (6%) | 4/50 (8%)
Adjusted rate | 0.0% | 0.0% | 7.8% | 9.4%
Terminal rate | 0/34 (0%) | 0/34 (0%) | 3/29 (10%) | 2/33 (6%)
First incidence (days) | – | – | 728 (T) | 625
Poly-3 test | P = 0.010 | – | P = 0.100 | P = 0.059
Uterus: Adenoma (Residual Longitudinal Review)
Overall rate | 3/50 (6%) | 2/50 (4%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 7.0% | 4.5% | 2.6% | 7.0%
Terminal rate | 1/34 (3%) | 1/34 (3%) | 1/29 (3%) | 1/33 (3%)
First incidence (days) | 668 | 548 | 728 (T) | 442
Poly-3 test | P = 0.556 | P = 0.489N | P = 0.347N | P = 0.662
Uterus: Adenoma (Original Transverse and Residual Longitudinal Reviews)
Overall rate | 3/50 (6%) | 2/50 (4%) | 4/50 (8%) | 6/50 (12%)
Adjusted rate | 7.0% | 4.5% | 10.4% | 13.9%
Terminal rate | 1/34 (3%) | 1/34 (3%) | 4/29 (14%) | 3/33 (9%)
First incidence (days) | 668 | 548 | 728 (T) | 442
Poly-3 test | P = 0.103 | P = 0.489N | P = 0.437 | P = 0.242
Uterus: Adenocarcinoma (Original Transverse Review)
Overall rate | 3/50 (6%) | 3/50 (6%) | 8/50 (16%) | 9/50 (18%)
Adjusted rate | 7.0% | 6.7% | 19.8% | 20.9%
Terminal rate | 2/34 (6%) | 0/34 (0%) | 4/29 (14%) | 5/33 (15%)
First incidence (days) | 713 | 548 | 321 | 607
Poly-3 test | P = 0.016 | P = 0.644N | P = 0.078 | P = 0.058
Uterus: Adenocarcinoma (Residual Longitudinal Review)
Overall rate | 4/50 (8%) | 9/50 (18%) | 15/50 (30%) | 15/50 (30%)
Adjusted rate | 9.3% | 19.9% | 36.4% | 33.8%
Terminal rate | 3/34 (9%) | 4/34 (12%) | 9/29 (31%) | 10/33 (30%)
First incidence (days) | 713 | 548 | 321 | 442
Poly-3 test | P = 0.003 | P = 0.137 | P = 0.002 | P = 0.005
Uterus: Adenocarcinoma (Original Transverse and Residual Longitudinal Reviews)
Overall rate | 4/50 (8%) | 10/50 (20%) | 15/50 (30%) | 16/50 (32%)
Adjusted rate | 9.3% | 22.0% | 36.4% | 35.9%
Terminal rate | 3/34 (9%) | 4/34 (12%) | 9/29 (31%) | 10/33 (30%)
First incidence (days) | 713 | 548 | 321 | 442
Poly-3 test | P = 0.002 | P = 0.089 | P = 0.002 | P = 0.002
Uterus: Malignant Mixed Müllerian Tumor (Original Transverse Review)
Overall rate | 0/50 (0%) | 4/50 (8%) | 0/50 (0%) | 2/50 (4%)^g^
Adjusted rate | 0.0% | 9.0% | 0.0% | 4.7%
Terminal rate | 0/34 (0%) | 1/34 (3%) | 0/29 (0%) | 1/33 (3%)
First incidence (days) | – | 656 | – | 615
Poly-3 test | P = 0.433 | P = 0.064 | – | P = 0.234
Uterus: Adenoma, Adenocarcinoma, or Malignant Mixed Müllerian Tumor (Original Transverse Review)
Overall rate | 3/50 (6%) | 7/50 (14%) | 11/50 (22%) | 13/50 (26%)
Adjusted rate | 7.0% | 15.4% | 27.3% | 29.9%
Terminal rate | 2/34 (6%) | 1/34 (3%) | 7/29 (24%) | 7/33 (21%)
First incidence (days) | 713 | 548 | 321 | 607
Poly-3 test | P = 0.003 | P = 0.181 | P = 0.013 | P = 0.005
Uterus: Adenoma, Adenocarcinoma, or Malignant Mixed Müllerian Tumor (Residual Longitudinal Review)
Overall rate | 6/50 (12%) | 10/50 (20%) | 16/50 (32%) | 16/50 (32%)
Adjusted rate | 13.9% | 22.1% | 38.8% | 35.8%
Terminal rate | 3/34 (9%) | 5/34 (15%) | 10/29 (35%) | 10/33 (30%)
First incidence (days) | 668 | 548 | 321 | 442
Poly-3 test | P = 0.008 | P = 0.237 | P = 0.007 | P = 0.015
Uterus: Adenoma, Adenocarcinoma, or Malignant Mixed Müllerian Tumor (Original Transverse and Residual Longitudinal Reviews)
Overall rate | 6/50 (12%) | 11/50 (22%) | 16/50 (32%) | 19/50 (38%)
Adjusted rate | 13.9% | 24.2% | 38.8% | 42.2%
Terminal rate | 3/34 (9%) | 5/34 (15%) | 10/29 (35%) | 11/33 (33%)
First incidence (days) | 668 | 548 | 321 | 442
Poly-3 test | P = 0.001 | P = 0.168 | P = 0.007 | P = 0.002
All Organs: Benign Neoplasms
Overall rate | 38/50 (76%) | 38/50 (76%) | 34/50 (68%) | 30/50 (60%)
Adjusted rate | 80.2% | 81.7% | 75.3% | 65.5%
Terminal rate | 26/34 (77%) | 28/34 (82%) | 20/29 (69%) | 20/33 (61%)
First incidence (days) | 364 | 492 | 243 | 462
Poly-3 test | P = 0.032N | P = 0.528 | P = 0.373N | P = 0.080N
All Organs: Malignant Neoplasms
Overall rate | 10/50 (20%) | 13/50 (26%) | 12/50 (24%) | 14/50 (28%)
Adjusted rate | 22.5% | 27.5% | 28.6% | 32.2%
Terminal rate | 5/34 (15%) | 4/34 (12%) | 5/29 (17%) | 8/33 (24%)
First incidence (days) | 546 | 383 | 321 | 607
Poly-3 test | P = 0.195 | P = 0.378 | P = 0.345 | P = 0.217
All Organs: Benign or Malignant Neoplasms
Overall rate | 40/50 (80%) | 43/50 (86%) | 39/50 (78%) | 38/50 (76%)
Adjusted rate | 83.4% | 87.6% | 81.8% | 81.2%
Terminal rate | 27/34 (79%) | 28/34 (82%) | 21/29 (72%) | 25/33 (76%)
First incidence (days) | 364 | 383 | 243 | 462
Poly-3 test | P = 0.342N | P = 0.383 | P = 0.524N | P = 0.497N

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for pituitary gland and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

^g^ One additional malignant mixed Müllerian tumor was found during the residual longitudinal review in an animal that already had this tumor diagnosed during the original transverse review.

Table B-3 Historical Incidence of Uterus Neoplasms in Control Female Wistar Han Rats^a^

| Adenoma | Adenocarcinoma^b^ | Malignant Mixed Müllerian Tumor | Adenoma, Adenocarcinoma or Malignant Mixed Müllerian Tumor^b^
Overall Historical Incidence: All Routes
Total (%) | 0/150 | 7/150 (4.7%) | 0/150 | 7/150 (4.7%)
Mean ± standard deviation | – | 4.7% ± 2.3% | – | 4.7% ± 2.3%
Range | – | 2%–6% | – | 2%–6%

^a^ Data as of June 2013.

^b^ Includes one endometrium carcinoma.

Table B-4 Summary of the Incidence of Non-neoplastic Lesions in Female Rats in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month Interim Evaluation | 10 | – | – | 10
Early deaths
Accidental deaths | 3 | – | – | 4
Moribund | 8 | 14 | 15 | 10
Natural deaths | 4 | 2 | 6 | 3
Survivors
Died last week of study | 1 | – | – | 1
Terminal kill | 34 | 34 | 29 | 32
Animals examined microscopically | 60 | 50 | 50 | 60
Three-month Interim Evaluation
Alimentary System
Intestine, large, rectum | (10) | – | – | (10)
Lymphoid tissue, hyperplasia | 1 (10%) | – | – | 1 (10%)
Pancreas | (10) | – | – | (10)
Acinus, atrophy | – | – | – | 1 (10%)
Endocrine System
Adrenal cortex | (10) | – | – | (10)
Hypertrophy | 1 (10%) | – | – | –
Pituitary gland | (10) | – | – | (10)
Cyst | 1 (10%) | – | – | –
Hematopoietic System
Lymph node, mesenteric | (10) | – | – | (10)
Hyperplasia, lymphoid | 3 (30%) | – | – | 3 (30%)
Respiratory System
Lung | (10) | – | – | (10)
Infiltration cellular, histiocyte | 1 (10%) | – | – | –
Perivascular, inflammation, chronic active | 1 (10%) | – | – | 1 (10%)
Nose | (10) | – | – | (10)
Olfactory epithelium, accumulation, hyaline droplet | – | – | – | 2 (20%)
Olfactory epithelium, necrosis | – | – | – | 1 (10%)
Respiratory epithelium, accumulation, hyaline droplet | – | – | – | 1 (10%)
Respiratory epithelium, necrosis | – | | | 1 (10%)
Urinary System
Kidney | (10) | – | – | (10)
Cyst | – | – | – | 1 (10%)
Nephropathy | 2 (20%) | – | – | 2 (20%)
Systems Examined at 3 Months with No Lesions Observed
Cardiovascular System
General Body System
Genital System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Two-year Study
Alimentary System
Esophagus | (50) | (49) | (50) | (50)
Inflammation | 1 (2%) | – | – | –
Inflammation, acute | – | – | – | 1 (2%)
Perforation | 3 (6%) | – | – | 3 (6%)
Intestine large, cecum | (50) | (49) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
Inflammation, suppurative | | 1 (2%) | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | 1 (2%) | – | –
Parasite metazoan | – | 1 (2%) | – | –
Intestine large, rectum | (50) | (50) | (50) | (50)
Parasite metazoan | 3 (6%) | 2 (4%) | 2 (4%) | 1 (2%)
Intestine small | (0) | (1) | (0) | (0)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (49) | (50) | (50)
Parasite metazoan | 1 (2%) | – | 1 (2%) | –
Lymphoid tissue, hyperplasia | – | – | – | 1 (2%)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 1 (2%) | – | –
Basophilic focus | 47 (94%) | 38 (76%) | 40 (80%) | 47 (94%)
Clear cell focus | 24 (48%) | 19 (38%) | 19 (38%) | 18 (36%)
Congestion | 1 (2%) | – | – | –
Cyst | – | 1 (2%) | – | –
Eosinophilic focus | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Fatty change | 11 (22%) | 12 (24%) | 7 (14%) | 7 (14%)
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Hepatodiaphragmatic nodule | 1 (2%) | – | 1 (2%) | –
Inflammation, suppurative | | 1 (2%) | – | –
Mixed cell focus | 13 (26%) | 22 (44%) | 12 (24%) | 20 (40%)
Necrosis | – | 1 (2%) | 4 (8%) | 2 (4%)
Pigmentation | – | 1 (2%) | – | –
Bile duct, cyst | 2 (4%) | – | 3 (6%) | 1 (2%)
Bile duct, hyperplasia | 11 (22%) | 29 (58%) | 21 (42%) | 20 (40%)
Centrilobular, necrosis | – | – | 1 (2%) | –
Oval cell, hyperplasia | – | – | – | 1 (2%)
Mesentery | (2) | (8) | (5) | (4)
Fat, necrosis | 2 (100%) | 3 (38%) | 2 (40%) | 2 (50%)
Pancreas | (50) | (50) | (50) | (50)
Acinus, atrophy | 4 (8%) | 4 (8%) | 1 (2%) | –
Duct, cyst | 2 (4%) | – | – | –
Salivary glands | (50) | (48) | (49) | (49)
Duct, hyperplasia | 1 (2%) | – | – | –
Duct, metaplasia, squamous | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | 1 (2%) | – | –
Inflammation, chronic | 2 (4%) | 1 (2%) | 2 (4%) | 2 (4%)
Ulcer | 1 (2%) | – | 1 (2%) | –
Epithelium, hyperplasia | – | – | – | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | 1 (2%) | – | –
Inflammation, acute | – | – | 1 (2%) | –
Inflammation, chronic | 1 (2%) | 2 (4%) | – | –
Mineralization | 6 (12%) | 1 (2%) | 1 (2%) | 2 (4%)
Ulcer | – | 1 (2%) | 2 (4%) | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Mineralization | 1 (2%) | – | – | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 9 (18%) | 10 (20%) | 3 (6%) | 7 (14%)
Congestion | 1 (2%) | – | – | –
Endocardium, hyperplasia | 2 (4%) | 2 (4%) | 1 (2%) | –
Myocardium, mineralization | 1 (2%) | – | – | –
Pericardium, inflammation, acute | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Angiectasis | 12 (24%) | 7 (14%) | 6 (12%) | 9 (18%)
Degeneration, cystic | 1 (2%) | 1 (2%) | 1 (2%) | –
Fibrosis | – | – | 1 (2%) | –
Hyperplasia | 7 (14%) | 7 (14%) | 7 (14%) | 11 (22%)
Inflammation, suppurative | – | – | – | 1 (2%)
Mineralization | – | – | – | 1 (2%)
Necrosis | – | 1 (2%) | – | –
Vacuolization cytoplasmic | 2 (4%) | 3 (6%) | 5 (10%) | 2 (4%)
Capsule, fibrosis | 1 (2%) | – | – | –
Adrenal medulla | (49) | (50) | (50) | (50)
Hemorrhage | – | – | – | 2 (4%)
Hyperplasia | 2 (4%) | 2 (4%) | – | 2 (4%)
Inflammation, suppurative | – | – | – | 1 (2%)
Thrombosis | – | – | 1 (2%) | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Parathyroid gland | (48) | (39) | (48) | (49)
Pituitary gland | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Cyst | 1 (2%) | 1 (2%) | 1 (2%) | –
Pars distalis, hyperplasia | 16 (32%) | 13 (26%) | 14 (28%) | 19 (38%)
Pars intermedia, hyperplasia | 2 (4%) | 3 (6%) | 2 (4%) | 1 (2%)
Thyroid gland | (50) | (48) | (50) | (50)
C-cell, hyperplasia | 32 (64%) | 37 (77%) | 39 (78%) | 36 (72%)
Follicle, hyperplasia | 2 (4%) | 4 (8%) | 3 (6%) | 1 (2%)
Follicular cell, hyperplasia | 1 (2%) | – | – | –
General Body System
None
Genital System
Clitoral gland | (50) | (50) | (50) | (50)
Hyperplasia | – | – | 1 (2%) | –
Inflammation | 4 (8%) | 2 (4%) | 4 (8%) | 5 (10%)
Ovary | (50) | (49) | (50) | (49)
Cyst | 1 (2%) | 4 (8%) | 4 (8%) | 6 (12%)
Inflammation, acute | 1 (2%) | – | – | –
Stromal hyperplasia, mixed cell | 1 (2%) | – | – | –
Bilateral, cyst | 1 (2%) | – | – | –
Bursa, dilatation | 4 (8%) | 2 (4%) | 5 (10%) | 8 (16%)
Rete ovarii, cyst | 1 (2%) | – | 6 (12%) | 6 (12%)
Uterus | (50) | (50) | (50) | (50)
Adenomyosis | – | – | – | 2 (4%)
Cyst | 1 (2%) | – | – | 1 (2%)
Dilatation | 1 (2%) | 4 (8%) | 3 (6%) | 2 (4%)
Hyperplasia, glandular, focal | – | – | 1 (2%) | –
Inflammation, suppurative | 7 (14%) | 3 (6%) | 2 (4%) | 3 (6%)
Ulcer | – | – | – | 1 (2%)
Cervix, hyperplasia, stromal | – | 1 (2%) | 4 (8%) | 2 (4%)
Endometrium, hyperplasia, adenomatous | – | – | – | 1 (2%)
Endometrium, hyperplasia, cystic | 8 (16%) | 13 (26%) | 11 (22%) | 18 (36%)
Vagina | (1) | (1) | (1) | (1)
Cyst | – | – | 1 (100%) | –
Necrosis | 1 (100%) | – | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (0) | (1) | (1) | (0)
Mediastinal, congestion | – | 1 (100%) | – | –
Mediastinal, ectasia | – | – | 1 (100%) | –
Lymph node, mandibular | (50) | (48) | (49) | (49)
Lymph node, mediastinal | (0) | (0) | (1) | (0)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hyperplasia, plasma cell | – | 1 (2%) | – | –
Inflammation, suppurative | – | 1 (2%) | – | –
Spleen | (50) | (50) | (50) | (50)
Hematopoietic cell proliferation | 26 (52%) | 30 (60%) | 26 (52%) | 26 (52%)
Inflammation, suppurative | – | 1 (2%) | – | –
Lymphoid follicle, atrophy | 3 (6%) | 2 (4%) | 2 (4%) | 1 (2%)
Red pulp, atrophy | – | 1 (2%) | – | –
Thymus | (50) | (50) | (49) | (50)
Atrophy | 43 (86%) | 43 (86%) | 40 (82%) | 45 (90%)
Cyst | – | – | 1 (2%) | –
Hemorrhage | – | – | – | 1 (2%)
Hyperplasia | 1 (2%) | 2 (4%) | – | –
Epithelial cell, hyperplasia | | 1 (2%) | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Galactocele | 3 (6%) | 1 (2%) | 2 (4%) | 2 (4%)
Hyperplasia | 1 (2%) | 2 (4%) | – | –
Inflammation, suppurative | – | – | – | 1 (2%)
Skin | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
Ulcer | – | – | 1 (2%) | –
Epidermis, hyperplasia | – | – | – | 1 (2%)
Vein, cyst | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fracture | – | – | – | 1 (2%)
Hyperplasia | – | – | 1 (2%) | –
Skeletal muscle | (0) | (2) | (1) | (1)
Inflammation, acute | – | – | – | 1 (100%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 11 (22%) | 10 (20%) | 9 (18%) | 6 (12%)
Hippocampus, necrosis | 1 (2%) | – | – | –
Meninges, inflammation, acute | 1 (2%) | – | – | –
Peripheral nerve | (0) | (1) | (0) | (0)
Spinal cord | (0) | (1) | (0) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Congestion | – | – | 1 (2%) | –
Inflammation, granulomatous | 1 (2%) | 2 (4%) | – | 4 (8%)
Inflammation, chronic | 2 (4%) | – | 3 (6%) | 1 (2%)
Alveolar epithelium, hyperplasia | 1 (2%) | 2 (4%) | 1 (2%) | –
Bronchiole, hyperplasia | 1 (2%) | 1 (2%) | – | 1 (2%)
Serosa, inflammation, suppurative | – | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Inflammation | 11 (22%) | 8 (16%) | 7 (14%) | 9 (18%)
Trachea | (50) | (49) | (50) | (50)
Inflammation | 2 (4%) | – | – | –
Special Senses System
Eye | (50) | (48) | (49) | (49)
Cataract | – | – | 2 (4%) | 1 (2%)
Degeneration | 1 (2%) | – | – | 1 (2%)
Malformation | 1 (2%) | – | – | –
Cornea, inflammation | – | 1 (2%) | – | –
Retina, atrophy | – | 2 (4%) | 3 (6%) | 4 (8%)
Harderian gland | (50) | (48) | (49) | (49)
Inflammation | – | 1 (2%) | – | 1 (2%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Accumulation, hyaline droplet | – | – | – | 1 (2%)
Cyst | 2 (4%) | 1 (2%) | 2 (4%) | –
Hydronephrosis | 1 (2%) | 1 (2%) | – | 2 (4%)
Infarct | – | 1 (2%) | 1 (2%) | –
Inflammation, suppurative | – | 2 (4%) | – | 1 (2%)
Inflammation, chronic | 1 (2%) | – | – | –
Nephropathy | 9 (18%) | 15 (30%) | 13 (26%) | 9 (18%)
Thrombosis | – | 2 (4%) | – | –
Pelvis, inflammation, suppurative | 2 (4%) | 4 (8%) | 3 (6%) | 1 (2%)
Renal tubule, autolysis | 1 (2%) | 1 (2%) | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.