# Appendix A Summary of Lesions in Male Wistar Han Rats in the Two-Year Gavage Study of Tetrabromobisphenol A

Table A-1 Summary of the Incidence of Neoplasms in Male Rats in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month Interim Evaluation | 10 | – | – | 10
Early deaths
Accidental deaths | 1 | – | – | 3
Moribund | 14 | 18 | 8 | 6
Natural deaths | 2 | 4 | 4 | 2
Survivors
Died last week of study | 1 | – | – | –
Terminal kill | 32 | 28 | 38 | 39
Animals examined microscopically | 60 | 50 | 50 | 60
Systems Examined at 3 Months with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Hemangiosarcoma, metastatic, blood vessel | 1 (2%) | – | – | –
Intestine small, jejunum | (50) | (50) | (50) | (50)
Liver | (50) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skin | – | – | 1 (2%) | –
Hepatocellular adenoma | – | 1 (2%) | – | –
Mesentery | (3) | (3) | (0) | (2)
Pancreas | (50) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skin | – | – | 1 (2%) | –
Acinus, adenoma | 1 (2%) | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (49)
Myoepithelioma | 1 (2%) | – | – | –
Sublingual gland, adenoma | – | – | 1 (2%) | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skin | – | – | 1 (2%) | –
Leiomyosarcoma | – | 1 (2%) | – | –
Squamous cell papilloma | – | – | – | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skin | – | – | 1 (2%) | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Adventitia, hemangiosarcoma | 1 (2%) | – | – | –
Heart | (50) | (50) | (50) | (50)
Carcinoma, metastatic, kidney | – | – | – | 1 (2%)
Fibrous histiocytoma, metastatic, skin | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (50)
Adenoma | – | 1 (2%) | – | 1 (2%)
Adrenal medulla | (49) | (50) | (49) | (50)
Pheochromocytoma benign | – | – | 1 (2%) | –
Pheochromocytoma malignant | – | 1 (2%) | – | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | 2 (4%) | 2 (4%)
Parathyroid gland | (45) | (48) | (47) | (49)
Adenoma | – | – | 1 (2%) | –
Pituitary gland | (50) | (49) | (50) | (48)
Pars distalis, adenoma | 20 (40%) | 24 (49%) | 13 (26%) | 13 (27%)
Pars distalis, adenoma, multiple | 1 (2%) | – | 1 (2%) | 3 (6%)
Pars intermedia, adenoma | 2 (4%) | 1 (2%) | 3 (6%) | 2 (4%)
Thyroid gland | (50) | (50) | (50) | (50)
Bilateral, C-cell, adenoma | – | – | 1 (2%) | –
C-cell, adenoma | 4 (8%) | 8 (16%) | 7 (14%) | 5 (10%)
C-cell, adenoma, multiple | 1 (2%) | – | – | –
C-cell, carcinoma | – | 1 (2%) | – | –
Follicular cell, adenoma | 3 (6%) | 1 (2%) | 3 (6%) | 2 (4%)
Follicular cell, carcinoma | – | 1 (2%) | – | –
General Body System
None
Genital System
Epididymis | (50) | (50) | (50) | (50)
Preputial gland | (50) | (50) | (50) | (50)
Prostate | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Seminal vesicle | (50) | (50) | (50) | (50)
Testes | (50) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skin | – | – | 1 (2%) | –
Bilateral, interstitial cell, adenoma | – | – | 1 (2%) | –
Interstitial cell, adenoma | – | – | – | 3 (6%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (3) | (0) | (2) | (1)
Pancreatic, hemangiosarcoma, metastatic, blood vessel | 1 (33%) | – | – | –
Lymph node, mandibular | (49) | (50) | (50) | (48)
Fibrous histiocytoma, metastatic, skin | – | – | – | 1 (2%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hemangioma | 1 (2%) | – | – | –
Hemangiosarcoma | 1 (2%) | 2 (4%) | 1 (2%)
Hemangiosarcoma, metastatic, blood vessel | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | – | – | –
Thymus | (49) | (49) | (49) | (50)
Fibrous histiocytoma, metastatic, skin | – | – | 1 (2%) | –
Schwannoma malignant | – | – | 1 (2%) | –
Thymoma benign | 1 (2%) | 1 (2%) | – | 3 (6%)
Integumentary System
Mammary gland | (47) | (50) | (50) | (50)
Fibroadenoma | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Basal cell adenoma | 2 (4%) | 1 (2%) | – | –
Basal cell carcinoma | 1 (2%) | – | – | –
Fibroma | – | – | 2 (4%) | –
Fibrous histiocytoma | – | – | 1 (2%) | –
Keratoacanthoma | 4 (8%) | – | 1 (2%) | 2 (4%)
Schwannoma malignant | – | – | – | 2 (4%)
Squamous cell papilloma | 1 (2%) | – | 1 (2%) | 1 (2%)
Subcutaneous tissue, fibroma | – | 1 (2%) | – | –
Subcutaneous tissue, fibrous histiocytoma | – | 1 (2%) | – | 1 (2%)
Subcutaneous tissue, schwannoma malignant | 2 (4%) | 1 (2%) | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Sarcoma, metastatic, skeletal muscle | 1 (2%) | – | – | –
Skeletal muscle | (1) | (0) | (0) | (1)
Rhabdomyosarcoma | – | – | – | 1 (100%)
Sarcoma | 1 (100%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Granular cell tumor benign | 1 (2%) | – | – | 1 (2%)
Meningioma malignant | – | 1 (2%) | – | –
Peripheral nerve | (0) | (2) | (1) | (0)
Spinal cord | (0) | (2) | (1) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | – | – | 1 (2%)
Carcinoma, metastatic, kidney | – | – | – | 1 (2%)
Carcinoma, metastatic, thyroid gland | – | 1 (2%) | – | –
Fibrous histiocytoma, metastatic, skin | – | 1 (2%) | 1 (2%) | –
Mediastinum, lipoma | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (49) | (50) | (50) | (50)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Renal tubule, carcinoma | – | – | – | 1 (2%)
Transitional epithelium, carcinoma | – | – | – | 1 (2%)
Urethra | (1) | (0) | (0) | (0)
Urinary bladder | (50) | (50) | (50) | (50)
Transitional epithelium, papilloma | 1 (2%) | – | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | – | 1 (2%) | 1 (2%)
Leukemia mononuclear | 1 (2%) | – | – | –
Lymphoma malignant | – | – | – | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^
Two-year study | 34 | 37 | 34 | 33
Total primary neoplasms
Two-year study | 54 | 50 | 44 | 48
Total animals with benign neoplasms
Two-year study | 30 | 32 | 29 | 28
Total benign neoplasms
Two-year study | 46 | 41 | 39 | 40
Total animals with malignant neoplasms
Two-year study | 8 | 8 | 5 | 8
Total malignant neoplasms
Two-year study | 8 | 9 | 5 | 8
Total animals with metastatic neoplasms
Two-year study | 2 | 2 | 1 | 2
Total metastatic neoplasms
Two-year study | 4 | 2 | 8 | 3

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Rats in the Two-year Gavage Study of Tetrabromobisphenol A

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Pituitary Gland (Pars Distalis): Adenoma
Overall rate^a^ | 21/50 (42%) | 24/49 (49%) | 14/50 (28%) | 16/48 (33%)
Adjusted rate^b^ | 47.4% | 52.4% | 29.8% | 37.0%
Terminal rate^c^ | 11/33 (33%) | 10/28 (36%) | 9/38 (24%) | 14/38 (37%)
First incidence (days) | 485 | 397 | 511 | 608
Poly-3 test^d^ | P = 0.084N | P = 0.395 | P = 0.063N | P = 0.221N
Pituitary Gland (Pars Intermedia): Adenoma
Overall rate | 2/50 (4%) | 1/49 (2%) | 3/50 (6%) | 2/48 (4%)
Adjusted rate | 5.0% | 2.4% | 6.6% | 4.7%
Terminal rate | 2/33 (6%) | 1/28 (4%) | 3/38 (8%) | 2/38 (5%)
First incidence (days) | 727 (T) | 727 (T) | 727 (T) | 727 (T)
Poly-3 test | P = 0.534 | P = 0.488N | P = 0.559 | P = 0.669N
Skin: Keratoacanthoma
Overall rate | 4/50 (8%) | 0/50 (0%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 10.1% | 0.0% | 2.2% | 4.5%
Terminal rate | 4/33 (12%) | 0/28 (0%) | 0/38 (0%) | 2/39 (5%)
First incidence (days) | 727 (T) | –^e^ | 723 | 727 (T)
Poly-3 test | P = 0.362N | P = 0.053N | P = 0.142N | P = 0.289N
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 5/50 (10%) | 0/50 (0%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 12.6% | 0.0% | 4.4% | 6.7%
Terminal rate | 5/33 (15%) | 0/28 (0%) | 0/38 (0%) | 2/39 (5%)
First incidence (days) | 727 (T) | – | 673 | 605
Poly-3 test | P = 0.434N | P = 0.026N | P = 0.165N | P = 0.295N
Skin: Squamous Cell Papilloma, Keratoacanthoma, Basal Cell Adenoma, or Basal Cell Carcinoma
Overall rate | 7/50 (14%) | 1/50 (2%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 17.6% | 2.4% | 4.4% | 6.7%
Terminal rate | 6/33 (18%) | 0/28 (0%) | 0/38 (0%) | 2/39 (5%)
First incidence (days) | 695 | 596 | 673 | 605
Poly-3 test | P = 0.159N | P = 0.023N | P = 0.051N | P = 0.114N
Skin: Fibroma or Fibrous Histiocytoma
Overall rate | 0/50 (0%) | 2/50 (4%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 0.0% | 4.8% | 6.5% | 2.3%
Terminal rate | 0/33 (0%) | 1/28 (4%) | 2/38 (5%) | 1/39 (3%)
First incidence (days) | – | 694 | 393 | 727 (T)
Poly-3 test | P = 0.508 | P = 0.249 | P = 0.148 | P = 0.521
Testes: Adenoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 2.2% | 6.8%
Terminal rate | 0/33 (0%) | 0/28 (0%) | 1/38 (3%) | 3/39 (8%)
First incidence (days) | – | – | 727 (T) | 727 (T)
Poly-3 test | P = 0.023 | –^f^ | P = 0.526 | P = 0.138
Thymus: Thymoma Benign
Overall rate | 1/49 (2%) | 1/49 (2%) | 0/49 (0%) | 3/50 (6%)
Adjusted rate | 2.5% | 2.4% | 0.0% | 6.7%
Terminal rate | 0/33 (0%) | 0/28 (0%) | 0/38 (0%) | 2/39 (5%)
First incidence (days) | 502 | 678 | – | 517
Poly-3 test | P = 0.180 | P = 0.752N | P = 0.476N | P = 0.349
Thyroid Gland (Follicular Cell): Adenoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 7.5% | 2.4% | 6.6% | 4.5%
Terminal rate | 2/33 (6%) | 1/28 (4%) | 2/38 (5%) | 2/39 (5%)
First incidence (days) | 622 | 727 (T) | 673 | 727 (T)
Poly-3 test | P = 0.487N | P = 0.290N | P = 0.604N | P = 0.456N
Thyroid Gland (Follicular Cell): Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 7.5% | 4.8% | 6.6% | 4.5%
Terminal rate | 2/33 (6%) | 2/28 (7%) | 2/38 (5%) | 2/39 (5%)
First incidence (days) | 622 | 727 (T) | 673 | 727 (T)
Poly-3 test | P = 0.415N | P = 0.481N | P = 0.604N | P = 0.456N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 5/50 (10%) | 8/50 (16%) | 8/50 (16%) | 5/50 (10%)
Adjusted rate | 12.3% | 18.9% | 17.7% | 11.3%
Terminal rate | 3/33 (9%) | 7/28 (25%) | 8/38 (21%) | 5/39 (13%)
First incidence (days) | 496 | 596 | 727 (T) | 727 (T)
Poly-3 test | P = 0.397N | P = 0.297 | P = 0.346 | P = 0.579N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 5/50 (10%) | 9/50 (18%) | 8/50 (16%) | 5/50 (10%)
Adjusted rate | 12.3% | 21.2% | 17.7% | 11.3%
Terminal rate | 3/33 (9%) | 7/28 (25%) | 8/38 (21%) | 5/39 (13%)
First incidence (days) | 496 | 596 | 727 (T) | 727 (T)
Poly-3 test | P = 0.355N | P = 0.212 | P = 0.346 | P = 0.579N
All Organs: Hemangiosarcoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 7.5% | 4.8% | 2.2% | 0.0%
Terminal rate | 2/33 (6%) | 1/28 (4%) | 0/38 (0%) | 0/39 (0%)
First incidence (days) | 687 | 673 | 654 | –
Poly-3 test | P = 0.053N | P = 0.476N | P = 0.260N | P = 0.101N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 4/50 (8%) | 2/50 (4%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 9.9% | 4.8% | 2.2% | 0.0%
Terminal rate | 2/33 (6%) | 1/28 (4%) | 0/38 (0%) | 0/39 (0%)
First incidence (days) | 502 | 673 | 654 | –
Poly-3 test | P = 0.025N | P = 0.320N | P = 0.146N | P = 0.050N
All Organs: Benign Neoplasms
Overall rate | 30/50 (60%) | 32/50 (64%) | 29/50 (58%) | 28/50 (56%)
Adjusted rate | 66.3% | 68.1% | 60.8% | 61.1%
Terminal rate | 19/33 (58%) | 16/28 (57%) | 22/38 (58%) | 24/39 (62%)
First incidence (days) | 244 | 397 | 511 | 517
Poly-3 test | P = 0.276N | P = 0.514 | P = 0.370N | P = 0.382N
All Organs: Malignant Neoplasms
Overall rate | 8/50 (16%) | 8/50 (16%) | 5/50 (10%) | 8/50 (16%)
Adjusted rate | 18.7% | 18.8% | 10.6% | 17.3%
Terminal rate | 2/33 (6%) | 4/28 (14%) | 1/38 (3%) | 4/39 (10%)
First incidence (days) | 196 | 625 | 393 | 447
Poly-3 test | P = 0.443N | P = 0.607 | P = 0.215N | P = 0.540N
All Organs: Benign or Malignant Neoplasms
Overall rate | 34/50 (68%) | 37/50 (74%) | 34/50 (68%) | 33/50 (66%)
Adjusted rate | 70.8% | 77.6% | 68.5% | 68.7%
Terminal rate | 19/33 (58%) | 18/28 (64%) | 23/38 (61%) | 25/39 (64%)
First incidence (days) | 196 | 397 | 393 | 447
Poly-3 test | P = 0.335N | P = 0.298 | P = 0.491N | P = 0.501N

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for pituitary gland, testes, thymus, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table A-3 Historical Incidence of Adenoma of the Testis in Control Male Wistar Han Rats^a^

| Incidence in Controls
Overall Historical Incidence: All Routes
Total (%) | 4/150 (2.7%)
Mean ± standard deviation | 2.7% ± 2.3%
Range | 0%–4%

^a^ Data as of June 2013.

Table A-4 Summary of the Incidence of Non-neoplastic Lesions in Male Rats in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month Interim Evaluation | 10 | – | – | 10
Early deaths
Accidental deaths | 1 | – | – | 3
Moribund | 14 | 18 | 8 | 6
Natural deaths | 2 | 4 | 4 | 2
Survivors
Died last week of study | 1 | – | – | –
Terminal kill | 32 | 28 | 38 | 39
Animals examined microscopically | 60 | 50 | 50 | 60
Alimentary System
Stomach, glandular | (10) | – | – | (10)
Cardiomyopathy | 1 (10%) | – | – | –
Cardiovascular System
Heart | (10) | – | – | (10)
Inflammation, chronic | 1 (10%) | – | – | 1 (10%)
Endocrine System
Pituitary gland | (10) | – | – | (10)
Cyst | 1 (10%) | – | – | 1 (10%)
Thyroid gland | (10) | – | – | (10)
Cyst | – | – | – | 1 (10%)
Ectopic thymus | 1 (10%) | – | – | –
Genital System
Preputial gland | (10) | – | – | (10)
Inflammation, chronic | 1 (10%) | – | – | 2 (20%)
Prostate | (10) | – | – | (10)
Hyperplasia | – | – | – | 1 (10%)
Inflammation | – | – | – | 1 (10%)
Seminal vesicle | (10) | – | – | (10)
Inflammation | 1 (10%) | – | – | –
Hematopoietic System
Lymph node, mesenteric | (10) | – | – | (10)
Hyperplasia, lymphoid | 4 (40%) | – | – | 3 (30%)
Necrosis | 1 (10%) | | | –
Respiratory System
Lung | (10) | – | – | (10)
Infiltration cellular, histiocyte | 1 (10%) | – | – | –
Inflammation, chronic | – | – | – | 1 (10%)
Perivascular, inflammation, chronic active | 1 (10%) | – | – | 2 (20%)
Nose | (10) | – | – | (10)
Olfactory epithelium, accumulation, hyaline droplet | 1 (10%) | – | – | 3 (30%)
Olfactory epithelium, inflammation, chronic active | – | – | – | 1 (10%)
Respiratory epithelium, accumulation, hyaline droplet | 1 (10%) | – | – | 1 (10%)
Special Senses System
Harderian gland | (10) | – | – | (10)
Inflammation, chronic | – | – | – | 1 (10%)
Urinary System
Kidney | (10) | – | – | (10)
Hydronephrosis | 1 (10%) | – | – | –
Nephropathy | 2 (20%) | – | – | 1 (10%)
Systems Examined at 3 Months with No Lesions Observed
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | –
Intestine large, cecum | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)
Ulcer | – | – | 1 (2%) | –
Intestine large, colon | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
Ulcer | 2 (4%) | – | – | –
Intestine large, rectum | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
Parasite metazoan | 1 (2%) | 1 (2%) | 1 (2%) | –
Ulcer | 1 (2%) | – | 1 (2%) | –
Intestine small, duodenum | (50) | (50) | (50) | (50)
Diverticulum | – | – | – | 1 (2%)
Metaplasia, osseous | – | – | – | 1 (2%)
Intestine small, ileum | (50) | (50) | (50) | (50)
Hyperplasia | – | – | – | 1 (2%)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 2 (4%) | 2 (4%) | – | 1 (2%)
Basophilic focus | 19 (38%) | 26 (52%) | 24 (48%) | 13 (26%)
Clear cell focus | 34 (68%) | 33 (66%) | 43 (86%) | 41 (82%)
Congestion | – | – | 1 (2%) | –
Eosinophilic focus | – | 3 (6%) | – | 3 (6%)
Fatty change | 28 (56%) | 35 (70%) | 30 (60%) | 27 (54%)
Hepatodiaphragmatic nodule | 1 (2%) | – | 2 (4%) | –
Inflammation, suppurative | – | – | 1 (2%) | –
Mixed cell focus | 9 (18%) | 10 (20%) | 12 (24%) | 16 (32%)
Necrosis | 1 (2%) | – | – | –
Thrombosis | – | 1 (2%) | – | –
Artery, vein, necrosis | – | 1 (2%) | – | –
Bile duct, hyperplasia | 3 (6%) | 5 (10%) | 7 (14%) | 7 (14%)
Oval cell, hyperplasia | – | 1 (2%) | – | –
Mesentery | (3) | (3) | (0) | (2)
Inflammation, chronic | 1 (33%) | – | – | –
Fat, necrosis | 2 (67%) | 3 (100%) | – | 2 (100%)
Pancreas | (50) | (50) | (50) | (50)
Atrophy | 4 (8%) | 1 (2%) | 1 (2%) | 2 (4%)
Necrosis | 1 (2%) | – | – | –
Acinus, hyperplasia | 1 (2%) | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (49)
Stomach, forestomach | (50) | (50) | (50) | (50)
Cyst | – | – | 1 (2%) | –
Inflammation, chronic | 6 (12%) | 5 (10%) | – | 1 (2%)
Mineralization | 1 (2%) | – | – | –
Necrosis | 1 (2%) | – | – | –
Ulcer | 1 (2%) | 1 (2%) | 2 (4%) | –
Epithelium, hyperplasia | – | – | 1 (2%) | –
Stomach, glandular | (50) | (50) | (50) | (50)
Inflammation, chronic | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Mineralization | – | 3 (6%) | 4 (8%) | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Ulcer | 1 (2%) | – | 1 (2%) | 1 (2%)
Epithelium, glands, hyperplasia | – | 1 (2%) | – | 1 (2%)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Adventitia, aorta, hemorrhage | 1 (2%) | – | – | –
Aorta, inflammation, chronic | 1 (2%) | – | – | –
Aorta, mineralization | – | – | – | 1 (2%)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 33 (66%) | 23 (46%) | 23 (46%) | 30 (60%)
Mineralization | – | – | – | 1 (2%)
Atrium, epicardium, inflammation, chronic | 1 (2%) | – | – | –
Endocardium, hyperplasia | 1 (2%) | 1 (2%) | 1 (2%)
Epicardium, fibrosis | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (50)
Cytoplasmic alteration | – | – | 1 (2%) | –
Degeneration, cystic | 1 (2%) | – | – | –
Hemorrhage | – | 1 (2%) | – | –
Hyperplasia | 12 (24%) | 5 (10%) | 6 (12%) | 9 (18%)
Metaplasia, osseous | – | – | 1 (2%) | –
Necrosis | – | 2 (4%) | 1 (2%) | –
Vacuolization cytoplasmic | 17 (34%) | 17 (34%) | 15 (31%) | 16 (32%)
Adrenal medulla | (49) | (50) | (49) | (50)
Hyperplasia | 3 (6%) | 1 (2%) | 3 (6%) | 2 (4%)
Necrosis | – | 1 (2%) | 1 (2%) | –
Vacuolization cytoplasmic | – | – | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | – | –
Parathyroid gland | (45) | (48) | (47) | (49)
Hyperplasia | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Pituitary gland | (50) | (49) | (50) | (48)
Cyst | 1 (2%) | 3 (6%) | – | 3 (6%)
Pars distalis, hyperplasia | 8 (16%) | 8 (16%) | 9 (18%) | 7 (15%)
Pars intermedia, hyperplasia | 2 (4%) | 2 (4%) | 2 (4%) | 2 (4%)
Thyroid gland | (50) | (50) | (50) | (50)
Cyst | 1 (2%) | – | – | –
C-cell, hyperplasia | 16 (32%) | 27 (54%) | 26 (52%) | 19 (38%)
Follicle, hyperplasia | 3 (6%) | | 2 (4%) | 2 (4%)
General Body System
None
Genital System
Epididymis | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | 1 (2%) | – | –
Granuloma sperm | – | 1 (2%) | – | –
Preputial gland | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | 6 (12%) | 10 (20%) | 3 (6%)
Prostate | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | –
Fibrosis | – | – | – | 1 (2%)
Hyperplasia | 2 (4%) | – | – | –
Inflammation | 12 (24%) | 19 (38%) | 12 (24%) | 14 (28%)
Artery, inflammation | 1 (2%) | – | – | –
Seminal vesicle | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | –
Inflammation | 3 (6%) | 5 (10%) | 2 (4%) | 1 (2%)
Testes | (50) | (50) | (50) | (50)
Edema | 35 (70%) | 32 (64%) | 37 (74%) | 36 (72%)
Arteriole, necrosis, fibrinoid | – | – | 1 (2%) | –
Germinal epithelium, atrophy | – | 4 (8%) | 1 (2%) | 2 (4%)
Germinal epithelium, mineralization | – | – | – | 2 (4%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (3) | (0) | (2) | (1)
Mediastinal, hyperplasia, lymphoid | 1 (33%) | – | – | –
Renal, ectasia | – | – | 1 (50%) | –
Lymph node, mandibular | (49) | (50) | (50) | (48)
Atrophy | – | 1 (2%) | – | –
Ectasia | – | 1 (2%) | – | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | –
Ectasia | – | – | 1 (2%) | 4 (8%)
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Necrosis | – | 1 (2%) | – | –
Spleen | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Congestion | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 8 (16%) | 15 (30%) | 9 (18%) | 10 (20%)
Necrosis | 1 (2%) | – | – | –
Capsule, fibrosis | – | 1 (2%) | – | –
Lymphoid follicle, atrophy | 6 (12%) | 5 (10%) | – | 2 (4%)
Thymus | (49) | (49) | (49) | (50)
Atrophy | 39 (80%) | 46 (94%) | 44 (90%) | 45 (90%)
Hyperplasia | 1 (2%) | – | – | –
Inflammation, chronic | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (47) | (50) | (50) | (50)
Skin | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | –
Ulcer | 10 (20%) | 7 (14%) | 3 (6%) | 6 (12%)
Epidermis, hyperplasia | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteosclerosis | – | – | – | 1 (2%)
Skeletal muscle | (1) | (0) | (0) | (1)
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 9 (18%) | 12 (24%) | 9 (18%) | 5 (10%)
Gliosis | – | – | – | 1 (2%)
Peripheral nerve | (0) | (2) | (1) | (0)
Axon, degeneration | – | 1 (50%) | 1 (100%) | –
Spinal cord | (0) | (2) | (1) | (0)
Axon, degeneration | | 1 (50%) | 1 (100%)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Foreign body | – | – | – | 1 (2%)
Hemorrhage | – | 1 (2%) | – | –
Inflammation, granulomatous | 2 (4%) | 2 (4%) | – | 3 (6%)
Inflammation, chronic | 8 (16%) | 6 (12%) | 6 (12%) | 6 (12%)
Metaplasia, osseous | – | – | – | 3 (6%)
Alveolar epithelium, necrosis | – | 1 (2%) | – | –
Alveolus, inflammation | 1 (2%) | – | – | –
Arteriole, thrombosis | – | 1 (2%) | – | –
Bronchiole, hyperplasia | 3 (6%) | 2 (4%) | 1 (2%) | 4 (8%)
Vein, necrosis | – | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Inflammation | 8 (16%) | 5 (10%) | 7 (14%) | 8 (16%)
Ulcer | 1 (2%) | – | – | –
Goblet cell, hyperplasia | 1 (2%) | – | – | 1 (2%)
Olfactory epithelium, degeneration | – | – | 2 (4%)
Trachea | (50) | (50) | (50) | (50)
Inflammation | 2 (4%) | – | – | –
Inflammation, chronic | – | 1 (2%) | – | –
Perforation | – | – | – | 1 (2%)
Peritracheal tissue, inflammation | 1 (2%) | – | – | –
Special Senses System
Eye | (50) | (50) | (50) | (50)
Cataract | – | – | 1 (2%) | –
Inflammation | 1 (2%) | – | – | –
Inflammation, acute | – | 1 (2%) | – | –
Retina, atrophy | 1 (2%) | 1 (2%) | 3 (6%) | –
Harderian gland | (49) | (50) | (50) | (50)
Hyperplasia | – | 1 (2%) | 1 (2%) | 2 (4%)
Inflammation | 1 (2%) | – | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | 1 (2%) | 1 (2%) | 4 (8%) | 3 (6%)
Hydronephrosis | – | 2 (4%) | 1 (2%) | 1 (2%)
Infarct | – | – | – | 1 (2%)
Inflammation, suppurative, multifocal | – | 1 (2%) | – | –
Inflammation, suppurative | – | – | – | 1 (2%)
Inflammation, chronic | – | – | – | 2 (4%)
Metaplasia, lipocyte | – | – | 1 (2%) | –
Metaplasia, osseous | – | – | – | 1 (2%)
Nephropathy | 39 (78%) | 30 (60%) | 35 (70%) | 31 (62%)
Pelvis, inflammation, suppurative | 4 (8%) | 2 (4%) | 2 (4%) | 5 (10%)
Renal tubule, accumulation, hyaline droplet | 1 (2%) | – | 1 (2%) | –
Renal tubule, dilatation | – | – | 1 (2%) | –
Urethra | (1) | (0) | (0) | (0)
Inflammation, chronic | 1 (100%) | – | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
Transitional epithelium, hyperplasia | – | 1 (2%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.