# Overview

The class of compounds known as metalworking fluids was nominated by the National Institute of Occupational Safety and Health for toxicologic testing by the National Toxicology Program. Individual metalworking fluids are formulated based upon the intended use, and hundreds of metalworking fluid formulations are believed to be in use. Selection of specific metalworking fluids for toxicologic testing based upon use and production data was not possible because these data are considered proprietary by the industry and were not available. For this reason, selection of specific metalworking fluids was initiated by selecting 30 heavily marketed soluble oils and semisynthetic fluids. These two classes, soluble oils and semisynthetic fluids, encompass the majority of metalworking fluids in use. The number of candidate metalworking fluids was reduced to 18 based on commercial availability, Material Safety Data Sheets, and elimination of redundant formulations. The 18 products underwent chemical analysis and the number of potential test compounds was reduced to nine by selecting from a minimum of three major producers a combination of representative formulations and complex, unique formulations. The remaining nine products underwent further chemical analysis and genetic toxicity assessment prior to selecting four formulations for inhalation studies. CIMSTAR 3800, TRIM VX, Syntilo 1023, and TRIM SC210 were selected for 3-month inhalation studies. Based on the results of the 3-month studies, CIMSTAR 3800 and TRIM VX were selected for 2-year studies.