# Peer Review

The members of the Peer Review Panel who evaluated the draft NTP Technical Report on the Toxicology Studies of CIMSTAR 3800 in F344/NTac Rats and B6C3F1/N Mice and Toxicology and Carcinogenesis Studies of CIMSTAR 3800 in Wistar Han [Crl:WI(Han)] Rats and B6C3F1/N Mice (Inhalation Studies) on May 22, 2014, are listed below. Panel members served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers had five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

## Peer Reviewers

- Hillary M. Carpenter, III, Ph.D. (Chairperson)
  Minnesota Department of Health
  Maplewood, Minnesota, USA
- Michael W. Conner, D.V.M.
  Theravance, Inc.
  San Francisco, California, USA
- Michelle V. Fanucchi, Ph.D. (Primary Reviewer)
  School of Public Health
  University of Alabama
  Birmingham, Alabama, USA
- Charles R. Mahrt, D.V.M., M.S., Ph.D. (Primary Reviewer)
  Eli Lilly and Company
  Indianapolis, Indiana, USA
- Jon C. Mirsalis, Ph.D.
  SRI International
  Menlo Park, California, USA
- Gary H. Perdew, Ph.D.
  College of Agricultural Sciences
  Pennsylvania State University
  State College, Pennsylvania, USA
- Karen Regan, D.V.M. (Primary Reviewer)
  Regan Pathology/Toxicology Services, Inc.
  Ashland, Ohio, USA