# References

1 Gauthier SL Metalworking fluids: oil mist and beyond. Appl Occup Environ Hyg. 2003;18(11):818–824. 10.1080/10473220390237313 14555433
2 Meyer SR, Boslett WS. Working safely with metalworking fluids. Fabricators and Manufacturers Association, International; 2001. https://www.thefabricator.com/article/safety/working-safely-with-metalworking-fluids
3 Woskie SR Virji MA Hallock M Smith TJ Hammond SK Summary of the findings from the exposure assessments for metalworking fluid mortality and morbidity studies. Appl Occup Environ Hyg. 2003;18(11):855–864. 10.1080/10473220390237377 14555438
4 Frazier AD Cutting fluid applications for today’s materials. Improving Production with Coolants and Lubricants. Dearborn (MI): Society of Manufacturing Engineers; 1982. p. 19–24.
5 Gordon T Metalworking fluid—the toxicity of a complex mixture. J Toxicol Environ Health A. 2004;67(3):209–219. 10.1080/15287390490266864 14681076
6 Arrandale VH Liss GM Tarlo SM Pratt MD Sasseville D Kudla I Holness DL Occupational contact allergens: are they also associated with occupational asthma? Am J Ind Med. 2012;55(4):353–360. 10.1002/ajim.22015 22238032
7 Zugerman C Cutting fluids. Their use and effects on the skin. Occup Med. 1986;1(2):245–258. 2956708
8 Independent Lubricant Manufacturers Association (ILMA). Report on the volume of lubricants manufactured in the United States and Canada by Independent Lubricant Manufacturers in 1999, August 11, 2000. Alexandria, VA; 2000.
9 National Institute of Occupational Safety and Health (NIOSH). National Occupational Exposure Survey (1981-1983), unpublished provisional data as of July 1, 1990. Cincinnati, OH: NIOSH. 1990.
10 National Institute of Occupational Safety and Health (NIOSH). What you need to know about occupational exposure to metalworking fluids. NIOSH; 2013. DHHS Publication No. 98-116. https://web.archive.org/web/20120508081324/http://www.cdc.gov/niosh/pdfs/98-116.pdf
11 Bennett EO Bennett DL Minimizing human exposure to chemicals in metalworking fluids. Lubr Eng. 1987;43(3):167–175.
12 Simpson AT Stear M Groves JA Piney M Bradley SD Stagg S Crook B Occupational exposure to metalworking fluid mist and sump fluid contaminants. Ann Occup Hyg. 2003;47(1):17–30. 12505903
13 Geier J Lessmann H Dickel H Frosch PJ Koch P Becker D Jappe U Aberer W Schnuch A Uter W Patch test results with the metalworking fluid series of the German Contact Dermatitis Research Group (DKG). Contact Dermat. 2004;51(3):118–130. 10.1111/j.0105-1873.2004.00416.x 15479200
14 Suuronen K Aalto-Korte K Piipari R Tuomi T Jolanki R Occupational dermatitis and allergic respiratory diseases in Finnish metalworking machinists. Occup Med (Lond). 2007;57(4):277–283. 10.1093/occmed/kqm011 17392449
15 National Institute of Occupational Safety and Health (NIOSH). Criteria for a recommended standard: Occupational exposure to metalworking fluids. NIOSH; 1998. DHHS Publication 98-102. https://www.cdc.gov/niosh/docket/archive/pdfs/niosh-046/046-Final-publication-98-102.pdf
16 Schaper M Detwiler K Evaluation of the acute respiratory effects of aerosolized machining fluids in mice. Fundam Appl Toxicol. 1991;16(2):309–319. 10.1016/0272-0590(91)90115-K 2055361
17 Alarie Y Irritating properties of airborne materials to the upper respiratory tract. Arch Environ Health. 1966;13(4):433–449. 10.1080/00039896.1966.10664593 5921282
18 Schaper MM Detwiler-Okabayashi KA An approach for evaluating the respiratory irritation of mixtures: application to metalworking fluids. Arch Toxicol. 1995;69(10):671–676. 10.1007/s002040050230 8572923
19 Lim CH Yu IJ Kim HY Lee SB Marshak DR Lee JH Kim KJ Effect of water-soluble metal working fluid aerosols on respiratory system after 13 weeks of repeated inhalation exposure in F344 rats. Toxicol Ind Health. 2005;21(9):207–213. 10.1191/0748233705th230oa 16342471
20 Thorne PS DeKoster JA Pulmonary effects of machining fluids in guinea pigs and mice. Am Ind Hyg Assoc J. 1996;57(12):1168–1172. 10.1080/15428119691014297 8976591
21 DeLorme MP Gao X Doyon-Reale N Barraclough-Mitchell H Bassett DJ Inflammatory effects of inhaled endotoxin-contaminated metal working fluid aerosols in rats. J Toxicol Environ Health A. 2003;66(1):7–24. 10.1080/15287390306458 12587288
22 Lim CH Yu IJ Kim HY Lee SB Kang MG Marshak DR Moon CK Respiratory effect of acute and subacute exposure to endotoxin-contaminated metal working fluid (MWF) aerosols on Sprague-Dawley rats. Arch Toxicol. 2005;79(6):321–329. 10.1007/s00204-004-0640-6 15692821
23 Meredith SK McDonald JC Work-related respiratory disease in the United Kingdom, 1989-1992: report on the SWORD project. Occup Med (Lond). 1994;44(4):183–189. 10.1093/occmed/44.4.183 7949060
24 Bernstein DI Lummus ZL Santilli G Siskosky J Bernstein IL Machine operator’s lung. A hypersensitivity pneumonitis disorder associated with exposure to metalworking fluid aerosols. Chest. 1995;108(3):636–641. 10.1378/chest.108.3.636 7656609
25 Kreiss K Cox-Ganser J Metalworking fluid-associated hypersensitivity pneumonitis: A workshop summary. Am J Ind Med. 1997; 32(4):423-432. 10.1002/(SICI)1097-0274(199710)32:4<423::AID-AJIM16>3.0.CO;2-5
26 Rose C Robins T Harkaway P Centers for Disease Control and Prevention (CDC) Biopsy-confirmed hypersensitivity pneumonitis in automobile production workers exposed to metalworking fluids—Michigan, 1994-1995. MMWR. 1996;45(28):606–610. 8676853
27 Rosenman KD Reilly MJ Watt FC Kalinowski DJ 1993 annual report on occupational asthma in Michigan. Michigan, US: Michigan State University and Michigan Department of Public Health; 1994.
28 Hendy MS Beattie BE Burge PS Occupational asthma due to an emulsified oil mist. Br J Ind Med. 1985;42(1):51–54. 10.1136/oem.42.1.51 3965015
29 Kennedy SM Acquired airway hyperresponsiveness from nonimmunogenic irritant exposure. Occup Med. 1992;7(2):287–300. 1615364
30 Michel O Ginanni R Le Bon B Content J Duchateau J Sergysels R Inflammatory response to acute inhalation of endotoxin in asthmatic patients. Am Rev Respir Dis. 1992;146(2):352–357. 10.1164/ajrccm/146.2.352 1489124
31 Eisen EA Holcroft CA Greaves IA Wegman DH Woskie SR Monson RR A strategy to reduce healthy worker effect in a cross-sectional study of asthma and metalworking fluids. Am J Ind Med. 1997; 31(6):671-677. 10.1002/(SICI)1097-0274(199706)31:6<671::AID-AJIM1>3.0.CO;2-U
32 Greaves IA Eisen EA Smith TJ Pothier LJ Kriebel D Woskie SR Kennedy SM Shalat S Monson RRRespiratory health of automobile workers exposed to metal-working fluid aerosols: Respiratory symptoms. Am J Ind Med. 1997; 32(5):450-459. 10.1002/(SICI)1097-0274(199711)32:5<450::AID-AJIM4>3.0.CO;2-W
33 Rosenman KD Reilly MJ Kalinowski D Work-related asthma and respiratory symptoms among workers exposed to metal-working fluids. Am J Ind Med. 1997; 32(4):325-331. 10.1002/(SICI)1097-0274(199710)32:4<325::AID-AJIM1>3.0.CO;2-T
34 Robertson AS Weir DC Burge PS Occupational asthma due to oil mists. Thorax. 1988;43(3):200–205. 10.1136/thx.43.3.200 3406905
35 Savonius B Keskinen H Tuppurainen M Kanerva L Occupational asthma caused by ethanolamines. Allergy. 1994;49(10):877–881. 10.1111/j.1398-9995.1994.tb00791.x 7709998
36 Kriebel D Sama SR Woskie S Christiani DC Eisen EA Hammond SK Milton DK Smith M Virji MAA field investigation of the acute respiratory effects of metal working fluids. I. Effects of aerosol exposures. Am J Ind Med. 1997; 31(6):756-766. 10.1002/(SICI)1097-0274(199706)31:6%3C756::AID-AJIM13%3E3.0.CO;2-X
37 Massin N Bohadana AB Wild P Goutet P Kirstetter H Toamain JP Airway responsiveness, respiratory symptoms, and exposures to soluble oil mist in mechanical workers. Occup Environ Med. 1996;53(11):748–752. 10.1136/oem.53.11.748 9038798
38 Robins T Seixas N Franzblau A Abrams L Minick S Burge H Schork MA Acute respiratory effects on workers exposed to metalworking fluid aerosols in an automotive transmission plant. Am J Ind Med. 1997; 31(5):510-524. 10.1002/(SICI)1097-0274(199705)31:5%3C510::AID-AJIM4%3E3.0.CO;2-X
39 Robins T, Sexias N, Franzblau A, Burge H, Abrams L, Minick S. Respiratory effects of machining fluid aerosols. Final report to the UAW-GM Occupational Health Advisory Board. 1994.
40 Forbes JD Markham TN Ann Arbor Case Reports. Cutting and grinding fluids in chronic pulmonary airway disease. J Occup Med. 1967;9(8):421–423. 6029747
41 Sprince NL Thorne PS Popendorf W Zwerling C Miller ER DeKoster JA Respiratory symptoms and lung function abnormalities among machine operators in automobile production. Am J Ind Med. 1997; 31(4):403-413. 10.1002/(SICI)1097-0274(199704)31:4%3C403::AID-AJIM5%3E3.0.CO;2-W
42 Desoille H Philbert M Ripault G Cavig-Neaux A Rossignoli H Carcinogenic action of mineral oils used in metal works. Arch Mal Prof. 1973;34(12):669–680.
43 Gilman JP Vesselinovitch SD Cutting oils and squamous-cell carcinoma. II. An experimental study of the carcinogenicity of two types of cutting oils. Br J Ind Med. 1955;12(3):244–248. 10.1136/oem.12.3.244 13240030
44 Gupta KP Mehrotra NK Tumor initiation in mouse skin by cutting oils. Environ Res. 1989;49(2):225–232. 10.1016/S0013-9351(89)80068-4 2502387
45 Jepsen JR Stoyanov S Unger M Clausen J Christensen HE Cutting fluids and their effects on the skin of mice. An experimental study with special reference to carcinogenicity. Acta Pathol Microbiol Scand [A]. 1977;85(5):731–738. 920187
46 McKee RH Scala RA Chauzy C An evaluation of the epidermal carcinogenic potential of cutting fluids. J Appl Toxicol. 1990;10(4):251–256. 10.1002/jat.2550100405 2391406
47 Wang D Huang WQ Wang HW Mutagenicity and carcinogenicity studies of homemade “rust-proof cutting fluid”. Teratog Carcinog Mutagen. 1988;8(1):35–43. 10.1002/tcm.1770080105 2897723
48 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of triethanolamine (CAS No. 102-71-6) in F344/N rats and B6C3F1 mice (dermal studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1999. Technical Report Series No. 449. NIH Publication No. 00-3365.
49 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of triethanolamine (CAS No. 102-71-6) in B6C3F1 mice (dermal study). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2004. Technical Report Series No. 518. NIH Publication No. 04 4452.
50 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of diethanolamine (CAS No. 111-42-2) in F344/N rats and B6C3F1 mice (dermal studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1999. Technical Report Series No. 478. NIH Publication No. 99-3968.
51 Cruickshank CN Gourevitch A Skin cancer of the hand and forearm. Br J Ind Med. 1952;9(1):74–79. 10.1136/oem.9.1.74 14895807
52 Jarvholm B Easton D Models for skin tumour risks in workers exposed to mineral oils. Br J Cancer. 1990;62(6):1039–1041. 10.1038/bjc.1990.435 2257210
53 Jarvholm B Fast K Lavenius B Tomsic P Exposure to cutting oils and its relation to skin tumors and premalignant skin lesions on the hands and forearms. Scand J Work Environ Health. 1985;11(5):365–369. 10.5271/sjweh.2211 4071002
54 Cruickshank CN Squire JR Skin cancer in the engineering industry from the use of mineral oil. Br J Ind Med. 1950;7(1):1–11. 10.1136/oem.7.1.1 15403146
55 Jarvholm B Lavenius B Mortality and cancer morbidity in workers exposed to cutting fluids. Arch Environ Health. 1987;42(6):361–366. 10.1080/00039896.1987.9934360 3439814
56 Roush GC Kelly JA Meigs JW Flannery JT Scrotal carcinoma in Connecticut metalworkers: sequel to a study of sinonasal cancer. Am J Epidemiol. 1982;116(1):76–85. 10.1093/oxfordjournals.aje.a113404 7102658
57 International Agency for Research on Cancer (IARC) Suppl. 7. Mineral oils: Untreated and mildly-treated oils (group 1). Highly-refined oils (group 3). Vol. 1-42. Lyon, France: IARC; 1987. p. 252–259. (IARC Monographs on the Evaluation of Carcinogenic Risks to Humans: Overall evaluation of carcinogenicity: An updating of IARC monographs.).
58 Tolbert PE Eisen EA Pothier LJ Monson RR Hallock MF Smith TJ Mortality studies of machining-fluid exposure in the automobile industry. II. Risks associated with specific fluid types. Scand J Work Environ Health. 1992;18(6):351–360. 10.5271/sjweh.1562 1485160
59 Eisen EA Tolbert PE Hallock MF Monson RR Smith TJ Woskie SR Mortality studies of machining fluid exposure in the automobile industry. III: A case-control study of larynx cancer. Am J Ind Med. 1994;26(2):185–202. 10.1002/ajim.4700260205 7977395
60 Bardin JA Eisen EA Tolbert PE Hallock MF Hammond SK Woskie SR Smith TJ Monson RRMortality studies of machining fluid exposure in the automobile industry. V: A case-control study of pancreatic cancer. Am J Ind Med. 1997; 32(3):240-247. 10.1002/(SICI)1097-0274(199709)32:3%3C240::AID-AJIM9%3E3.0.CO;2-0
61 Costello S Friesen MC Christiani DC Eisen EA Metalworking fluids and malignant melanoma in autoworkers. Epidemiology. 2011;22(1):90–97. 10.1097/EDE.0b013e3181fce4b8 20975563
62 Behrens T Pohlabeln H Mester B Langner I Schmeisser N Ahrens W Exposure to metal-working fluids in the automobile industry and the risk of male germ cell tumours. Occup Environ Med. 2012;69(3):224–226. 10.1136/oemed-2011-100070 22131554
63 Langner I Schmeisser N Mester B Behrens T Gottlieb A Ahrens W Case-control study of male germ cell tumors nested in a cohort of car-manufacturing workers: findings from the occupational history. Am J Ind Med. 2010;53(10):1006–1018. 10.1002/ajim.20865 20860055
64 Fuchs J Burg J Hengstler JG Bolm-Audorff U Oesch F DNA damage in mononuclear blood cells of metal workers exposed to N-nitrosodiethanolamine in synthetic cutting fluids. Mutat Res. 1995;342(1-2):95–102. 10.1016/0165-1218(95)90094-2 7885399
65 Hill MA, Watson CR, Moss OR. An interactive computer program for particle size analysis. Richland, WA: Pacific Northwest Laboratory; 1977. PNL-2405, UC-32. 10.2172/5306504
66 King-Herbert A Thayer K NTP workshop: Animal models for the NTP rodent cancer bioassay: Stocks and strains—should we switch? Toxicol Pathol. 2006;34(6):802–805. 10.1080/01926230600935938 17162538
67 Brecher G Schneiderman M A time-saving device for the counting of reticulocytes. Am J Clin Pathol. 1950;20(11):1079–1083. 10.1093/ajcp/20.11_ts.1079 14783090
68 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. 10.1177/019262338201000210 28094716
69 Boorman GA Montgomery CA Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
70 McConnell EE Solleveld HA Swenberg JA Boorman GA Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986;76(2):283–289. 3456066
71 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958;53(282):457–481.10.1080/01621459.1958.10501452
72 Cox DR Regression models and life‐tables. J R Stat Soc [Ser A]. 1972;34(2):187–202.
73 Tarone RE Tests for trend in life table analysis. Biometrika. 1975;62(3):679–690.10.1093/biomet/62.3.679
74 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44(2):417–431. 10.2307/2531856 3390507
75 Portier CJ Bailer AJ Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989;12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
76 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology. Section 6.3.2. London, UK: Chapman and Hall; 1997.
77 Portier CJ Hedges JC Hoel DG Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986;46(9):4372–4378. 3731095
78 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;49(3):793–801. 10.2307/2532200 8241374
79 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121.10.1080/01621459.1955.10501294
80 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. 10.2307/2528930 5547548
81 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. 10.2307/2556164 5037867
82 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
83 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. 10.2307/2531254 3719054
84 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252.10.1080/00401706.1964.10490181
85 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1-2):133–145.10.1093/biomet/41.1-2.133
86 Dixon WJ Massey FJ Introduction to statistical analysis. 2nd ed. New York (NY): McGraw Hill Book Company Inc; 1957. p. 276–278, 412.
87 Haseman JK Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992;26(2):191–200.10.1177/009286159202600210
88 Haseman JK Rao GN Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992;20(1):52–60. 10.1177/019262339202000107 1411131
89 Haseman JKData analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharm. 1995; 21(1):52-59. 10.1006/rtph.1995.1009
90 Code of Federal Regulations (CFR). 21:Part 58.
91 Heddle JA Hite M Kirkhart B Mavournin K MacGregor JT Newell GW Salamone MF The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983;123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
92 Schmid W The micronucleus test. Mutat Res. 1975;31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
93 Miller JA Miller EC Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH Watson JD Winsten JAeditors. Origins of Human Cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. p. 605–627.
94 Crawford BD Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA Flamm WG Lorentzen RJeditors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton (NJ): Princeton Scientific Publishing Co., Inc; 1985. p. 13–59.
95 Straus DS Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67(2):233–241. 7021938
96 Ashby J Tennant RW Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991;257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
97 Tennant RW Margolin BH Shelby MD Zeiger E Haseman JK Spalding J Caspary W Resnick M Stasiewicz S Anderson B Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987;236(4804):933–941. 10.1126/science.3554512 3554512
98 Zeiger E Haseman JK Shelby MD Margolin BH Tennant RWEvaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutag. 1990; 16 Suppl 18:1-14. 10.1002/em.2850160502
99 Shelby MD Erexson GL Hook GJ Tice RREvaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutag. 1993; 21(2):160-179. 10.1002/em.2850210210
100 Shelby MD Witt KL Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutag. 1995; 25(4):302-313. 10.1002/em.2850250407
101 Witt KL Knapton A Wehr CM Hook GJ Mirsalis J Shelby MD MacGregor JT Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short‐term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutag. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3%3C163::AID-EM1%3E3.0.CO;2-P
102 National Toxicology Program (NTP). Toxicology studies of tetrabromobisphenol A (CAS No. 79 94 7) in F344/NTac rats and B6C3F1/N mice and toxicology and carcinogenesis studies of tetrabromobisphenol A in Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2014. Technical Report Series No. 587. NIH Publication No. 14-5929.
103 National Toxicology Program (NTP). Toxicology studies of green tea extract in F344/NTac rats and B6C3F1/N mice and toxicology and carcinogenesis studies of green tea extract in Wistar Han[Crl:WI(Han)] rats and B6C3F1/N mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2015. Technical Report Series No. 585.
104 Haschek WM Rousseaux CG Wallig MA Fundamentals of toxicologic pathology. London, UK: Elsevier, Inc.; 2010. p. 93–133.10.1016/B978-0-12-370469-6.00006-4
105 Jaakkola MS Suuronen K Luukkonen R Jarvela M Tuomi T Alanko K Makela EA Jolanki R Respiratory symptoms and conditions related to occupational exposures in machine shops. Scand J Work Environ Health. 2009;35(1):64–73. 10.5271/sjweh.1299 19190832
106 Oudyk J Haines AT D’Arcy J Investigating respiratory responses to metalworking fluid exposure. Appl Occup Environ Hyg. 2003;18(11):939–946. 10.1080/10473220390237610 14555447
107 Park DU Jin KW Koh DH Kim BK Kim KS Park DY Association between use of synthetic metalworking fluid and risk of developing rhinitis-related symptoms in an automotive ring manufacturing plant. J Occup Health. 2008;50(2):212–220. 10.1539/joh.O7006 18403875
108 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of diethylamine (CAS No. 109-89-7) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2011. Technical Report Series No. 566. NIH Publication No. 12-5908.
109 National Toxicology Program (NTP). Toxicity studies of triethylamine (CAS No. 121-44-8) administered by inhalation to F344/N rats and B6C3F1/N mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2015. Toxicity Report Series No. 78.
110 Henriks-Eckerman ML Suuronen K Jolanki R Riala R Tuomi T Determination of occupational exposure to alkanolamines in metal-working fluids. Ann Occup Hyg. 2007;51(2):153–160. 17189280
111 Mortelmans K Haworth S Lawlor T Speck W Tainer B Zeiger E Salmonella mutagenicity tests: II. Results from the testing of 270 chemicals. Environ Mutagen. 1986;8 Suppl 7:1–119. 10.1002/em.2860080802 3516675
112 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Speck W Salmonella mutagenicity tests: III. Results from the testing of 255 chemicals. Environ Mutagen. 1987;9 Suppl 9:1–109. 10.1002/em.2860090602 3552650
113 Zeiger E Anderson B Haworth S Lawlor T Mortelmans KSalmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutag. 1992; 19 Suppl 21:2-141. 10.1002/em.2850190603
114 Witt KL Livanos E Kissling GE Torous DK Caspary W Tice RR Recio L Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008;649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
115 Dertinger SD Camphausen K Macgregor JT Bishop ME Torous DK Avlasevich S Cairns S Tometsko CR Menard C Muanza T Three-color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutag. 2004; 44(5):427-435. 10.1002/em.20075
116 Kissling GE Dertinger SD Hayashi M MacGregor JT Sensitivity of the erythrocyte micronucleus assay: dependence on number of cells scored and inter-animal variability. Mutat Res. 2007;634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
117 United States Environmental Protection Agency (USEPA). Method 1664, revision A: n-Hexane Extractable Material (HEM; oil and grease) and silica gel treated n-Hexane Extractable Material (SGT HEM; non polar material) by extraction and gravimetry. Washington, DC: U.S. Environmental Protection Agency, Office of Water; 1999. EPA 821-R-89-98-002; PB99-1-21949.