# Conclusions

Under the conditions of these 2-year inhalation studies, there was equivocal evidence of carcinogenic activity^1^ of CIMSTAR 3800 in male Wistar Han rats based on the incidences of prostate gland adenoma or carcinoma (combined). There was equivocal evidence of carcinogenic activity of CIMSTAR 3800 in female Wistar Han rats based on the incidences of squamous cell papilloma or keratoacanthoma (combined) of the skin and adenocarcinoma or mixed malignant Müllerian tumor (combined) of the uterus. There was no evidence of carcinogenic activity of CIMSTAR 3800 in male B6C3F1/N mice exposed to 10, 30, or 100 mg/m^3^. There was some evidence of carcinogenic activity of CIMSTAR 3800 in female B6C3F1/N mice based on the incidences of follicular cell carcinoma of the thyroid gland and alveolar/bronchiolar adenoma or carcinoma (combined) of the lung.

1 See Explanation of Levels of Evidence of Carcinogenic Activity. A summary of the peer review panel comments and the public discussion on this Technical Report appears in Appendix K.

Exposure to CIMSTAR 3800 resulted in increased incidences of nonneoplastic lesions of the nose, larynx, and lung in male and female rats and mice, lymph nodes in male and female rats, and thyroid gland in female mice.