# Discussion

Occupational exposures to metalworking fluids occur primarily by inhalation and have been reported to cause a number of respiratory problems in workers. The upper respiratory tract was the primary target site in rodents exposed by whole body inhalation to CIMSTAR 3800 aerosols. In 3-month inhalation studies, exposure to CIMSTAR 3800 (25 to 400 mg/m^3^) caused significant irritation of the nasal cavity of F344/NTac rats and B6C3F1/N mice. Hyaline droplet accumulation in the respiratory and olfactory epithelium of the nose was present in almost all exposed rats and mice, and goblet cell hyperplasia was present in the nasal cavity of almost all exposed rats. These lesions are commonly observed in the nasal cavity of rodents following inhalation of an irritant^104^. Rhinitis symptoms are common among machinists exposed to water-soluble metalworking fluids^33; 105-107^.

The larynx was also a target of CIMSTAR 3800 toxicity in the 3-month studies. Squamous metaplasia of the respiratory epithelium lining the larynx was present in all exposed rats and was the most severe lesion observed in the 3-month studies. In addition, squamous epithelium hyperplasia and chronic active inflammation were present in the larynx of most rats and mice exposed to 100 mg/m^3^ or greater. Minimal to mild laryngeal lesions are commonly observed in inhalation studies of irritant chemicals; however, in the 3-month CIMSTAR 3800 study, the marked severity of squamous metaplasia in the larynx of rats and mice and the presence of epithelial dysplasia in the epiglottis of some exposed mice were unusual. Squamous metaplasia is a common adaptive response to repeated injury to the epithelium and results in the replacement of injured epithelium with the more resistant squamous epithelium. Though marked squamous metaplasia of the larynx has only been reported in a few NTP inhalation studies, squamous metaplasia of the larynx, in general, is a common lesion in NTP inhalation studies. However, laryngeal neoplasia is extremely rare; therefore, laryngeal squamous metaplasia is not considered a preneoplastic lesion by NTP. Inhalation exposure to diethylamine^108^ or triethylamine^109^ vapors caused marked squamous metaplasia of the larynx, similar to lesions caused by CIMSTAR 3800. Notably, diethylamine and triethylamine are highly alkaline chemicals, like CIMSTAR 3800.

In the more distal respiratory tract, 3-month exposures to CIMSTAR 3800 caused minimal to mild bronchiole hyperplasia in the lungs of all exposed mice. Arteriole hypertrophy and perivascular chronic active inflammation were also observed in some mice at the higher concentrations. Effects on the lung were less in the rat and consisted of mild alveolar histiocytosis at the two highest exposure concentrations.

Exposure to 10, 30, or 100 mg/m^3^ CIMSTAR 3800 for 2 years had no adverse effect on survival or body weights of Wistar Han rats or B6C3F1/N mice. As in the 3-month studies, nonneoplastic lesions were observed in the upper respiratory tract of exposed animals. Goblet cell hyperplasia, hyperplasia of olfactory submucosal glands, and hyaline droplet accumulation were present in the nasal cavity of most exposed rats and mice. Squamous metaplasia of the respiratory and olfactory epithelium of the nose was also present in mice; this lesion was not observed in the 3-month study.

Squamous metaplasia of the larynx was observed in almost all rats and mice exposed to CIMSTAR 3800 for 2 years. The severity of this lesion was exposure concentration-dependent and was moderate to marked in the 100 mg/m^3^ group. Despite the severity and persistence of squamous metaplasia, there were no neoplasms in the larynx of rats or mice. Squamous metaplasia of the larynx is not known to be preneoplastic in rodents, and there have been no incidences of adenoma or carcinoma of the larynx in rats or mice in NTP studies. Epidemiological studies have reported increased laryngeal cancer in workers exposed to straight oil metalworking fluids^59^; however, the evidence was significantly less for machinists exposed to soluble oils^58^. CIMSTAR 3800 is a semisynthetic oil and does not contain the carcinogens (e.g., polyaromatic hydrocarbons, diethanolamine) that were present in the straight oil metalworking fluids.

An unusual lymphohistiocytic inflammation was observed in the lungs of rats exposed to CIMSTAR 3800 for 2 years. The incidence and severity of lymphohistiocytic inflammation increased with increasing exposure concentration, and the lesion was present in the lungs of almost all male and female rats exposed to 100 mg/m^3^. Lymphohistiocytic hyperplasia of the bronchus-associated lymphoid tissue also was observed in exposed rats suggesting that the lymphohistiocytic inflammation may have been mediated by an immunologic reaction. In the workplace, in-use CIMSTAR 3800 and other metalworking fluids can become contaminated by fungi and bacteria. These microbes and their by-products may cause immunologically mediated reactions such as hypersensitivity pneumonitis when inhaled. However, in the current study, rats were exposed to uncontaminated CIMSTAR 3800 indicating that chemical components were the cause of lymphohistiocytic inflammation. Formaldehyde-releasing biocides and alkanolamines present in metalworking fluids have been implicated as potential causes of hypersensitivity pneumonitis^13; 35^, and CIMSTAR 3800 contains a triazine biocide as well as ethanolamine and triethanolamine. Repeated inhalation exposure to the highly alkaline CIMSTAR 3800 (pH 9) and accumulation of the oil components undoubtedly contributed to the upper respiratory tract lesions observed in rats and mice, although the contribution of the highly diluted chemical components of CIMSTAR 3800 cannot be discounted.

There is considerable evidence for increased risk of cancer at several sites in machinists exposed to metal-working fluids used before the mid-1970s. CIMSTAR 3800 and other newer semisynthetic formulations are presumed to be safer because a number of known and suspected carcinogens have been removed or reduced; however, the potential carcinogenicity of these newer formulations has not been evaluated.

There was some evidence of CIMSTAR 3800 carcinogenicity in the lungs of female mice exposed for 2 years. A significantly increased (P = 0.021) incidence of alveolar/bronchiolar adenoma or carcinoma (combined) was observed in the lungs of female mice exposed to 100 mg/m^3^. The incidence (24%) exceeded the historical control range (2% to 16%) for inhalation studies. The incidences of alveolar/bronchiolar adenoma or carcinoma (combined) in female mice exposed to lower concentrations were not significant; however, there were positive trends in the incidences of alveolar/bronchiolar carcinoma (P = 0.021), and alveolar/bronchiolar adenoma or carcinoma (combined) (P = 0.006). In addition, the incidences of bronchiole hyperplasia were significantly increased (P < 0.001) in female mice exposed to 30 or 100 mg/m^3^. The severity of this minimal lesion did not increase with increasing exposure concentration. Bronchiole hyperplasia may contribute to the development of adenoma and carcinoma in the lung. This was considered only some evidence of carcinogenicity, rather than clear evidence of carcinogenicity, of lung neoplasms in female mice because the incidence in the 100 mg/m^3^ group was only slightly greater than the historical control range and only the combined incidence of alveolar/bronchiolar adenoma or carcinoma in the 100 mg/m^3^ group was significantly increased. The incidences of bronchiole hyperplasia were also significantly increased in 30 and 100 mg/m^3^ male mice, although there was no evidence of carcinogenicity in the lungs of male mice. There was also no evidence of carcinogenicity in the lungs of rats in the 2-year study. Epidemiological data do not show an association between lung cancer and soluble metalworking fluid exposure^58^.

Follicular cell carcinoma of the thyroid gland was present in 6% of female mice exposed to 100 mg/m^3^ CIMSTAR 3800 for 2 years. This incidence of follicular cell carcinoma was not statistically significant relative to concurrent chamber controls, and these neoplasms were not present in females exposed to lower concentrations or in exposed male mice. Follicular cell carcinomas have been observed in only two of 942 female historical control mice exposed by all routes. The incidence of follicular cell hyperplasia, a potential precursor to neoplasia, was increased in female mice in an exposure concentration-dependent manner up to 6% in the 100 mg/m^3^ group. Because the neoplasms were malignant, are uncommon, and there were exposure concentration-related increased incidences of follicular cell hyperplasia, the follicular cell carcinomas were considered to be treatment related.

In female rats, three C-cell carcinomas of the thyroid gland occurred in the 100 mg/m^3^ group, which exceeded the historical control range (0% to 2%) for all routes of exposure. There was also a positive trend in the incidence of C-cell adenoma or carcinoma (combined); however, the incidence in the 100 mg/m^3^ group did not exceed the historical control range (6% to 14%) for all routes of exposure. Furthermore, the incidences of C-cell carcinoma and C-cell adenoma or carcinoma (combined) were not significantly increased in any exposed group when compared to the chamber control group. Therefore, the C-cell neoplasms in female rats were not considered to be exposure related.

An increased incidence of prostate gland adenoma or carcinoma (combined) was observed in male rats exposed to 100 mg/m^3^ (6%); however, this incidence was not significantly different from that in the concurrent chamber controls. Prostate gland neoplasms were all adenomas except for one carcinoma in the 30 mg/m^3^ group. No adenomas or carcinomas of the prostate gland have been reported in the previous two studies with Wistar Han rats (100 rats) and are rare in F344/N rats (3/698). Despite the rarity of these neoplasms and the exposure concentration-dependent increased incidences, it is unclear if this is a treatment-related effect because of the low incidences of neoplasms, the lack of statistical significance, and the lack of historical control data for inhalation studies in Wistar Han rats, which complicates the interpretation of data for rare neoplasms. Although there is epidemiological evidence of increased prostate gland cancer in metalworkers exposed to straight oils, there was no association in workers exposed to water-soluble formulations like CIMSTAR 3800^58^.

A small number of uterine adenocarcinomas and a mixed malignant Müllerian tumor (MMMT) were observed in the original evaluation in female rats. In an effort by NTP to more thoroughly evaluate rat uteri, additional evaluations were conducted on the residual uterine tissue, which was sectioned longitudinally (i.e., parallel to the long axis), from this and other studies. In the residual evaluation in the current study, there were statistically significant increases in the incidences of uterine adenocarcinoma and adenocarcinoma or MMMT (combined) in the 30 and 100 mg/m^3^ groups. However, when combined with the neoplasm incidences in the original evaluation, the incidences were not statistically significant. Additionally, in two residual uterine tissue evaluations in other Wistar Han rat studies, there were four adenocarcinomas in the control group from one study and eight adenocarcinomas in the control group from the other study^102; 103^; the incidence from the latter study exceeding the incidence of adenocarcinoma or MMMT (combined) in the 100 mg/m^3^ group in the current study. These results suggest that background uterine adenocarcinomas are more prevalent in Wistar Han rats than originally expected. Therefore, it is unclear whether the incidences of uterine adenocarcinoma or MMMT (combined) in the current study are chemical related.

Skin contact is also a major route of occupational exposure to metalworking fluids. Although dermal application of metalworking fluids has been reported to cause skin papillomas and carcinomas in experimental animals^43-45^, these studies were conducted with straight oil formulations before known or suspected carcinogens were removed. Similarly, substantial evidence exists for an increased risk of squamous cell skin cancer associated with exposure conditions of the mid-1970s and earlier^51-53^. In the mid-1980s many known and suspected carcinogens were removed or reduced in metalworking fluid formulations. New semisynthetic metalworking fluids such as CIMSTAR 3800 are considered to be safer.

Animals received significant dermal exposure to CIMSTAR 3800 during the 2-year whole body inhalation study due to deposition of the liquid aerosols on the fur and skin. Squamous cell papilloma or keratoacanthoma (combined) of the skin occurred in 8% of female rats exposed to 100 mg/m^3^; however, this increased incidence was not statistically significant. Only one of these benign neoplasms was a keratoacanthoma. Squamous cell papilloma and keratoacanthoma of the skin were not observed in 150 female Wistar Han historical control rats from all routes of exposure. Despite the dermal exposure and a slight increased incidence in benign neoplasms in the 100 mg/m^3^ group, it is unclear if this is a treatment-related effect because of the lack of statistical significance and the lack of historical control data from inhalation studies in the Wistar Han rat.

CIMSTAR 3800, like all metalworking fluids, is a complex mixture of chemicals. The chemical composition of CIMSTAR 3800 is proprietary information and its potentially toxic components have not been identified. The major component of CIMSTAR 3800 and most semisynthetic metalworking fluids is water. The CIMSTAR 3800 concentrate used in this study contained 60% water. In the workplace, this concentrate is diluted 1:10 to 1:20 with water prior to use, therefore workers are exposed to CIMSTAR 3800 aerosols composed of 90% to 95% water. Because it is technically difficult to generate and expose animals to liquid aerosols containing up to 90% water without saturating the chamber air, the aerosols in the current study were generated from undiluted concentrate and diluted with clean air to produce the desired concentrations. Thus, the CIMSTAR 3800 exposure concentrations used in the current study were considerably higher than those encountered in the workplace.

Although a complete chemical analysis of CIMSTAR 3800 was not performed, several major chemical groups were identified. In addition to water, CIMSTAR 3800 concentrate was found to contain approximately 25% (by weight) hexane extractable (water insoluble) compounds. The CIMSTAR 3800 concentrate also contained several alkanolamines including ethanolamine (4.7% to 5.7% by weight), triethanolamine (3.2% to 3.4% by weight) and 1-amino-2-propanol (1.4% to 1.6% by weight). Diethanolamine (a known carcinogen) was not detected. Alkanolamines are generally added to semisynthetic metal-working fluids to prevent corrosion and to maintain a high pH to facilitate rust removal^110^.

There are no published genotoxicity data for CIMSTAR 3800 or other metalworking fluids, with the exception of the single epidemiological study that looked for an association between the incidence of DNA strand breaks and occupational exposure to N-nitrosodiethanolamine (NDELA), a known genotoxic and carcinogenic contaminant present in older formulations of metalworking fluids^64^. Although more modern (beginning mid-1980s) formulations of metalworking fluids do not contain the nitrosating agents that can result in the formation of NDELA, it is possible that other components of these complex mixtures have genotoxic potential, and indeed, CIMSTAR 3800 was shown to be a weak bacterial mutagen in assays presented in this Technical Report. Ethanolamine and triethanolamine, both present in CIMSTAR 3800, have been shown to be non-mutagenic in bacteria^111^, while 1-amino-2-propanol was judged to be equivocal in a bacterial mutagenicity assay^112^. However, the small percentage of 1-amino-2-propanol in CIMSTAR 3800 and the pattern of activity (variable responses in Salmonella typhimurium strain TA1535 in the presence of S9 mix) indicate that it does not have a role in the weak positive response seen with CIMSTAR 3800 in the Escherichia coli tester strain in the absence of S9 only. NTP has evaluated the mutagenicity of several different metalworking fluids in bacteria and most were shown to be negative (NTP, unpublished data). Three types of metalworking fluids (two soluble oils and one semisynthetic) did demonstrate clear mutagenicity in the E. coli strain in the presence of S9 mix, and all three contained biocides that release formaldehyde, a known bacterial mutagen. CIMSTAR 3800 also contains a formaldehyde-releasing biocide, and therefore, formaldehyde may have been responsible for its mutagenic activity in bacteria. No indication of chromosomal damage, measured in an erythrocyte micronucleus assay, was seen in rats or mice from the current 3-month inhalation study.