# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-586.

## Three-month Study in F344/NTac Rats

All rats survived to the end of the study and mean body weights of exposed groups of rats were similar to those of chamber control rats (Table 2; Figure 1). Clinical findings in male and female rats exposed to 200 or 400 mg/m^3^ consisted mainly of lethargy, ruffled fur, and nasal/eye discharge.

Table 2 Survival and Body Weights of F344/NTac Rats in the Three-month Inhalation Study of CIMSTAR 3800^^a^^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 85 ± 2 | 349 ± 6 | 264 ± 6
25 | 10/10 | 85 ± 2 | 353 ± 9 | 269 ± 9 | 101
50 | 10/10 | 84 ± 2 | 354 ± 7 | 271 ± 7 | 102
100 | 10/10 | 85 ± 2 | 354 ± 7 | 269 ± 7 | 102
200 | 10/10 | 84 ± 2 | 352 ± 5 | 268 ± 4 | 101
400 | 10/10 | 84 ± 2 | 350 ± 6 | 266 ± 5 | 100
Female
0 | 10/10 | 76 ± 1 | 188 ± 5 | 112 ± 5
25 | 10/10 | 78 ± 1 | 190 ± 5 | 113 ± 4 | 101
50 | 10/10 | 77 ± 1 | 195 ± 5 | 118 ± 5 | 104
100 | 10/10 | 77 ± 1 | 189 ± 5 | 112 ± 4 | 100
200 | 10/10 | 76 ± 1 | 185 ± 5 | 110 ± 5 | 98
400 | 10/10 | 77 ± 2 | 184 ± 4 | 107 ± 4 | 98

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 1

Growth Curves for F344/NTac Rats Exposed to CIMSTAR 3800 by Inhalation for Three Months

There were no changes in hematology parameters attributable to CIMSTAR 3800 exposure (Table F-1).

At 3 months, there was a minimal to mild (up to 23%) exposure concentration-related decrease in serum activity of alanine aminotransferase in all exposed groups of male rats (Table F-1). There was also a mild (up to 43%) exposure concentration-related decrease in sorbitol dehydrogenase activity in all exposed groups of male rats and in females exposed to 100 mg/m^3^ or greater. The biological significance or mechanism of these decreases is unknown, but these changes may represent decreased hepatocellular enzyme production or release.

There were no biologically significant changes in absolute or relative organ weights (Table G-1).

Treatment-related changes were seen only in the respiratory system. In the nose, the incidences of goblet cell hyperplasia, olfactory epithelium and respiratory epithelium hyaline droplet accumulation, and olfactory epithelium and respiratory epithelium suppurative inflammation in all exposed groups of male and female rats were significantly greater than the chamber control incidences (Table 3). These lesions did not occur in chamber controls, except one male had hyaline droplet accumulation in the olfactory epithelium. In both males and females, there were slight, generally exposure concentration-related increases in the severities of goblet cell hyperplasia and olfactory epithelium and respiratory epithelium suppurative inflammation. A single 400 mg/m^3^ male had focal necrosis of the olfactory epithelium and focal hyperplasia of the respiratory epithelium and one 400 mg/m^3^ female had focal squamous metaplasia of the respiratory epithelium.

Table 3 Incidences of Nonneoplastic Lesions of the Respiratory System in F344/NTac Rats in the Three-month Inhalation Study of CIMSTAR 3800

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
Male
Nose^a^ | 10 | 10 | 10 | 10 | 10 | 10
Goblet Cell, Hyperplasia^b^ | 0 | 10** (1.3)^c^ | 10** (1.6) | 10** (1.7) | 10** (1.8) | 10** (1.9)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 1 (1.0) | 10** (3.0) | 10** (3.0) | 10** (3.0) | 10** (3.0) | 10** (3.0)
Olfactory Epithelium, Inflammation, Suppurative | 0 | 10** (1.2) | 10** (1.3) | 10** (1.3) | 10** (1.6) | 10** (1.7)
Olfactory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 10** (2.6) | 10** (1.8) | 10** (2.4) | 10** (2.8) | 10** (2.8)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Respiratory Epithelium, Inflammation, Suppurative | 0 | 10** (1.2) | 10** (1.3) | 10** (1.3) | 10** (1.6) | 10** (1.7)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Chronic Active | 1 (1.0) | 9** (1.1) | 10** (1.3) | 10** (1.5) | 10** (2.0) | 10** (2.5)
Metaplasia, Squamous | 0 | 10** (3.1) | 10** (3.9) | 10** (4.0) | 10** (4.0) | 10** (4.0)
Squamous Epithelium, Hyperplasia | 0 | 6** (1.0) | 5* (1.0) | 10** (1.3) | 10** (1.6) | 10** (1.7)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Alveolus, Infiltration Cellular, Histiocyte | 0 | 0 | 0 | 0 | 7** (1.0) | 10** (1.0)
Female
Nose | 10 | 10 | 10 | 10 | 10 | 10
Goblet cell, Hyperplasia | 0 | 8** (1.5) | 10** (1.5) | 9** (1.6) | 10** (1.7) | 10** (1.8)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 0 | 10** (2.8) | 10** (3.0) | 10** (2.9) | 10** (3.0) | 10** (3.0)
Olfactory Epithelium, Inflammation, Suppurative | 0 | 9** (1.0) | 10** (1.1) | 10** (1.3) | 10** (1.6) | 10** (1.4)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 10** (2.6) | 10** (2.8) | 10** (2.6) | 10** (2.8) | 10** (2.7)
Respiratory Epithelium, Inflammation, Suppurative | 0 | 9** (1.0) | 10** (1.1) | 10** (1.3) | 10** (1.6) | 10** (1.4)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Chronic Active | 0 | 10** (1.0) | 10** (1.1) | 10** (1.6) | 10** (1.7) | 10** (2.2)
Metaplasia, Squamous | 0 | 10** (2.9) | 10** (3.4) | 10** (4.0) | 10** (4.0) | 10** (4.0)
Squamous Epithelium, Hyperplasia | 0 | 9** (1.1) | 7** (1.0) | 10** (1.4) | 9** (1.3) | 10** (1.7)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Alveolus, Infiltration Cellular, Histiocyte | 0 | 0 | 0 | 0 | 10** (1.0) | 10** (1.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Goblet cell hyperplasia was minimal or mild, and involved the respiratory epithelium covering the ventral half of the nasal septum, ventral meatus, medial surface of nasoturbinates, and nasopharyngeal duct. Goblet cells were usually hypertrophic as well as hyperplastic. The hyaline droplet accumulation in the respiratory and olfactory epithelia was characterized by the presence of variably sized, eosinophilic globules within the cytoplasm of the epithelial cells. Suppurative inflammation consisted of increased numbers of neutrophils, many degenerate, scattered within the lamina propria associated with both the olfactory and respiratory epithelia. Occasionally, there were small numbers of degenerate neutrophils within glandular lumina, as well.

In the larynx of all exposed groups of males and females, there were significantly increased incidences of squamous metaplasia of the respiratory epithelium, hyperplasia of the squamous epithelium lining the arytenoid processes, and chronic active inflammation in the lamina propria (Table 3). These lesions did not occur in chamber controls except for chronic active inflammation in a single male. There were also generally exposure concentration-related increases in the severities of these lesions in both sexes.

Squamous metaplasia of the larynx was characterized by replacement of the respiratory epithelium by three to 13 cell layers of well-differentiated squamous epithelial cells with variable amounts of keratin. The lesion was located predominantly at the base of the epiglottis but was occasionally seen within the ventral pouch and ventrolateral laryngeal wall as well, particularly in the higher exposure concentration groups. Hyperplasia of the squamous epithelium lining the arytenoid processes had a similar appearance, but because these processes are normally covered by squamous epithelium, hyperplasia was deemed a more appropriate term. The hyperplasia was minimal to mild with up to seven layers of epithelial cells. Chronic active inflammation was characterized by variable numbers of neutrophils with fewer lymphocytes, plasma cells, and occasional macrophages in the lamina propria, most often at the base of the epiglottis, but also in the ventral pouch and vocal folds.

In the lung of 200 and 400 mg/m^3^ males and females, there were significantly increased incidences of alveolus histiocytic cellular infiltration (Table 3). This lesion was characterized by an increase in the number of alveolar macrophages in the lung compared to the lung of chamber control rats. Often, these macrophages were larger than those in the chamber control rats and contained several clear, cytoplasmic vacuoles.

Exposure Concentration Selection Rationale: The exposure concentrations selected for the 2-year inhalation study in rats were 10, 30, and 100 mg/m^3^. The 10 mg/m^3^ concentration was selected based on the occurrence of significant lesions in the nose and larynx in groups exposed to 25 mg/m^3^ or greater in the 3-month study. The 100 mg/m^3^ exposure concentration was selected based on exposure concentration-related increased severity of squamous metaplasia of the respiratory epithelium in the larynx, and olfactory epithelium necrosis in one 400 mg/m^3^ male. In addition, the observation of nasal and eye discharge in groups exposed to 200 or 400 mg/m^3^ indicated that exposure to these concentrations of the alkaline aerosol for 2 years might result in undue animal stress and discomfort.

## Two-year Study in Wistar Han Rats

### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 4 and in the Kaplan-Meier survival curves (Figure 2). Survival of all exposed groups of male and female rats was similar to that of the chamber control groups.

Table 4 Survival of Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Male
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 17 | 12 | 13 | 15
Natural deaths | 0 | 4 | 3 | 2
Animals surviving to study termination | 33 | 34 | 34 | 33
Percent probability of survival at end of study^a^ | 66 | 68 | 68 | 66
Mean survival (days)^b^ | 688 | 681 | 703 | 683
Survival analysis^c^ | P = 1.000 | P = 1.000 | P = 0.818N | P = 1.000
Female
Animals initially in study | 50 | 50 | 50 | 50
Accidental death^d^ | 0 | 1 | 0 | 0
Moribund | 13 | 16 | 14 | 19
Natural deaths | 2 | 0 | 0 | 1
Animals surviving to study termination | 35^e^ | 33^e^ | 36 | 30^e^
Percent probability of survival at end of study | 70 | 65 | 72 | 58
Mean survival (days) | 700 | 693 | 711 | 707
Survival analysis | P = 0.380 | P = 0.738 | P = 0.926N | P = 0.416

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and terminal kill).

^c^ The result of the life table trend test^73^ is in the chamber control column, and the results of the life table pairwise comparisons^72^ with the chamber controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

^d^ Censored from survival analyses.

^e^ Includes one animal that died during the last week of the study.

Figure 2

Kaplan-Meier Survival Curves for Wistar Han Rats Exposed to CIMSTAR 3800 by Inhalation for Two Years

### Body Weights and Clinical Findings

The mean body weights of all exposed groups of males and females were similar to those of the chamber control groups throughout the study (Table 5, Table 6; Figure 3). Clinical findings included thinness and torso/ventral mass in all exposed and chamber control groups, torso/dorsal mass or torso/dorsal ulcer/abscess in 30 and 100 mg/m^3^ males, ruffled fur in 10 and 100 mg/m^3^ males, and abnormal breathing and torso/lateral mass in 100 mg/m^3^ males.

Table 5 Mean Body Weights and Survival of Male Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

Day | Chamber Control | | 10 mg/m^3^ | | | 30 mg/m^3^ | | | 100 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | | No. of Survivors
1 | 138 | 50 | 138 | 100 | 50 | 137 | 99 | 50 | 137 | | 99 | 50
10 | 192 | 50 | 193 | 100 | 50 | 189 | 98 | 50 | 186 | | 97 | 50
17 | 232 | 50 | 234 | 101 | 50 | 231 | 100 | 50 | 227 | | 98 | 50
24 | 265 | 50 | 269 | 102 | 50 | 266 | 100 | 50 | 261 | | 99 | 50
31 | 291 | 50 | 296 | 102 | 50 | 293 | 101 | 50 | 289 | | 99 | 50
38 | 314 | 50 | 321 | 102 | 50 | 316 | 101 | 50 | 312 | | 99 | 50
45 | 335 | 50 | 342 | 102 | 50 | 338 | 101 | 50 | 334 | | 100 | 50
52 | 351 | 50 | 357 | 102 | 50 | 355 | 101 | 50 | 350 | | 100 | 50
59 | 363 | 50 | 370 | 102 | 50 | 367 | 101 | 50 | 362 | | 100 | 50
66 | 375 | 50 | 383 | 102 | 50 | 379 | 101 | 50 | 374 | | 100 | 50
73 | 385 | 50 | 394 | 102 | 50 | 389 | 101 | 50 | 385 | | 100 | 50
80 | 396 | 50 | 405 | 102 | 50 | 395 | 100 | 50 | 395 | | 100 | 50
87 | 405 | 50 | 413 | 102 | 50 | 405 | 100 | 50 | 405 | | 100 | 50
115 | 430 | 50 | 437 | 102 | 50 | 431 | 100 | 50 | 427 | | 99 | 50
143 | 450 | 50 | 458 | 102 | 50 | 450 | 100 | 50 | 446 | | 99 | 50
171 | 464 | 50 | 474 | 102 | 50 | 465 | 100 | 50 | 460 | | 99 | 50
199 | 478 | 50 | 488 | 102 | 50 | 478 | 100 | 50 | 472 | | 99 | 50
227 | 492 | 50 | 502 | 102 | 50 | 489 | 99 | 50 | 488 | | 99 | 49
255 | 504 | 50 | 516 | 102 | 50 | 501 | 99 | 50 | 499 | | 99 | 49
283 | 517 | 50 | 527 | 102 | 50 | 511 | 99 | 50 | 510 | | 99 | 49
311 | 524 | 50 | 537 | 103 | 49 | 519 | 99 | 49 | 517 | | 99 | 49
339 | 535 | 50 | 550 | 103 | 49 | 529 | 99 | 49 | 529 | | 99 | 49
367 | 545 | 49 | 558 | 102 | 49 | 535 | 98 | 49 | 534 | | 98 | 49
395 | 555 | 49 | 568 | 102 | 49 | 543 | 98 | 49 | 545 | | 98 | 48
423 | 565 | 49 | 578 | 102 | 49 | 553 | 98 | 49 | 551 | | 98 | 48
451 | 572 | 49 | 580 | 102 | 47 | 562 | 98 | 49 | 556 | | 97 | 48
479 | 578 | 49 | 589 | 102 | 47 | 569 | 98 | 49 | 568 | | 98 | 46
507 | 584 | 48 | 597 | 102 | 46 | 575 | 98 | 49 | 578 | | 99 | 45
535 | 590 | 46 | 604 | 102 | 46 | 582 | 99 | 49 | 585 | | 99 | 45
563 | 593 | 46 | 606 | 102 | 44 | 587 | 99 | 49 | 589 | | 99 | 45
591 | 593 | 46 | 613 | 103 | 43 | 593 | 100 | 47 | 591 | | 100 | 45
619 | 597 | 40 | 612 | 102 | 42 | 593 | 99 | 47 | 595 | | 100 | 43
647 | 597 | 39 | 621 | 104 | 39 | 596 | 100 | 44 | 600 | | 101 | 40
675 | 602 | 38 | 622 | 103 | 38 | 605 | 101 | 43 | 602 | | 100 | 39
703 | 603 | 38 | 622 | 103 | 37 | 610 | 101 | 41 | 596 | | 99 | 38
Mean for Weeks
1–13 | 311 | – | 317 | 102 | – | 312 | 100 | – | 309 | | 99 | –
14–52 | 488 | – | 499 | 102 | – | 486 | 100 | – | 483 | | 99 | –
53–101 | 583 | – | 598 | 103 | – | 577 | 99 | – | 576 | | 99 | –

Table 6 Mean Body Weights and Survival of Female Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

Day | Chamber Control | | 10 mg/m^3^ | | | 30 mg/m^3^ | | | 100 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 118 | 50 | 118 | 100 | 50 | 118 | 100 | 50 | 117 | 99 | 50
10 | 143 | 50 | 143 | 100 | 50 | 143 | 100 | 50 | 141 | 99 | 50
17 | 158 | 50 | 159 | 101 | 50 | 158 | 100 | 50 | 157 | 99 | 50
24 | 172 | 50 | 174 | 101 | 50 | 174 | 101 | 50 | 170 | 99 | 50
31 | 182 | 50 | 183 | 101 | 50 | 184 | 101 | 50 | 180 | 99 | 50
38 | 191 | 50 | 191 | 100 | 50 | 193 | 101 | 50 | 189 | 99 | 50
45 | 199 | 50 | 199 | 100 | 50 | 200 | 101 | 50 | 197 | 99 | 50
52 | 204 | 50 | 206 | 101 | 50 | 208 | 102 | 50 | 202 | 99 | 50
59 | 209 | 50 | 211 | 101 | 50 | 213 | 102 | 50 | 208 | 99 | 50
66 | 211 | 50 | 215 | 102 | 50 | 215 | 102 | 50 | 213 | 101 | 50
73 | 217 | 50 | 220 | 101 | 50 | 221 | 102 | 50 | 217 | 100 | 50
80 | 222 | 50 | 225 | 101 | 50 | 226 | 102 | 50 | 220 | 99 | 50
87 | 227 | 50 | 230 | 101 | 50 | 230 | 102 | 50 | 225 | 99 | 50
115 | 237 | 50 | 240 | 101 | 50 | 241 | 102 | 50 | 235 | 99 | 50
143 | 246 | 50 | 249 | 101 | 50 | 252 | 103 | 50 | 243 | 99 | 50
171 | 253 | 50 | 256 | 101 | 50 | 259 | 103 | 50 | 250 | 99 | 50
199 | 258 | 50 | 262 | 102 | 50 | 267 | 103 | 50 | 257 | 100 | 50
227 | 265 | 50 | 271 | 102 | 50 | 272 | 103 | 50 | 264 | 100 | 50
255 | 271 | 50 | 275 | 102 | 50 | 278 | 102 | 50 | 268 | 99 | 50
283 | 278 | 50 | 284 | 102 | 50 | 286 | 103 | 50 | 275 | 99 | 50
311 | 288 | 50 | 290 | 101 | 50 | 293 | 102 | 50 | 280 | 98 | 50
339 | 295 | 50 | 299 | 101 | 50 | 299 | 101 | 50 | 285 | 97 | 50
367 | 300 | 50 | 303 | 101 | 50 | 307 | 103 | 50 | 289 | 96 | 50
395 | 313 | 50 | 313 | 100 | 50 | 317 | 102 | 50 | 300 | 96 | 50
423 | 322 | 49 | 326 | 101 | 50 | 328 | 102 | 50 | 296 | 92 | 50
451 | 334 | 49 | 336 | 101 | 50 | 339 | 102 | 50 | 316 | 95 | 50
479 | 341 | 49 | 339 | 99 | 50 | 348 | 102 | 50 | 326 | 96 | 50
507 | 344 | 48 | 348 | 101 | 49 | 359 | 104 | 50 | 336 | 98 | 50
535 | 355 | 48 | 363 | 102 | 47 | 370 | 104 | 50 | 344 | 97 | 49
563 | 362 | 48 | 369 | 102 | 46 | 380 | 105 | 49 | 348 | 96 | 49
591 | 367 | 47 | 373 | 101 | 45 | 385 | 105 | 49 | 358 | 97 | 48
619 | 371 | 42 | 377 | 102 | 43 | 396 | 107 | 47 | 361 | 97 | 48
647 | 375 | 41 | 380 | 101 | 40 | 396 | 106 | 45 | 359 | 96 | 43
675 | 385 | 41 | 384 | 100 | 39 | 401 | 104 | 43 | 360 | 94 | 40
703 | 377 | 37 | 396 | 105 | 33 | 398 | 106 | 39 | 370 | 98 | 36
Mean for Weeks
1–13 | 189 | – | 190 | 101 | – | 191 | 101 | – | 187 | 99 | –
14–52 | 266 | – | 270 | 102 | – | 272 | 102 | – | 262 | 99 | –
53–101 | 350 | – | 354 | 101 | – | 363 | 104 | – | 336 | 96 | –

Figure 3

Growth Curves for Wistar Han Rats Exposed to CIMSTAR 3800 by Inhalation for Two Years

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms or nonneoplastic lesions of the prostate gland, brain, uterus, skin, nose, larynx, lung, bronchial and mediastinal lymph nodes, and thyroid gland. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix A for male rats and Appendix B for female rats.

Prostate Gland: There were increased incidences of prostate gland adenoma or carcinoma (combined) in 30 and 100 mg/m^3^ males compared to chamber controls (Table 7, Table A-1, and Table A-2); however, the increases were not statistically significant. The increases were mainly attributable to increased incidences of adenoma, as there was a single carcinoma in the 30 mg/m^3^ group. In three studies using Wistar Han rats (including the current study), there were no carcinomas and there was a single adenoma in the 150 control animals. In the current study, there were five adenomas and one carcinoma in the exposed groups.

Table 7 Incidences of Neoplasms of the Prostate Gland in Male Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m3 | 30 mg/m3 | 100 mg/m3
Number Examined Microscopically | 50 | 50 | 50 | 50
Adenoma, multiple^a^ | 1 | 0 | 1 | 1
Adenoma (includes multiple)^b^ | 1 | 1 | 1 | 3
Carcinoma^c^ | 0 | 0 | 1 | 0
Adenoma or Carcinoma (includes multiple)^b^
Overall rate^d^ | 1/50 (2%) | 1/50 (2%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate^e^ | 2.3% | 2.3% | 4.3% | 6.9%
Terminal rate^f^ | 1/33 (3%) | 1/34 (3%) | 1/34 (3%) | 3/33 (9%)
First incidence (days) | 729 (T) | 729 (T) | 684 | 729 (T)
Poly-3 test^g^ | P = 0.187 | P = 0.757 | P = 0.520 | P = 0.304

(T) = Terminal kill.

^a^ Number of animals with neoplasm.

^b^ Historical control incidence for all routes of 2-year studies: 1/150.

^c^ Historical control incidence: 0/150.

^d^ Number of animals with neoplasm per number of animals with prostate gland examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

All neoplasms of the prostate gland were located in the ventral prostatic lobe. The adenomas were small masses that occupied one to three minimally expanded acini and caused minimal compression of the adjacent acini. The neoplastic cells grew in a cribriform pattern and the epithelium was generally two to five cell layers thick with occasional solid areas. The cells were often jumbled and the nuclei lacked basal polarity. They had moderate amounts of basophilic to amphophilic cytoplasm and round to oval nuclei with one to two small nucleoli. There was scant connective tissue within the adenomas. The carcinoma was much larger, effacing nearly the entire prostate gland and invading into surrounding tissues. There were numerous, often dilated, glands lined by one to three layers of cuboidal to flattened neoplastic epithelial cells with basophilic to amphophilic cytoplasm. The nuclei were round to oval with an open chromatin pattern. The glands were often filled with degenerate neutrophils and cell debris or mucinous material with fewer inflammatory cells. There was abundant fibrous stroma separating the glands with scattered mononuclear inflammatory cells and fewer neutrophils.

Brain: The occurrences of benign or malignant granular cell tumor (combined) were slightly increased in all exposed male groups compared to chamber controls (Table 8, Table A-1, and Table A-2), with the highest incidence in the 10 mg/m^3^ group. Although not statistically significant, the incidence of benign or malignant granular cell tumor (combined) in the 10 mg/m^3^ group exceeded the historical control range (0% to 4%) for all exposure routes.

Table 8 Incidences of Neoplasms of the Brain in Male Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Number Examined Microscopically | 50 | 50 | 50 | 50
Benign Granular Cell Tumor^a,b^ | 0 | 2 | 0 | 1
Malignant Granular Cell Tumor^c^ | 0 | 1 | 1 | 0
Benign or Malignant Granular Cell Tumor^b^
Overall rate^d^ | 0/50 (0%) | 3/50 (6%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate^e^ | 0.0% | 7.0% | 2.2% | 2.3%
Terminal rate^f^ | 0/33 (0%) | 2/34 (6%) | 0/34 (0%) | 1/33 (3%)
First incidence (days) | –^h^ | 704 | 684 | 729 (T)
Poly-3 test^g^ | P = 0.593N | P = 0.116 | P = 0.511 | P = 0.500

T = terminal kill.

^a^ Number of animals with neoplasm.

^b^ Historical control incidence for all routes of 2-year studies: 3/150.

^c^ Historical control incidence: 0/150.

^d^ Number of animals with neoplasm per number of animals with brain examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend is indicated by N.

^h^ Not applicable; no neoplasms in animal group.

The benign granular cell tumors were located in the meninges of the cerebellum or cerebrum. The malignant granular cell tumors were located within or adjacent to the lateral and fourth ventricles and distorted the brain architecture. There was also evidence of invasion into the adjacent neuropil. The neoplastic cells in the benign and malignant granular cell tumors had a similar appearance. They were large, round cells with abundant, deeply eosinophilic, granular cytoplasm. The nuclei were generally oval with finely stippled chromatin and a single, small nucleolus.

Uterus: In the female rats, there was a small increase in the incidence of uterine adenocarcinoma and a single mixed malignant Müllerian tumor (MMMT) in the 100 mg/m^3^ group (Table 9, Table B-1, and Table B-2). In an effort by NTP to evaluate rat uteri more thoroughly, additional evaluations were conducted on the residual uterine tissue from this and other studies. The residual uterine tissue was sectioned longitudinally (i.e., parallel to long axis) and included the cervix and vagina. In the residual evaluation for CIMSTAR 3800, additional uterine neoplasms were identified in the exposed groups, but not in the control group, and there were significantly increased incidences of uterine adenocarcinoma and adenocarcinoma or MMMT (combined) in the 30 and 100 mg/m^3^ groups (Table 9 and Table B-2). The trend statistic for these lesions was not significant. When combined with the data from the original evaluation in which there was a single adenocarcinoma in the chamber control group, the incidences of adenocarcinoma and adenocarcinoma or MMMT (combined) in the 30 and 100 mg/m^3^ groups were not statistically significant. In two other studies in which residual uterine tissue from Wistar Han rats was evaluated, there were eight adenocarcinomas in controls from one study and four adenocarcinomas in controls from the other study^102; 103^. Although the total number of female rats in the Wistar Han historical control database is low (150), this suggests that uterine epithelial neoplasms are not uncommon in Wistar Han rats. Furthermore, the eight adenocarcinomas in controls from the one study^103^ exceeds the total incidence of adenocarcinoma or MMMT (combined) in the 100 mg/m^3^ group from the current study.

Table 9 Incidences of Neoplasms of the Uterus in Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m3 | 30 mg/m3 | 100 mg/m3
Number Necropsied | 50 | 50 | 50 | 50
Original Evaluation
Adenocarcinoma^a,b^ | 1 | 1 | 1 | 2
Mixed Malignant Müllerian Tumor^c^ | 0 | 0 | 0 | 1
Adenocarcinoma or Mixed Malignant Müllerian Tumor^b^ | 1 | 1 | 1 | 3
Residual Longitudinal Evaluation
Adenocarcinoma
Overall rate^d^ | 0/50 (0%) | 4/50 (8%) | 5/50 (10%) | 5/50 (10%)
Adjusted rate^e^ | 0.0% | 9.2% | 10.7% | 11.0%
Terminal rate^f^ | 0/35 (0%) | 4/32 (13%) | 3/36 (8%) | 4/29 (14%)
First incidence (days) | –^h^ | 731 (T) | 646 | 725
Poly-3 test^g^ | P = 0.126 | P = 0.057 | P = 0.034 | P = 0.032
Mixed Malignant Müllerian Tumor | 0 | 0 | 0 | 1
Adenocarcinoma or Mixed Malignant Müllerian Tumor
Overall rate | 0/50 (0%) | 4/50 (8%) | 5/50 (10%) | 6/50 (12%)
Adjusted rate | 0.0% | 9.2% | 10.7% | 13.1%
Terminal rate | 0/35 (0%) | 4/32 (13%) | 3/36 (8%) | 5/29 (17%)
First incidence (days) | – | 731 (T) | 646 | 725
Poly-3 test | P = 0.059 | P = 0.057 | P = 0.034 | P = 0.016
Original and Residual Longitudinal Evaluation
Adenocarcinoma | 1 | 4 | 5 | 5
Mixed Malignant Müllerian Tumor | 0 | 0 | 0 | 1
Adenocarcinoma or Mixed Malignant Müllerian Tumor
Overall rate | 1/50 (2%) | 4/50 (8%) | 5/50 (10%) | 6/50 (12%)
Adjusted rate | 2.2% | 9.2% | 10.7% | 13.1%
Terminal rate | 1/35 (3%) | 4/32 (13%) | 3/36 (8%) | 5/29 (17%)
First incidence (days) | 731 (T) | 731 (T) | 646 | 725
Poly-3 test | P = 0.102 | P = 0.170 | P = 0.111 | P = 0.058

T = terminal kill.

^a^ Number of animals with neoplasm.

^b^ Historical control incidence for all routes of 2-year studies: 7/150.

^c^ Historical control incidence for all routes of 2-year studies: 0/150.

^d^ Number of animals with neoplasm per number of animals necropsied.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^h^ Not applicable; no neoplasms in animal group.

Uterine adenocarcinomas were generally small and poorly demarcated masses composed of cuboidal epithelial cells. The neoplastic cells were large and polymorphic and often had basophilic cytoplasm. They were arranged in branching papillary patterns and often formed tubular or acinar structures. There were often multiple layers of neoplastic epithelial cells lining these structures. The MMMT was a large mass and had a similar epithelial component, but also had a mesenchymal component that was also considered neoplastic. The mesenchymal cells were enlarged with large, elongated nuclei and scattered mitotic figures and were arranged in streaming bundles.

Skin: In females, there was a positive trend in the incidences of squamous cell papilloma or keratoacanthoma (combined) of the skin (Table 10, Table B-1 and Table B-2); however, the incidence in the 100 mg/m^3^ group was not significantly greater than the chamber control incidence. The majority of these neoplasms were squamous cell papillomas, but there was also one keratoacanthoma. No squamous cell papillomas or keratoacanthomas have occurred in the 150 female Wistar Han historical controls from all routes of study.

Table 10 Incidences of Neoplasms of the Skin in Female Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Number of Animals Necropsied | 50 | 50 | 50 | 50
Squamous Cell Papilloma^a^
Overall rate^b^ | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate^c^ | 0.0% | 0.0% | 0.0% | 6.5%
Terminal rate^d^ | 0/35 (0%) | 0/32 (0%) | 0/36 (0%) | 2/29 (7%)
First incidence (days) | –^f^ | – | – | 673
Poly-3 test^e^ | P = 0.008 | –^g^ | – | P = 0.122
Keratoacanthoma^a,h^ | 0 | 0 | 0 | 1
Squamous Cell Papilloma or Keratoacanthoma^a^
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 4/50 (8%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 8.7%
Terminal rate | 0/35 (0%) | 0/32 (0%) | 0/36 (0%) | 2/29 (7%)
First incidence (days) | – | – | – | 673
Poly-3 test | P = 0.002 | – | – | P = 0.063

^a^ Historical control incidence for all routes of 2-year studies: 0/150.

^b^ Number of animals with neoplasm per number of animals necropsied.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal kill.

^e^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^f^ Not applicable; no neoplasms in animal group.

^g^ Value of statistic cannot be computed.

^h^ Number of animals with neoplasm.

Nose: In the nose, there were chemical-related, nonneoplastic lesions consistent with an irritant effect. In all exposed male and female groups, there were significantly increased incidences of goblet cell hyperplasia, hyperplasia of submucosal glands subjacent to the olfactory epithelium, and hyaline droplet accumulation in the respiratory and olfactory epithelia (Table 11, Table A-3, and Table B-3).

Table 11 Incidences of Nonneoplastic Lesions of the Respiratory System in Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m^3^ | 3 mg/m^3^ | 100 mg/m^3^
Male
Nose^a^ | 50 | 50 | 50 | 50
Glands, Olfactory Epithelium, Hyperplasia^b^ | 1 (1.0)^c^ | 39** (1.5) | 47** (2.0) | 50** (2.6)
Goblet Cell, Hyperplasia | 0 | 20** (1.1) | 25** (1.1) | 34** (1.3)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 19 (1.6) | 50** (2.8) | 50** (3.0) | 50** (3.5)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 17** (1.1) | 25** (1.1) | 29** (1.2)
Larynx | 50 | 50 | 50 | 50
Metaplasia, Squamous | 1 (2.0) | 47** (1.5) | 50** (2.2) | 50** (2.7)
Lung | 50 | 50 | 50 | 50
Alveolar Epithelium, Hyperplasia | 4 (1.3) | 6 (1.8) | 11 (1.9) | 13* (2.4)
Bronchus-associated Lymphoid Tissue, Hyperplasia, Lymphohistiocytic | 0 | 1 (1.0) | 5* (1.0) | 19** (2.0)
Inflammation, Lymphohistiocytic | 6 (1.2) | 14* (1.0) | 41** (1.1) | 47** (1.8)
Lymph Node, Bronchial | 42 | 40 | 37 | 35
Hyperplasia, Lymphohistiocytic | 0 | 0 | 10** (1.1) | 28** (2.1)
Lymph Node, Mediastinal | 46 | 45 | 50 | 49
Hyperplasia, Lymphohistiocytic | 0 | 0 | 4 (1.5) | 29** (2.2)
Female
Nose | 50 | 50 | 50 | 50
Glands, Olfactory Epithelium, Hyperplasia | 1 (1.0) | 32** (1.6) | 48** (2.0) | 49** (2.6)
Goblet Cell, Hyperplasia | 0 | 25** (1.0) | 34** (1.1) | 42** (1.2)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 16 (1.6) | 50** (2.6) | 50** (2.9) | 50** (3.5)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 1 (1.0) | 24** (1.1) | 31** (1.1) | 34** (1.2)
Larynx | 50 | 50 | 50 | 50
Metaplasia, Squamous | 1 (2.0) | 50** (1.7) | 50** (2.5) | 50** (2.8)
Lung | 50 | 50 | 50 | 50
Bronchus-associated Lymphoid Tissue, Hyperplasia, Lymphohistiocytic | 0 | 0 | 0 | 5* (1.0)
Inflammation, Lymphohistiocytic | 3 (1.0) | 20** (1.0) | 42** (1.0) | 50** (1.9)
Lymph Node, Bronchial | 38 | 35 | 32 | 35
Hyperplasia, Lymphohistiocytic | 0 | 0 | 7** (1.1) | 30** (1.6)
Lymph Node, Mediastinal | 49 | 46 | 45 | 47
Hyperplasia, Lymphohistiocytic | 0 | 0 | 4 (1.3) | 23** (1.7)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Goblet cell hyperplasia of the respiratory epithelium was histologically characterized by minimally to mildly increased number and size of goblet cells, particularly along the nasal septum, ethmoturbinates, and the epithelium lining the nasopharyngeal duct. Hyperplasia of the olfactory epithelium submucosal glands was characterized by an increase in the size and number of the glands, and the cytoplasm of the glandular cells was often distended by concurrent hyaline droplet accumulations. The volumetric expansion of the submucosal glands often resulted in variable elevation of the overlying olfactory epithelium. A few neutrophils were sometimes present in the hyperplastic gland lumens or adjacent submucosal stroma, but this was not a prominent feature. Hyaline droplet accumulation of the respiratory and olfactory epithelia typically occurred in the ventral nasal cavity, on the ethmoturbinates, and along the margin of the ventromedial nasal cavity adjacent to the nasopharynx. Histologically, this lesion was characterized by aggregates of hyalinized, eosinophilic material distending the cytoplasm of olfactory and respiratory epithelial cells, though the severity was much greater in the olfactory epithelium.

Larynx: In the larynx of all exposed groups of males and females, there were significantly increased incidences of squamous metaplasia of the respiratory epithelium (Table 11, Table A-3, and Table B-3). In the 30 and 100 mg/m^3^ groups the severities of this lesion increased with increasing exposure concentration. In a few animals, there was concurrent inflammation (Table A-3 and Table B-3), but in the majority of the exposed rats, squamous metaplasia was the only lesion present. Squamous metaplasia of the laryngeal respiratory epithelium was also seen in the 3-month study. The difference in the severity of this lesion between the 3-month and 2-year studies was likely due to differences in the grading schemes.

Squamous metaplasia was most common along the ventral aspect of the most cranial section of larynx, at the base of the epiglottis, although in severely affected animals, the medial aspects of the arytenoid cartilages were also affected. Histologically, this lesion was characterized by replacement of the respiratory or transitional epithelium by flattened squamous epithelium.

Lung: In the lung, there were significant, exposure concentration-related increased incidences of lymphohistiocytic inflammation in all exposed groups of males and females and of lymphohistiocytic hyperplasia of bronchus-associated lymphoid tissue (BALT) in 30 mg/m^3^ males and 100 mg/m^3^ males and females (Table 11, Table A-3, and Table B-3). There were also increased incidences of alveolar epithelium hyperplasia in all exposed groups of males, but only the incidence in 100 mg/m^3^ males was significantly increased compared to that in the chamber controls. The severities of lymphohistiocytic inflammation in the 100 mg/m^3^ groups and BALT lymphohistiocytic hyperplasia in 100 mg/m^3^ males were increased compared to the chamber controls. The severities of alveolar epithelium hyperplasia increased with exposure concentration in males.

Lymphohistiocytic inflammation was characterized histologically by accumulations of small lymphocytes and foamy, vacuolated macrophages (Figure 7). In some cases, the inflammatory cells were closely intermixed forming nodules, typically within alveoli. These nodules, reminiscent of small granulomas, were most often found in the subpleural region. The inflammatory cells also formed more dispersed accumulations where the macrophages and lymphocytes were not as closely associated. The macrophages were often within alveoli and the lymphocytes multifocally expanded the adjacent alveolar septa. The more dispersed pattern was present in all animals with inflammation, but the nodules were mainly present in the more severely affected rats in the 30 and 100 mg/m^3^ groups. Lymphohistiocytic hyperplasia in the BALT was histologically similar to lymphohistiocytic inflammation in the lungs and was characterized by multifocal aggregates of foamy, vacuolated histiocytes within the BALT separated by increased numbers of small lymphocytes (Figure 8). Secondary follicles were generally absent. Alveolar epithelium hyperplasia consisted of poorly demarcated, noncompressive parenchymal foci in which alveolar septa were lined by plump, cuboidal epithelial cells.

Lymph Nodes: In the bronchial lymph nodes, there were significant, exposure concentration-related increased incidences of lymphohistiocytic hyperplasia in 30 and 100 mg/m^3^ males and females (Table 11, Table A-3, and Table B-3). In the mediastinal lymph nodes, there were significant, exposure concentration-related increased incidences of lymphohistiocytic hyperplasia in 100 mg/m^3^ males and females. The severities of these lesions also increased with increasing exposure concentration.

Lymphohistiocytic hyperplasia in the bronchial and mediastinal lymph nodes was characterized by multifocal aggregates of foamy, vacuolated histiocytes, particularly in the paracortical region, separated by increased numbers of small lymphocytes. Secondary follicles were generally absent throughout the cortex. The appearance of this lesion was similar to the appearance of the lymphohistiocytic inflammation of the lung and lymphohistiocytic hyperplasia of the BALT described above.

Thyroid Gland: In female rats, there were positive trends in the incidences of C-cell carcinoma (chamber control, 0/50; 10 mg/m^3^, 0/50; 30 mg/m^3^, 0/50; 100 mg/m^3^, 3/49; Table B-1 and Table B-2) and C-cell adenoma or carcinoma (combined) (3/50, 2/50, 4/50, 7/49). The incidence of C-cell adenoma or carcinoma (combined) in the 100 mg/m^3^ group did not exceed the historical control range (6% to 14%) for all routes; however, the incidence of C-cell carcinoma in the 100 mg/m^3^ group did exceed the all routes historical control range (0% to 2%). Furthermore, the incidences of C-cell carcinoma and C-cell adenoma or carcinoma (combined) in any exposed group were not statistically significant when compared to the chamber controls.

## Mice

### Three-month Study

All mice survived to the end of the study (Table 12). Final mean body weights and mean body weight gains of 400 mg/m^3^ males and females were significantly less than those of the chamber controls; the final mean body weight of 200 mg/m^3^ females was also significantly less (Table 12; Figure 4). Clinical findings associated with exposure to CIMSTAR 3800 consisted of lethargy in all 200 and 400 mg/m^3^ mice and ruffled fur in all exposed groups of males and 400 mg/m^3^ females.

Table 12 Survival and Body Weights of Mice in the Three-month Inhalation Study of CIMSTAR 3800^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 24.3 ± 0.5 | 39.5 ± 0.9 | 15.2 ± 0.7
25 | 10/10 | 24.3 ± 0.6 | 38.1 ± 1.3 | 13.8 ± 1.1 | 97
50 | 10/10 | 24.3 ± 0.4 | 38.6 ± 0.7 | 14.3 ± 0.8 | 98
100 | 10/10 | 24.3 ± 0.5 | 37.4 ± 0.6 | 13.1 ± 0.4 | 95
200 | 10/10 | 24.2 ± 0.4 | 37.8 ± 0.6 | 13.6 ± 0.6 | 96
400 | 10/10 | 24.0 ± 0.5 | 32.9 ± 0.9** | 8.9 ± 0.6** | 83
Female
0 | 10/10 | 20.0 ± 0.3 | 33.0 ± 1.2 | 13.0 ± 1.1
25 | 10/10 | 19.5 ± 0.5 | 31.6 ± 0.7 | 12.1 ± 0.6 | 96
50 | 10/10 | 20.3 ± 0.4 | 31.8 ± 0.8 | 11.5 ± 0.9 | 96
100 | 10/10 | 19.4 ± 0.3 | 31.9 ± 0.7 | 12.5 ± 0.6 | 97
200 | 10/10 | 19.4 ± 0.2 | 30.5 ± 0.8* | 11.1 ± 0.6 | 92
400 | 10/10 | 19.6 ± 0.5 | 28.1 ± 0.5** | 8.6 ± 0.4** | 85

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 4

Growth Curves for Mice Exposed to CIMSTAR 3800 by Inhalation for Three Months

There were no changes in hematology parameters attributable to CIMSTAR 3800 exposure (Table F-2).

The absolute and relative lung weights of males exposed to 100 mg/m^3^ or greater were significantly greater than those of the chamber controls (Table G-2). The relative lung weights of 200 and 400 mg/m^3^ females were also significantly greater than that of the chamber controls. Other organ weight differences were related to the reduced body weights.

Treatment-related lesions were seen only in the respiratory system. In the nose of all exposed groups of mice, the incidences of hyaline droplet accumulation in the olfactory and respiratory epithelia were significantly greater than the chamber control incidences (Table 13). These lesions did not occur in chamber control mice. In both sexes, the severity of these lesions tended to increase with increasing exposure concentration. Hyaline droplet accumulation in the respiratory and olfactory epithelia was characterized by the presence of variably sized, eosinophilic globules within the cytoplasm of the epithelial cells, particularly on the ventral and lateral aspects of the ethmoid turbinates, in the nasopharyngeal duct, and at the junctions of olfactory and respiratory epithelia.

Table 13 Incidences of Nonneoplastic Lesions of the Respiratory System in Mice in the Three-month Inhalation Study of CIMSTAR 3800

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
Male
Nose^a^ | 10 | 10 | 10 | 10 | 10 | 10
Olfactory Epithelium, Accumulation, Hyaline Droplet^b^ | 0 | 7** (1.0)^c^ | 4* (1.0) | 10** (1.9) | 10** (1.7) | 9** (2.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 8** (1.0) | 10** (1.0) | 10** (2.0) | 10** (1.7) | 10** (1.9)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Epiglottis, Dysplasia | 0 | 0 | 0 | 0 | 0 | 6** (1.8)
Inflammation, Chronic Active | 0 | 0 | 4* (1.3) | 6** (1.3) | 10** (1.9) | 9** (1.9)
Metaplasia, Squamous | 0 | 10** (2.0) | 10** (2.2) | 10** (2.9) | 10** (3.9) | 10** (4.0)
Squamous Epithelium, Hyperplasia | 0 | 1 (1.0) | 0 | 0 | 7** (1.9) | 10** (2.2)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Arteriole, Hypertrophy | 0 | 0 | 0 | 2 (1.0) | 3 (1.3) | 4* (1.0)
Bronchiole, Hyperplasia | 0 | 10** (1.0) | 10** (1.0) | 10** (1.9) | 10** (1.5) | 10** (1.9)
Perivascular, Inflammation, Chronic Active | 0 | 0 | 0 | 3 (1.0) | 4* (1.0) | 6** (1.2)
Female
Nose | 10 | 10 | 10 | 10 | 10 | 10
Olfactory Epithelium, Accumulation, Hyaline Droplet | 0 | 7** (1.0) | 10** (1.0) | 10** (1.8) | 10** (2.0) | 10** (2.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 10** (1.0) | 10** (1.0) | 10** (1.8) | 10** (2.0) | 10** (2.0)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Epiglottis, Dysplasia | 0 | 0 | 0 | 0 | 2 (1.0) | 7** (1.7)
Inflammation, Chronic Active | 0 | 0 | 1 (1.0) | 9** (1.3) | 10** (2.1) | 10** (2.0)
Metaplasia, Squamous | 0 | 10** (2.0) | 10** (2.0) | 10** (2.8) | 10** (3.9) | 10** (4.0)
Squamous Epithelium, Hyperplasia | 0 | 0 | 0 | 1 (1.0) | 10** (2.0) | 10** (2.0)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Arteriole, Hypertrophy | 0 | 0 | 0 | 2 (1.0) | 4* (1.0) | 2 (1.0)
Bronchiole, Hyperplasia | 0 | 10** (1.0) | 10** (1.0) | 10** (2.0) | 10** (1.8) | 10** (2.0)
Perivascular, Inflammation, Chronic Active | 0 | 0 | 1 (1.0) | 6** (1.0) | 8** (1.0) | 3 (1.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the larynx, there were significantly increased incidences of squamous metaplasia of the respiratory epithelium in all exposed groups of males and females, and the severity of this lesion increased with increasing exposure concentration (Table 13). In males and females exposed to 200 or 400 mg/m^3^, there were significantly increased incidences of hyperplasia of the squamous epithelium lining the arytenoid processes. There were significantly increased incidences of chronic active inflammation of the lamina propria in males exposed to 50 mg/m^3^ or greater and females exposed to 100 mg/m^3^ or greater, and the severity increased with increasing exposure concentration. There were also significantly increased incidences of dysplasia of the epithelium at the level of the epiglottis in 400 mg/m^3^ males and females. Squamous metaplasia was characterized by replacement of the respiratory epithelium by three to 15 cell layers of well-differentiated squamous epithelial cells with variable amounts of keratin. The lesion was located predominantly at the base of the epiglottis, but was occasionally seen on the ventrolateral laryngeal wall as well, particularly in the higher exposure concentration groups. Hyperplasia of the squamous epithelium lining the arytenoid processes had a similar appearance, but because these processes are normally covered by squamous epithelium, hyperplasia was deemed a more appropriate term. Hyperplasia was slightly less severe than metaplasia with up to seven layers of squamous epithelial cells. Chronic active inflammation was generally associated with squamous metaplasia and was characterized by variable numbers of neutrophils with fewer lymphocytes, plasma cells, and occasional macrophages in the lamina propria, most often at the base of the epiglottis, but also in the ventral pouch and vocal folds. Epithelial dysplasia of the epiglottis was associated with squamous metaplasia and was characterized by the extensive proliferation of metaplastic squamous epithelium resulting in irregular, disorganized epithelial surfaces (Figure 9). Proliferating epithelial cells formed tortuous invaginations into the subjacent submucosa and an undulating epithelial surface. The cytomegalic and karyomegalic dysplastic squamous epithelial cells were either randomly oriented or aligned perpendicular to the basal lamina and sometimes formed whorls. There were also dyskeratotic cells in the stratum granulosum, reflecting disorderly cellular maturation.

In the lung, there were significantly increased incidences of bronchiole hyperplasia in all exposed groups of males and females, and the severity was increased at 100 mg/m^3^ or greater (Table 13). There were significantly increased incidences of chronic active perivascular inflammation in 200 and 400 mg/m^3^ males and 100 and 200 mg/m^3^ females. There were also significantly increased incidences of arteriole hypertrophy in 400 mg/m^3^ males and 200 mg/m^3^ females. Bronchiole hyperplasia was characterized histologically by increased numbers of cuboidal to columnar epithelial cells, with up to three layers of epithelial cells. In some instances, there were clusters of cuboidal to columnar epithelial cells that sometimes formed papillary projections into the airway lumen. Only the terminal bronchioles were involved in the minimally affected animals, but in the mildly affected animals, the terminal bronchioles and alveolar ducts were involved. Arteriole hypertrophy consisted of thickening of the tunica media of small pulmonary arterioles. Chronic active perivascular inflammation was characterized by the accumulation of small numbers of lymphocytes with fewer plasma cells and neutrophils around arterioles and, rarely, venules, and was observed in the presence and absence of arteriole hypertrophy.

Exposure Concentration Selection Rationale: The exposure concentrations selected for the 2-year inhalation study in mice were 10, 30, and 100 mg/m^3^. The 10 mg/m^3^ concentration was selected based on the occurrence of significant lesions of the larynx in groups exposed to 25 mg/m^3^ or greater in the 3-month study. There were increased severities of chronic active inflammation of the larynx in males and females exposed to 50 mg/m^3^ or greater. The 100 mg/m^3^ concentration was selected based on significantly reduced body weights in 200 mg/m^3^ females and 400 mg/m^3^ males and females, increased incidences of hyperplasia of the squamous epithelium of the larynx in 200 and 400 mg/m^3^ groups, and increased incidences of epithelial dysplasia of the epiglottis in 400 mg/m^3^ groups.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 14 and in the Kaplan-Meier survival curves (Figure 5). Survival of all exposed groups of male and female mice was similar to that of the chamber control groups.

Table 14 Survival of Mice in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Male
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 5 | 12 | 7 | 4
Natural deaths | 6 | 7 | 7 | 6
Animals surviving to study termination | 39 | 31 | 36 | 40
Percent probability of survival at end of study^a^ | 78 | 62 | 72 | 80
Mean survival (days)^b^ | 709 | 688 | 693 | 706
Survival analysis^c^ | P = 0.323N | P = 0.109 | P = 0.558 | P = 1.000
Female
Animals initially in study | 50 | 50 | 50 | 50
Accidental death^d^ | 0 | 0 | 0 | 1
Moribund | 7 | 8 | 10 | 11
Natural deaths | 4 | 5 | 3 | 5
Animals surviving to study termination | 39 | 37 | 37 | 33
Percent probability of survival at end of study | 78 | 74 | 74 | 67
Mean survival (days) | 696 | 706 | 706 | 688
Survival analysis | P = 0.308 | P = 0.817 | P = 0.847 | P = 0.358

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and terminal kill).

^c^ The result of the life table trend test^73^ is in the chamber control column, and the results of the life table pairwise comparisons^72^ with the chamber controls are in the exposed group columns. A negative trend is indicated by N.

^d^ Censored from survival analyses.

Figure 5

Kaplan-Meier Survival Curves for Mice Exposed to CIMSTAR 3800 by Inhalation for Two Years

#### Body Weights and Clinical Findings

The mean body weights of all exposed groups of males and females were similar to those of the chamber control groups throughout the study (Figure 6; Table 15 and Table 16). Clinical findings included thinness in all exposed and chamber control groups of males and females, torso/ ventral mass in all exposed male groups, and torso/dorsal mass in 100 mg/m^3^ males.

Figure 6

Growth Curves for Mice Exposed to CIMSTAR 3800 by Inhalation for Two Years

Table 15 Mean Body Weights and Survival of Male Mice in the Two-year Inhalation Study of CIMSTAR 3800

Day | Chamber Control | | 10 mg/m^3^ | | | 30 mg/m^3^ | | | 100 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 22.4 | 50 | 22.1 | 99 | 50 | 22.2 | 99 | 50 | 22.0 | 98 | 50
11 | 25.2 | 50 | 24.9 | 99 | 50 | 25.2 | 100 | 50 | 25.1 | 99 | 50
18 | 26.5 | 50 | 26.0 | 98 | 50 | 26.4 | 99 | 50 | 26.3 | 99 | 50
25 | 27.7 | 50 | 27.0 | 98 | 50 | 27.4 | 99 | 50 | 27.4 | 99 | 50
32 | 28.5 | 50 | 27.8 | 98 | 50 | 28.4 | 100 | 50 | 28.2 | 99 | 50
39 | 29.2 | 50 | 28.6 | 98 | 50 | 29.1 | 99 | 50 | 29.0 | 99 | 50
46 | 30.2 | 50 | 29.6 | 98 | 50 | 30.0 | 99 | 50 | 29.8 | 99 | 50
53 | 30.8 | 50 | 30.5 | 99 | 50 | 30.9 | 100 | 50 | 30.9 | 100 | 50
60 | 31.8 | 50 | 31.4 | 99 | 50 | 31.9 | 100 | 50 | 31.8 | 100 | 50
67 | 32.8 | 50 | 32.5 | 99 | 50 | 33.0 | 101 | 50 | 32.9 | 100 | 50
74 | 33.5 | 50 | 33.2 | 99 | 50 | 33.4 | 100 | 50 | 33.5 | 100 | 50
81 | 34.3 | 50 | 33.8 | 99 | 50 | 34.2 | 100 | 50 | 33.8 | 99 | 50
88 | 35.2 | 50 | 34.7 | 99 | 50 | 35.0 | 100 | 50 | 34.7 | 99 | 50
116 | 37.9 | 50 | 38.1 | 101 | 50 | 37.7 | 100 | 50 | 37.9 | 100 | 50
144 | 40.9 | 50 | 40.8 | 100 | 50 | 40.4 | 99 | 50 | 41.0 | 100 | 50
172 | 42.5 | 50 | 42.7 | 101 | 50 | 42.6 | 100 | 50 | 43.2 | 102 | 50
200 | 44.6 | 50 | 44.8 | 100 | 50 | 44.8 | 101 | 50 | 45.0 | 101 | 50
228 | 46.6 | 50 | 46.6 | 100 | 50 | 46.6 | 100 | 50 | 46.9 | 101 | 50
256 | 47.5 | 50 | 47.3 | 100 | 50 | 47.7 | 101 | 50 | 47.9 | 101 | 50
284 | 48.8 | 50 | 48.8 | 100 | 50 | 48.9 | 100 | 50 | 49.1 | 101 | 50
312 | 50.0 | 50 | 50.1 | 100 | 50 | 50.3 | 100 | 50 | 50.4 | 101 | 50
340 | 50.2 | 50 | 50.3 | 100 | 50 | 50.4 | 100 | 50 | 50.6 | 101 | 50
368 | 51.0 | 50 | 51.5 | 101 | 50 | 51.2 | 101 | 50 | 51.5 | 101 | 49
396 | 51.2 | 50 | 51.7 | 101 | 50 | 51.9 | 101 | 50 | 51.7 | 101 | 49
424 | 51.6 | 50 | 51.9 | 101 | 50 | 51.9 | 101 | 50 | 51.9 | 101 | 49
452 | 51.7 | 50 | 51.9 | 101 | 49 | 52.6 | 102 | 48 | 52.2 | 101 | 49
480 | 51.9 | 50 | 51.8 | 100 | 49 | 52.4 | 101 | 48 | 52.9 | 102 | 49
508 | 51.8 | 49 | 51.4 | 99 | 49 | 52.8 | 102 | 48 | 52.9 | 102 | 49
536 | 51.6 | 49 | 51.4 | 100 | 49 | 53.1 | 103 | 46 | 53.1 | 103 | 49
564 | 52.6 | 47 | 52.3 | 99 | 47 | 53.4 | 102 | 46 | 53.9 | 102 | 49
592 | 52.2 | 45 | 51.5 | 99 | 43 | 52.6 | 101 | 44 | 52.8 | 101 | 47
620 | 51.9 | 45 | 51.4 | 99 | 40 | 51.8 | 100 | 44 | 51.5 | 99 | 46
648 | 51.4 | 45 | 51.3 | 100 | 37 | 51.6 | 100 | 40 | 51.3 | 100 | 45
676 | 50.5 | 44 | 50.4 | 100 | 36 | 51.7 | 102 | 39 | 51.4 | 102 | 43
704 | 49.8 | 43 | 49.1 | 99 | 35 | 50.9 | 102 | 37 | 50.9 | 102 | 42
Mean for Weeks
1–13 | 29.9 | – | 29.4 | 98 | – | 29.8 | 100 | – | 29.6 | 99 | –
14–52 | 45.4 | – | 45.5 | 100 | – | 45.5 | 100 | – | 45.8 | 101 | –
53–101 | 51.5 | – | 51.4 | 100 | – | 52.2 | 101 | – | 52.2 | 101 | –

Table 16 Mean Body Weights and Survival of Female Mice in the Two-year Inhalation Study of CIMSTAR 3800

Day | Chamber Control | | 10 mg/m^3^ | | | 30 mg/m^3^ | | | 100 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 19.3 | 50 | 19.1 | 99 | 50 | 19.0 | 98 | 50 | 18.8 | 97 | 50
11 | 21.2 | 50 | 20.8 | 98 | 50 | 21.0 | 99 | 50 | 21.2 | 100 | 50
18 | 22.2 | 50 | 22.0 | 99 | 50 | 22.3 | 101 | 50 | 22.4 | 101 | 50
25 | 23.4 | 50 | 23.0 | 99 | 50 | 23.5 | 100 | 50 | 23.7 | 101 | 50
32 | 24.2 | 50 | 24.0 | 100 | 50 | 24.2 | 100 | 50 | 24.5 | 101 | 50
39 | 24.9 | 50 | 24.5 | 98 | 50 | 25.0 | 100 | 50 | 25.3 | 102 | 50
46 | 25.4 | 50 | 25.4 | 100 | 50 | 26.0 | 103 | 50 | 26.1 | 103 | 50
53 | 26.4 | 50 | 26.5 | 101 | 50 | 26.9 | 102 | 50 | 27.0 | 103 | 50
60 | 26.6 | 50 | 26.8 | 101 | 50 | 27.1 | 102 | 50 | 27.4 | 103 | 50
67 | 27.5 | 50 | 27.2 | 99 | 50 | 27.5 | 100 | 50 | 27.9 | 101 | 50
74 | 27.8 | 50 | 27.6 | 99 | 50 | 28.0 | 101 | 50 | 28.5 | 102 | 50
81 | 28.4 | 50 | 28.1 | 99 | 50 | 28.7 | 101 | 50 | 29.0 | 102 | 50
88 | 29.1 | 50 | 28.9 | 99 | 50 | 29.2 | 100 | 50 | 29.8 | 102 | 50
116 | 31.3 | 50 | 31.2 | 100 | 50 | 30.8 | 99 | 50 | 32.1 | 103 | 50
144 | 34.1 | 50 | 33.8 | 99 | 50 | 33.5 | 99 | 50 | 34.8 | 102 | 50
172 | 36.6 | 50 | 36.4 | 99 | 50 | 36.1 | 99 | 50 | 37.6 | 103 | 50
200 | 39.3 | 49 | 38.6 | 98 | 50 | 38.7 | 99 | 50 | 39.6 | 101 | 50
228 | 41.2 | 49 | 41.1 | 100 | 50 | 40.9 | 99 | 50 | 42.4 | 103 | 50
256 | 43.4 | 49 | 42.6 | 98 | 50 | 43.5 | 100 | 50 | 44.4 | 102 | 49
284 | 45.8 | 49 | 45.2 | 99 | 50 | 45.2 | 99 | 50 | 46.5 | 102 | 49
312 | 48.6 | 49 | 48.1 | 99 | 50 | 47.3 | 97 | 50 | 49.7 | 102 | 49
340 | 50.6 | 49 | 50.0 | 99 | 50 | 49.7 | 98 | 50 | 51.8 | 102 | 49
368 | 52.1 | 48 | 51.6 | 99 | 50 | 50.6 | 97 | 50 | 52.9 | 102 | 49
396 | 54.2 | 48 | 53.6 | 99 | 50 | 52.4 | 97 | 50 | 54.9 | 101 | 49
424 | 56.0 | 48 | 55.2 | 99 | 50 | 53.8 | 96 | 50 | 55.8 | 100 | 49
452 | 56.5 | 48 | 55.6 | 99 | 50 | 54.7 | 97 | 50 | 57.1 | 101 | 48
480 | 57.6 | 48 | 56.8 | 99 | 50 | 56.1 | 97 | 49 | 59.0 | 102 | 48
508 | 58.8 | 48 | 57.7 | 98 | 49 | 57.1 | 97 | 48 | 60.2 | 102 | 48
536 | 58.4 | 47 | 57.9 | 99 | 49 | 56.2 | 96 | 48 | 60.5 | 104 | 46
564 | 59.2 | 46 | 58.4 | 99 | 48 | 57.7 | 98 | 48 | 61.2 | 103 | 45
592 | 57.6 | 46 | 56.1 | 97 | 47 | 55.8 | 97 | 47 | 60.2 | 105 | 44
620 | 56.4 | 44 | 54.3 | 96 | 45 | 54.7 | 97 | 45 | 58.8 | 104 | 43
648 | 55.3 | 44 | 53.2 | 96 | 43 | 53.8 | 97 | 44 | 57.9 | 105 | 41
676 | 53.7 | 44 | 52.2 | 97 | 42 | 52.0 | 97 | 44 | 56.5 | 105 | 39
704 | 52.9 | 40 | 50.8 | 96 | 38 | 50.0 | 95 | 39 | 55.2 | 104 | 35
Mean for Weeks
1–13 | 25.1 | – | 24.9 | 99 | – | 25.3 | 101 | – | 25.5 | 102 | –
14–52 | 41.2 | – | 40.8 | 99 | – | 40.6 | 99 | – | 42.1 | 102 | –
53–101 | 56.1 | – | 54.9 | 98 | – | 54.2 | 97 | – | 57.7 | 103 | –

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the thyroid gland, lung, nose, larynx, and trachea. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice.

Thyroid Gland: There was an increased incidence of follicular cell carcinoma in 100 mg/m^3^ females (Table 17, Table D-1, and Table D-2). Although the incidence was not statistically significant, there was a positive trend and the 100 mg/m^3^ incidence exceeded the historical control ranges for inhalation studies (0% to 2%) and all routes of exposure (0% to 2%); follicular cell carcinoma occurred in three female mice exposed to 100 mg/m^3^ in the current study but in only two of 942 historical controls (Table D-3). Although no follicular cell adenomas occurred in the current study, there were slight but exposure concentration-related increased incidences of follicular cell hyperplasia in females (Table 17 and Table D-5). Follicular cell hyperplasia is an uncommon background lesion and is thought to be a precursor to follicular cell neoplasia.

Table 17 Incidences of Neoplasms and Nonneoplastic Lesions of the Thyroid Gland in Female Mice in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Number Examined Microscopically | 50 | 48 | 50 | 50
Follicular Cell Hyperplasia^a^ | 1 (2.0)^b^ | 1 (2.0) | 2 (2.0) | 3 (2.3)
Follicular Cell Carcinoma^c^
Overall rate^d^ | 0/50 (0%) | 0/48 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate^e^ | 0.0% | 0.0% | 0.0% | 6.9%
Terminal rate^f^ | 0/39 (0%) | 0/36 (0%) | 0/37 (0%) | 2/33 (6%)
First incidence (days) | –^h^ | – | – | 712
Poly-3 test^g^ | P = 0.008 | –^i^ | – | P = 0.112

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year inhalation studies with chamber controls (mean ± standard deviation): 1/299 (0.3% ± 0.8%), range 0%–2%; all routes: 2/942 (0.2% ± 0.6%), range 0%–2%.

^d^ Number of animals with neoplasm per number of animals with thyroid gland examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal sacrifice.

^h^ Not applicable; no neoplasm in animal group.

^i^ Value of statistic cannot be computed.

Follicular cell carcinomas were bilateral masses that replaced the normal thyroid gland parenchyma. They were composed of neoplastic follicular epithelial cells that formed variably sized follicular structures with infoldings and papillary projections of follicular cells into the follicles and little to no colloid. There were other areas with more solid nodules of follicular cells. The neoplastic cells were polygonal with moderate amounts of amphophilic cytoplasm and round to oval nuclei. In one instance, the neoplasm had invaded into a lymphatic duct. Follicular cell hyperplasia was characterized by increased numbers of normal follicular cells within follicles, sometimes appearing as a segment of the follicular epithelium with several layers of cells and other times as papillary infoldings of the follicular epithelium into the follicular lumen.

Lung: Compared to that of the chamber controls, there was a significantly increased incidence of alveolar/ bronchiolar adenoma or carcinoma (combined) in 100 mg/m^3^ females (Table 18, Table D-1, and Table D-2). There were also increased incidences of alveolar/bronchiolar carcinoma in 100 mg/m^3^ females and of alveolar/bronchiolar adenoma in all exposed female groups, but the increases were not statistically significant. However, there were positive trends in the incidences of alveolar/bronchiolar carcinoma and alveolar/bronchiolar adenoma or carcinoma (combined) in female mice. The incidences of alveolar/bronchiolar carcinoma and alveolar/bronchiolar adenoma or carcinoma (combined) in 100 mg/m^3^ females exceeded the historical control ranges for inhalation studies and for all routes of exposure (Table 18 and Table D-4).

Table 18 Incidences of Neoplasms and Nonneoplastic Lesions of the Respiratory System in Mice in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Male
Lung^a^ | 50 | 50 | 50 | 50
Alveolar Epithelium, Hyperplasia^b^ | 4 (1.3)^c^ | 4 (1.3) | 6 (2.3) | 7 (2.6)
Bronchiole, Hyperplasia | 11 (1.0) | 11 (1.1) | 32** (1.2) | 44** (1.1)
Infiltration Cellular, Histiocyte | 5 (1.6) | 5 (1.6) | 1 (1.0) | 9 (2.0)
Alveolar/bronchiolar Adenoma^d^ | 5 | 2 | 8 | 9
Alveolar/bronchiolar Carcinoma, Multiple | 1 | 1 | 0 | 5
Alveolar/bronchiolar Carcinoma (includes multiple)^e^ | 8 | 8 | 8 | 10
Alveolar/bronchiolar Adenoma or Carcinoma^f^ | 13 | 9 | 14 | 17
Nose | 50 | 50 | 50 | 50
Inflammation, Chronic Active | 6 (1.3) | 8 (2.1) | 4 (1.5) | 12 (1.7)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 4 (1.3) | 31** (1.5) | 43** (1.8) | 49** (2.6)
Olfactory Epithelium, Atrophy | 1 (1.0) | 0 | 0 | 4 (1.0)
Olfactory Epithelium, Metaplasia, Respiratory | 7 (1.1) | 15* (1.3) | 25** (1.2) | 37** (1.5)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 7 (1.1) | 36** (1.4) | 50** (1.8) | 50** (2.6)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 3 (1.3) | 0 | 1 (1.0)
Larynx | 50 | 50 | 49 | 50
Inflammation, Chronic Active | 0 | 2 (1.5) | 3 (1.0) | 8** (1.0)
Metaplasia, Squamous | 0 | 50** (1.0) | 49** (2.0) | 50** (3.4)
Necrosis | 0 | 1 (2.0) | 1 (1.0) | 1 (1.0)
Trachea | 50 | 50 | 47 | 50
Ulcer | 0 | 0 | 0 | 1
Female
Lung | 50 | 50 | 50 | 50
Alveolar Epithelium, Hyperplasia | 4 (1.5) | 2 (2.0) | 5 (1.2) | 4 (2.0)
Bronchiole, Hyperplasia | 7 (1.0) | 4 (1.0) | 22** (1.0) | 41** (1.0)
Infiltration Cellular, Histiocyte | 4 (1.0) | 1 (1.0) | 1 (1.0) | 6 (1.5)
Perivascular, Inflammation, Chronic Active | 4 (1.8) | 3 (1.7) | 0 | 11* (2.0)
Alveolar/bronchiolar Adenoma, Multiple | 0 | 1 | 0 | 0
Alveolar/bronchiolar Adenoma (includes multiple)^g^ | 1 | 4 | 2 | 4
Alveolar/bronchiolar Carcinoma^h^
Overall rate^i^ | 4/50 (8%) | 1/50 (2%) | 4/50 (8%) | 8/50 (16%)
Adjusted rate^j^ | 8.8% | 2.2% | 8.6% | 18.2%
Terminal rate^k^ | 4/39 (10%) | 1/37 (3%) | 3/37 (8%) | 6/33 (18%)
First incidence (days) | 731 (T) | 731 (T) | 460 | 644
Poly-3 test^l^ | P = 0.021 | P = 0.176N | P = 0.627N | P = 0.163
Alveolar/bronchiolar Adenoma or Carcinoma^m^
Overall rate | 4/50 (8%) | 5/50 (10%) | 6/50 (12%) | 12/50 (24%)
Adjusted rate | 8.8% | 10.9% | 12.8% | 27.2%
Terminal rate | 4/39 (10%) | 5/37 (14%) | 4/37 (11%) | 9/33 (27%)
First incidence (days) | 731 (T) | 731 (T) | 460 | 644
Poly-3 test | P = 0.006 | P = 0.505 | P = 0.391 | P = 0.021
Nose | 50 | 49 | 50 | 50
Olfactory Epithelium, Accumulation, Hyaline Droplet | 25 (1.8) | 40** (1.9) | 50** (2.6) | 49** (3.0)
Olfactory Epithelium, Metaplasia, Respiratory | 3 (1.0) | 4 (1.3) | 12* (1.6) | 23** (1.5)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 34 (1.6) | 48** (1.7) | 50** (2.6) | 50** (3.0)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 1 (1.0) | 0 | 1 (1.0)
Larynx | 49 | 49 | 50 | 50
Inflammation, Chronic Active | 0 | 0 | 0 | 10** (1.2)
Metaplasia, Squamous | 1 (1.0) | 49** (1.1) | 50** (2.1) | 50** (3.5)
Necrosis | 0 | 0 | 0 | 4 (1.5)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

(T) = terminal kill.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 39/300 (13.0% ± 4.2%), range 8%–20%; all routes: 145/950 (15.3% ± 6.2%), range 2%–26%.

^e^ Historical control incidence for inhalation studies: 59/300 (19.7% ± 3.4%), range 16%–24%; all routes: 132/950 (13.9% ± 7.1%), range 4%–24%.

^f^ Historical control incidence for inhalation studies: 90/300 (30.0% ± 5.5%), range 26%–40%; all routes: 263/950 (27.7% ± 5.7%), range 16%–40%.

^g^ Historical control incidence for inhalation studies: 16/299 (5.4% ± 3.7%), range 2%-12%; all routes: 54/949 (5.7% ± 3.6%), range 0%–12%.

^h^ Historical control incidence for inhalation studies: 13/299 (4.4% ± 4.3%), range 0%-10%; all routes: 38/949 (4.0% ± 3.6%), range 0%–14%.

^i^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^j^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^k^ Observed incidence at terminal kill.

^l^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^m^ Historical incidence for inhalation studies: 28/299 (9.4% ± 4.8%), range 2%–16%; all routes: 90/949 (9.5% ± 4.8%), range 2%–22%.

In male mice, the incidences of alveolar/bronchiolar adenoma, alveolar/bronchiolar carcinoma, and alveolar/ bronchiolar adenoma or carcinoma (combined) were slightly increased in the 100 mg/m^3^ group, but the incidences and trends were not statistically significant, and the incidences did not exceed the historical control ranges for inhalation studies or for all routes (Table 18, Table C-1, Table C-2, and Table C-3). However, there was an increase in the number of animals with multiple carcinomas in the 100 mg/m^3^ group relative to the concurrent control.

Alveolar/bronchiolar adenomas were well circumscribed and expansile, often compressing the adjacent lung parenchyma. The neoplasms were most often composed of cuboidal to low columnar epithelial cells that occasionally formed short projections into the alveolar spaces. The neoplastic cells were relatively monomorphic with slightly vacuolated cytoplasm. The mitotic index was low and necrosis was rare. Alveolar/bronchiolar carcinomas were similar to adenomas; however, the carcinomas were often locally invasive, were generally larger, had areas of sarcomatous and squamous differentiation, and the neoplastic cells were occasionally anaplastic.

There were significantly increased incidences of bronchiole hyperplasia in 30 and 100 mg/m^3^ males and females (Table 18, Table C-4, and Table D-5). It is not known whether this lesion is a precursor to alveolar/bronchiolar neoplasms. Hyperplasia of the alveolar epithelium, which may be a precursor to pulmonary neoplasia, occurred in all groups of males and females. While the incidences of this lesion in exposed groups were not significantly increased compared to the chamber controls, there was an exposure-related increase in the severity of the lesion in males. In both sexes, there were slightly increased incidences of histiocytic cellular infiltration in the 100 mg/m^3^ groups, but the incidences were not statistically significant. In 100 mg/m^3^ females, there was a significantly increased incidence of chronic active perivascular inflammation.

Bronchiole epithelium hyperplasia primarily involved small bronchioles and often extended into the alveolar ducts and spaces. Epithelial cells lining the affected small bronchioles formed one to two layers of cells that frequently had loss of basal nuclear orientation. In more severe cases, epithelial cells formed papillary projections that obscured the bronchiolar lumen. There was often an increase in fibrous connective tissue within the lesion. Alveolar epithelium hyperplasia was characterized by foci in which the alveolar septa were thickened by a single layer of cuboidal, type II alveolar epithelium cells. There was minimal inflammation and no involvement of the terminal bronchioles, thus this lesion was distinct from bronchiolar epithelium hyperplasia. Histiocyte infiltration was characterized by an increase in the number of alveolar macrophages, often large and with foamy cytoplasm, in the alveolar spaces. Chronic active perivascular inflammation was characterized by increased numbers of lymphocytes, macrophages, and neutrophils in the perivascular spaces.

Nose: In all exposed groups of males and females, there were significantly increased incidences of hyaline droplet accumulation in the respiratory and olfactory epithelia and respiratory metaplasia of the olfactory epithelium (except 10 mg/m^3^ females) (Table 18, Table C-4, and Table D-5). There was a positive trend in the incidences of olfactory epithelium atrophy in males and a slightly increased incidence in the 100 mg/m^3^ group. There were increased incidences of chronic active inflammation in 10 and 100 mg/m^3^ males and squamous metaplasia of the respiratory epithelium occurred in a few males and females exposed to 10 or 100 mg/m^3^; although the incidences of these lesions were not statistically significant, they were considered to be related to CIMSTAR 3800 exposure.

Olfactory and respiratory epithelium hyaline droplet accumulation were characterized by the accumulation of brightly eosinophilic, homogenous material within the cytoplasm of the epithelial cells. This change mainly affected the naso- and maxilloturbinates, the nasal septum, the glands at the junction of the respiratory and olfactory epithelia, the lateral wall, the nasopharyngeal duct, and the lateral aspects of the ethmoturbinates. Respiratory metaplasia of the olfactory epithelium is the replacement of the olfactory epithelium by ciliated respiratory epithelium, and olfactory epithelium atrophy was characterized by loss of cells and resultant attenuation of the olfactory epithelium. Both lesions were primarily seen in the dorsal meatus and ethmoturbinates. While the biologic significance of hyaline droplet accumulation is unknown, it is frequently seen in inhalation studies. Atrophy of the olfactory epithelium is a degenerative change and respiratory metaplasia of the olfactory epithelium is considered an adaptive or protective change induced by prolonged, low-level exposure to nasal toxicants. In the current study, these lesions were minimal to mild.

Larynx: There were chemical-related increased incidences of chronic active inflammation, squamous metaplasia, and necrosis in both sexes (Table 18, Table C-4, and Table D-5). The incidences of squamous metaplasia in all exposed groups were significantly increased, and the severities increased with increasing exposure concentration. This lesion occurred in all exposed animals examined, but in only one chamber control mouse. There were significantly increased incidences of chronic active inflammation 100 mg/m^3^ males and females. Epithelial necrosis occurred in a single male in each exposed group and in four 100 mg/m^3^ females; while the incidences were low, this lesion was considered to be related to CIMSTAR 3800 exposure.

Squamous metaplasia was characterized by the replacement of the normal respiratory epithelium with three to 10 layers of squamous epithelium. This lesion was most commonly present at the base of the epiglottis, but at higher exposure concentrations it was also present on the lateral walls. Squamous metaplasia included squamous hyperplasia of the epithelium lining the arytenoid cartilages (three to eight layers of cells), which normally have one to three layers of squamous epithelium. In the 3-month study, epithelial dysplasia was present in association with squamous metaplasia, but there was no evidence of epithelial dysplasia in the 2-year study. Chronic active inflammation was characterized by the accumulation of lymphocytes with fewer macrophages, plasma cells, and neutrophils in the submucosa of the larynx with occasional small foci of subepithelial fibrosis. This lesion was limited to the base of the epiglottis. Epithelial necrosis was characterized by hypereosinophilia of the epithelial cells with nuclear pyknosis and karyorrhexis. While uncommon in the current study, this lesion was also considered to be related to CIMSTAR 3800 exposure.

Trachea: There was a single incidence of ulcer in 100 mg/m^3^ males (Table 18 and Table C-4) that was characterized by loss of the epithelium from the surface of the trachea, exposing the underlying basement membrane. This is a very uncommon spontaneous lesion and is likely due to CIMSTAR 3800 exposure.

## Genetic Toxicology

CIMSTAR 3800 (dose range tested, 1,000 to 10,000 µg/plate) was weakly mutagenic in Escherichia coli strain WP2 uvrA/pKM101 in the absence of exogenous metabolic activation (S9); no mutagenic activity was observed in Salmonella typhimurium strains TA98 and TA100 tested over the same dose range, with or without S9, or in the E. coli strain with S9 (Table E-1).

In vivo, no increases in the frequencies of micronucleated reticulocytes or erythrocytes were observed in peripheral blood samples from male or female F344/NTac rats or B6C3F1/N mice exposed to CIMSTAR 3800 via inhalation (25 to 400 mg/m^3^) for 3 months (Table E-2 and Table E-3). In female rats, a significant trend was observed for micronucleated erythrocytes (P = 0.003). However, in rats, the appropriate cell population to evaluate for frequency of micronucleated cells in peripheral blood is the very young newly emerged reticulocyte population because the rat spleen is very efficient at quickly sequestering and destroying damaged erythrocytes. Thus, despite the very slight increase in micronucleated erythrocytes in 400 mg/m^3^ female rats, the absence of supporting data in the female micronucleated reticulocyte data set and in the male rats suggests that the increase is not biologically significant.

In addition to the micronucleus endpoint, the percentage of reticulocytes among circulating red blood cells was calculated as a measure of bone marrow toxicity or perturbations in erythropoiesis (Table E-2 and Table E-3). No significant alterations in the percentage of reticulocytes among red blood cells was seen with CIMSTAR 3800, suggesting an absence of treatment-related bone marrow toxicity. The very small and inconsistent changes in percentage of reticulocytes noted in both the male and female mice, in the absence of any observed hematologic effects, were not considered biologically significant.

Figure 7

Lymphohistiocytic Inflammation in the Lung of a Male Wistar Han Rat Exposed to 100 mg/m^3^ CIMSTAR 3800 by Whole Body Inhalation for Two Years (H&E)

Note the unusual inflammatory response characterized by clusters of large, foamy macrophages surrounded by numerous mononuclear inflammatory cells. The variably sized, clear vacuoles that appear to be both intracellular (within macrophages) and extracellular are suggestive of the presence of lipid material.

Figure 8

Lymphohistiocytic Hyperplasia of the Bronchus-associated Lymphoid Tissue in the Lung of a Male Wistar Han Rat Exposed to 100 mg/m^3^ CIMSTAR 3800 by Whole Body Inhalation for Two Years (H&E)

Note the unusual hyperplastic lesion that is morphologically similar to the inflammation in the lung seen in these animals. It is characterized by clusters of large, foamy macrophages surrounded by numerous mononuclear inflammatory cells.

Figure 9

Dysplasia of the Epiglottis in the Larynx of a Male B6C3F1/N Mouse Exposed To 400 mg/m^3^ CIMSTAR 3800 by Whole Body Inhalation for Three Months (H&E)

Note the unusual exophytic growth of epithelial cells above the stratum corneum. The cells also have increased nuclear to cytoplasmic ratios and variability in the staining of the nuclei and cytoplasm. The epithelium, which is normally a single layer of ciliated cuboidal to columnar cells, also exhibits squamous metaplasia.