# Materials and Methods

## Procurement and Characterization of CIMSTAR 3800

CIMSTAR 3800 was obtained from Milacron (Cincinnati, OH) in three lots (60224BBN, 71205BN, and 90317JN). Lot 60224BBN was used during the 3-month studies, and lots 71205BN and 90317JN were used during the 2-year studies. Characterization and stability analyses of the test material were conducted by the analytical chemistry laboratory at Chemir Analytical Services (Maryland Heights, MO) and by the study laboratory at Battelle Toxicology Northwest (Richland, WA) (Appendix H). Reports on analyses performed in support of the CIMSTAR 3800 studies are on file at the National Institute of Environmental Health Sciences.

Spectra of lots 60224BBN, 71205BN, and 90317JN of the test material, a yellow-orange liquid, were obtained by the analytical chemistry laboratory using Fourier transform infrared (FTIR) spectroscopy. FTIR was used to estimate the relative presence of various functional groups and create a reference for future comparison for the same lot or different lots. In general, the spectra were consistent with the presence of organic amines, and the spectra of the three lots were similar to each other.

Analyses for all lots included Karl Fischer titration for water content; the determination of pH, specific gravity, and refractive index; elemental analysis for carbon, hydrogen, nitrogen, and sulfur using a C, H, N, S analyzer; and elemental and metal analysis using inductively coupled plasma/optical emission spectrometry (ICP/OES); chloride, nitrate, and nitrite analysis by ion chromatography; and iodide by ion specific electrode titration. The study laboratory initially identified general organic components using gas chromatography (GC) with flame ionization detection (FID) and identified the major components using GC with mass spectrometry (MS) (lot 60224BBN). Alkanolamines were identified and quantified using high performance liquid chromatography (HPLC) with MS detection. Methanol was quantified using GC/FID (lot 60224BBN) or GC/MS (lots 71205BN and 90317JN). The oil fraction was assessed using GC/MS and GC/FID. The total amount of hexane extractable material was determined gravimetrically. The amounts of bacteria and fungi were determined using a Sani-Check BF^®^ test kit (Biosan Laboratories, Warren, MI). Samples were diluted to 10% with sterile water and applied to paddles coated on one side with media for the determination of bacteria and on the other side for the determination of fungi, then incubated for 7 days at 25° to 30°C.

The test material was determined to be primarily composed of water, alkanolamines, and oil. Boron was present at approximately 0.6%. The material was basic with a pH of approximately 9.0. In general, the FTIR spectra were consistent with the presence of organic amines, which contained less than 0.01% of water soluble nitrates, nitrites, or chlorides. The mass balance percentages based on elemental and compound contributions resulted in 96% and 96% (lot 60224BBN) and 92% and 96% (lot 71205BN) coverage, respectively. There were no significant differences between the three lots. Taken together, these data indicate that all three lots of the test material were CIMSTAR 3800 with the expected composition of organic amines (Table H-3).

To ensure stability, the bulk test material was stored at approximately 63°F, protected from light, in metal drums. Periodic reanalyses of lots 71205BN and 90317JN were performed by the analytical chemistry laboratory and the study laboratory at least every 6 months during the 2-year studies. For each lot, FTIR spectra were obtained and compared to reference spectra of the same lot and other lots; determinations were made for the pH, specific gravity, and refractive index; determination and quantitation of alkanolamines were performed using HPLC/MS; assessment of fatty acid methyl esters was performed using GC/FID; and the amounts of bacteria and fungi were determined. No degradation of the bulk test material was detected.

## Aerosol Generation and Exposure System

The generation and delivery system used in the 3-month and 2-year studies consisted of two generator assemblies configured together so that the output from each assembly containing multi-jet nebulizers was directed to a common distribution line. CIMSTAR 3800 was continuously pumped to the liquid reservoir from the chemical cabinet reservoir by metering pumps during the aerosol generation process. A constant volume of test material was maintained in each assembly by a siphon tube inserted near the top of the assembly and connected to a vacuum source. Ports in the generator assembly introduced heated compressed air to drive the nebulizers and heated dilution air to transport aerosol to the distribution line.

High velocity compressed air created a vacuum in the liquid uptake tube that drew test material from the liquid reservoir into the multi-jet nebulizer streams where shear force broke the resultant liquid filaments into droplets. Large droplets were impacted on the impaction plate of the nebulizer or the generator assembly walls and were returned to the liquid reservoir; smaller droplets were drawn into the heated dilution air and transported to the common distribution line. The common distribution line was divided into two branches to supply aerosol to exposure chambers located on both sides of the exposure room; each branch line was insulated and terminated in a filter protecting the flowmeter controlling the line via the house vacuum supply. During exposures, at each chamber position, aerosol was removed from the distribution line and injected into a tee fitting and directed to the inlet of the exposure chamber where it was mixed with conditioned air to achieve the desired exposure concentration.

## Aerosol Concentration Monitoring

Summaries of the chamber aerosol concentrations are given in Table H-4 and Table H-5. The concentration of boron in CIMSTAR 3800 was monitored using real-time aerosol monitors (RAMs). The monitors were connected to the chambers by a sampling system designed by Battelle incorporating a valve that multiplexed each RAM to a 0 mg/m^3^ chamber or the room, a HEPA-filtered room air blank, and two exposure chambers. The output voltage of the RAM was recorded by a program designed by Battelle (Battelle Exposure Data Acquisition and Control) to select the correct sample stream and acquire a raw voltage signal from each RAM. Equations for the calibration curves resided within the program and were used to convert the measured RAM voltages to exposure chamber concentrations. Each RAM was calibrated by constructing a response curve using the measured RAM voltages (voltage readings were corrected by subtracting the RAM zero-offset voltage from measured RAM voltages) and boron in CIMSTAR 3800 concentrations that were determined by analyzing tandem filters collected daily from the exposure chambers.

For the 3-month studies and from April to July 24, 2008, in the 2-year studies, boron in CIMSTAR 3800 was extracted from the filters, shaken on an orbital shaker table, filtered and analyzed using ICP/OES. The ICP/OES instrument was calibrated against serially diluted CIMSTAR 3800 and a NIST-traceable spectrometric internal standard of yttrium. After July 24, 2008, to the end of the study, the calibration of the RAMs was based on gravimetric determination of the amount of test material on the filters. Samples were acidified, serially extracted with n-hexane, chemically dried, solvent evaporated, desiccated, and weighed.

## Chamber Atmosphere Characterization

Particle size distribution in each chamber was determined prior to the start of all studies and monthly during the studies. Impactor samples were taken from each exposure chamber using a Mercer-style seven-stage impactor and the stages were initially collected on glass coverslips lightly coated with silicone (stages 1–7) or filters (stage 8) and were analyzed by ICP/OES for boron in CIMSTAR 3800 for the 3-month studies and from April 2008 until July 23, 2008, for the 2-year studies. However, for the remainder of the 2-year studies, gravimetric samples were collected using stainless steel coverslips (stages 1–7) or glass fiber filters coated with Teflon^®^ (stage 8) and analyzed gravimetrically as described previously. The relative mass collected on each stage was analyzed by the CASPACT impactor analysis program developed at Battelle based on probit analysis^65^. The resulting estimates of the mass median aerodynamic diameter and the geometric standard deviation of each set of samples are given in Table H-6, Table H-7, and Table H-8.

Buildup and decay rates for chamber aerosol concentrations were determined with and without animals present in the chambers. At a chamber air flow rate of 15 cubic feet per minute, the theoretical values for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) was approximately 9.4 minutes for the 3-month and 2-year studies. T_90_ values of 18 minutes and 12 minutes were selected for the 3-month and 2-year studies, respectively.

The uniformity of aerosol concentration in the inhalation exposure chambers with animals present was measured once during the 3-month studies and was evaluated before the 2-year studies began without animals present and every 3 months during the 2-year studies. RAM measurements were taken from 12 different chamber positions. Chamber concentration uniformity was acceptable throughout the 3-month and 2-year studies.

The persistence of CIMSTAR 3800 in the exposure chambers was monitored after aerosol delivery ended by monitoring the concentration overnight in the 400 mg/m^3^ rat and mouse chambers during the 3-month studies and the 100 mg/m^3^ rat and mouse chambers during the 2-year studies with and without animals present. The average CIMSTAR 3800 concentration decreased to 1% of the target concentration within 18 (rats and mice, 3-month studies), 14 (male rats, 2-year studies), 16 (female rats and mice, 2-year studies), or 15 (without animals, 2-year studies) minutes.

Stability studies of the test material in the generation and exposure system were performed before and during the studies by the study laboratory and the analytical chemistry laboratory. For the 3-month and the 2-year stability studies without animals present in the exposure chambers, the relative amounts of the major constituents in the exposure atmosphere generally reflected that of the bulk test material. The concentrations of all constituents were higher in the liquid reservoirs at the end of the exposure day indicating the loss of water. Boron, triethanolamine, and fatty acid methyl esters were present primarily as particulates while ethanolamine and 1-amino-2-propanol had significant vapor phase contributions. The percentage of methanol in the liquid reservoirs was lower than that in the bulk test material.

Approximately 4 months into the 2-year studies, exposure chamber analyses with animals present indicated a shift in the relative amounts of several of the constituents relative to boron. Characterization of the test material was performed and compared with the results obtained prior to the study; all results were consistent, indicating that the test material was stable. Further investigation indicated that boron was not a good marker for the determination of CIMSTAR 3800 concentrations. The decision was made to calibrate the RAMs using CIMSTAR 3800 concentrations based on gravimetric determinations for the remainder of the 2-year studies.

Samples were collected, prepared, and analyzed gravimetrically. Instruments were calibrated for each method using gravimetrically prepared dilutions of the bulk test material. Constituents were within approximately 30% of the on-line monitor results in the distribution line and were comparable to the results observed during prestart assays. Triethanolamine concentrations were 95% to 107% of the on-line monitor results in the chamber atmosphere samples; fatty acid methyl ester concentrations were within 35% in the 10 mg/m^3^ chambers and 20% in 100 mg/m^3^ chambers. The relative proportions for boron and the volatile alkanolamines were reduced in the 100 mg/m^3^ chambers and the reductions were greater in the rat/mouse chambers than in the male rat chambers. The greatest degree of reduction was seen in the 10 mg/m^3^ rat/mouse chambers where boron was 34%, ethanolamine was 16%, and 1-amino-2-propanol was 30% of the expected values.

Methanol concentrations were increased in the reservoirs as well as the distribution line and exposure chambers. However, other volatile constituents (ethanolamine and 1-amino-2-propanol) were comparable in the reservoirs as well as the distribution line compared to prestart measurements while decreasing in the exposure chamber atmosphere with decreasing exposure concentrations, most significantly in the 10 mg/m^3^ exposure chambers.

The concentrations of all constituents were 94% to 108% relative to the bulk test material in the chemical cabinet reservoir at the end of the exposure day. Concentrations of these constituents were 117% to 150% higher in the liquid reservoirs indicating the loss of water, comparable to prestart measurements.

## Animal Source

Male and female F344/NTac rats were obtained from the commercial colony at Taconic Farms, Inc. (Germantown, NY), and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc., for the 3-month studies. Male and female Wistar Han [Crl:WI (Han)] rats were obtained from Charles River Laboratories (Raleigh, NC) and male and female B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc., for use in the 2-year studies. The rationale for change of rat strain from F344/N to F344/NTac was a programmatic decision. For many years NTP used the inbred F344/N rat for its toxicity and carcinogenicity studies. Over a period of time, the F344/N rat exhibited sporadic seizures and idiopathic chylothorax, and consistently high rates of mononuclear cell leukemia and testicular neoplasia. Because of these issues in the F344/N rat and NTP’s desire to find a more fecund rat model that could be used in both reproductive and carcinogenesis studies for comparative purposes, a change in the rat model was explored. Following a workshop in 2005, the F344 rat from the Taconic commercial colony (F344/NTac) was used for a few NTP studies to allow NTP time to evaluate different rat models between 2005 and 2006^66^. The Wistar Han rat, an outbred rat stock, was then selected because it was projected to have a long lifespan, resistance to disease, large litter size, and low neonatal mortality.

### Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to CIMSTAR 3800 and to determine the appropriate exposure concentrations to be used in the 2-year studies.

On receipt, rats were 3 to 4 weeks old and mice were 4 to 5 weeks old. Animals were quarantined for 11 days and were 5 to 6 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix J).

Groups of 10 male and 10 female rats and mice were exposed by whole body inhalation to CIMSTAR 3800 aerosol at concentrations of 0, 25, 50, 100, 200, or 400 mg/m^3^, 6 hours plus T_90_ (18 minutes) per day, 5 days per week for 14 weeks. Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Clinical findings were recorded after exposure on day 1, twice daily on days 2 through 5, 8 through 12, and 19, weekly thereafter, and at study termination. The animals were weighed initially, on days 6, 13, and 19, weekly thereafter, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Inhalation Studies of CIMSTAR 3800

Three-month Studies | Two-year Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA) | Battelle Toxicology Northwest (Richland, WA)
Strain and Species
F344/NTac rats B6C3F1/N mice | Wistar Han rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Rats: Charles River Laboratories (Raleigh, NC) Mice: Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
11 days | Rats: 13 days Mice: 12 days
Average Age When Studies Began
5 to 6 weeks | Rats: 6 weeks Mice: 5 to 6 weeks
Date of First Exposure
June 12, 2006 | Rats: April 14, 2008 Mice: May 5, 2008
Duration of Exposure
6 hours plus T_90_ (18 minutes) per day, 5 days per week, for 14 weeks | 6 hours plus T_90_ (12 minutes) per day, 5 days per week, for 105 weeks
Date of Last Exposure
Rats: September 11 (males) or 12 (females), 2006 Mice: September 13 (males) or 14 (females), 2006 | Rats: April 11–13 (males) or 13–15 (females), 2010 Mice: May 2–4 (males) or 4–6 (females), 2010
Necropsy Dates
Rats: September 12 (males) or 13 (females) 2006 Mice: September 14 (males) or 15 (females), 2006 | Rats: April 12–14 (males) or 14–16 (females), 2010 Mice: May 3–5 (males) or 5–7 (females), 2010
Average Age at Necropsy
Rats: 18 to 19 weeks Mice: 19 to 20 weeks | Rats: 110 to 111 weeks Mice: 109 to 111 weeks
Size of Study Groups
10 males and 10 females | 50 males and 50 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 3-month studies
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 wafers (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, except during exposure periods, changed weekly | Same as 3-month studies
Water
Tap water (Richland, WA, municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Same as 3-month studies
Cages
Stainless steel wire bottom (Lab Products, Inc., Seaford, DE), changed weekly, rotated on study days 5 through 12 then weekly within chambers | Same as 3-month studies, except rotated weekly within chambers
Cageboard
Techboard^®^ untreated paper excreta pan liner (Shepherd Specialty Papers, Kalamazoo, MI), changed daily | Techboard^®^ Ultra untreated paper excreta pan liner (Shepherd Specialty Papers, Watertown, TN), changed daily
Chamber Air Supply Filters
Single HEPA, new at study start; charcoal (RSE, Inc., New Baltimore, MI), new at study start; Purafil (Environmental Systems, Lynnwood, WA), new at study start | Same as 3-month studies, except HEPA changed annually
Chambers
Stainless steel, excreta pan at each of six levels (Lab Products, Inc., Seaford, DE), changed weekly, excreta pans changed daily | Same as 3-month studies
Chamber Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: 15 ± 2/hour | Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: 15 ± 2/hour
Exposure Concentrations
0, 25, 50, 100, 200, and 400 mg/m^3^ | 0, 10, 30, and 100 mg/m^3^
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, on days 6, 13 and 19, weekly thereafter, and at the end of the studies; clinical findings were recorded on day 1 after exposure, twice daily on days 2 through 5, 8 through 12, and 19, weekly thereafter, and at the end of the studies. | Observed twice daily; animals were weighed initially, weekly for 13 weeks, monthly thereafter, and at the end of the studies; clinical findings were recorded monthly and at the end of the studies.
Method of Kill
Carbon dioxide asphyxiation | Same as 3-month studies
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, spleen, right testis, and thymus. | Necropsies were performed on all animals.
Clinical Pathology
Blood was collected from the retroorbital plexus of rats and the retroorbital sinus of mice at the end of the studies for hematology and clinical chemistry (rats only). [underlined: Hematology]: hematocrit; packed cell volume; hemoglobin; erythrocyte, reticulocyte, nucleated erythrocyte, and platelet counts; Howell-Jolly bodies; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte counts and differentials [underlined: Clinical chemistry]: urea nitrogen, creatinine, total protein, albumin, globulin, glucose, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and total bile acids | None
Histopathology
Complete histopathology was performed on chamber control and 400 mg/m^3^ rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined to a no-effect level: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung (with bronchus), lymph nodes (bronchial, mandibular, mediastinal, mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis (with epididymis and seminal vesicle), thymus, thyroid gland, trachea, urinary bladder, and uterus. | Complete histopathology was performed on all rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung, lymph nodes (bronchial, mandibular, mediastinal, mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, and uterus.

Blood was collected from the retroorbital plexus of rats and the retroorbital sinus of mice at the end of the studies for hematology and clinical chemistry (rats only) analyses. For the hematology samples, blood was collected in tubes containing potassium EDTA; for the clinical chemistry samples, the blood was collected in a tube devoid of anticoagulant but containing a separator gel for serum. An Abbott Cell-Dyn 3700 (Abbott Diagnostics Systems, Abbott Park, IL) was used to determine packed cell volume; hemoglobin concentration; erythrocyte, platelet, and leukocyte counts; mean cell volume; mean cell hemoglobin; and mean cell hemoglobin concentration. Manual hematocrit values were determined using a microcentrifuge (Heraeus Haemofuge, Heraeus Holding GmbH; Hanau, Germany) and a Damon/IEC capillary reader (International Equipment Company, Needham Heights, MA) for comparison to Cell-Dyn values for packed cell volume. Blood smears were stained with a Romanosky-type aqueous stain in a Wescor 7100 slide stainer (Wescor, Inc., Logan, UT). Leukocyte differential counts were based on classifying a minimum of 100 white cells. Reticulocytes were stained with new methylene blue and enumerated as reticulocyte:erythrocyte ratio using the Miller disc method^67^. Blood samples for clinical chemistry analyses were analyzed using a Roche Hitachi 912 System (Roche Diagnostic Corporation, Indianapolis, IN). The hematology and clinical chemistry parameters measured are listed in Table 1.

Necropsies were performed on all animals. The heart, right kidney, liver, lung, spleen, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on chamber control and 400 mg/m^3^ rats and mice. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to an NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^68^ and Boorman et al.^69^.

## Two-year Studies

### Study Design

Groups of 50 male and 50 female rats and mice were exposed by whole body inhalation to CIMSTAR 3800 aerosol at concentrations of 0, 10, 30, or 100 mg/m^3^, 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 105 weeks.

Rats were quarantined for 13 days and mice were quarantined for 12 days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats were approximately 6 weeks old and mice approximately 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix J).

Rats and mice were housed individually. Feed was available ad libitum except during exposure periods; water was available ad libitum. Cages were rotated weekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix I.

### Clinical Examinations and Pathology

All animals were observed twice daily. Clinical findings were recorded every 4 weeks and at study termination. Body weights were recorded on day 1, weekly for 13 weeks, every 4 weeks thereafter and at study termination.

Complete necropsies and microscopic examinations were performed on all rats and mice. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution and testes were first fixed in a modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. A special study of the uterus was conducted to examine the residual uterine tissue for additional lesions. In the original evaluation, a transverse section through each uterine horn, approximately 0.5 cm distal to the cervix, was collected for histopathologic evaluation. For the residual evaluation, all remaining cervices, vaginas, and uterine remnants were processed, sectioned longitudinally (i.e., parallel to the long axis), and stained with hematoxylin and eosin. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all tumors and all potential target organs, which included the lung, larynx, and nose of rats and mice; bronchial and mediastinal lymph nodes, prostate gland, and testis of rats; and trachea of mice.

The QA report and the reviewed slides were submitted to the NTP PWG coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^68^ and Boorman et al.^69^. For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^70^.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^71^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^72^ method for testing two groups for equality and Tarone’s^73^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-3, Table B-1, Table B-3, Table C-1, Table C-4, Table D-1, and Table D-5 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal kill.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^74-76^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal kill; if the animal died prior to terminal kill and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time^74^. Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^74^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344/N rats and B6C3F1/N mice^77^. Bailer and Portier^74^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams^78^.

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1−P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N).

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^79^ and Williams^80; 81^. Hematology and clinical chemistry data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^82^ (as modified by Williams^83^) and Dunn^84^. Jonckheere’s test^85^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^86^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period^87-89^. In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the current mouse study. The current study is the only inhalation study in Wistar Han rats in the historical control database; therefore, only historical control incidences for all routes and all vehicles are used for Wistar Han rats in this Technical Report.

## Quality Assurance Methods

The 3-month and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations^90^. In addition, as records from the 3-month and 2-year studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of CIMSTAR 3800 was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli and increases in the frequency of micronucleated erythrocytes in rat and mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division^91; 92^. The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^93^ and the somatic mutation theory of cancer^94; 95^. However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites^96^. A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens)^97; 98^. Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test^99; 100^. However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies^101^. Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.