# Introduction

## Chemical and Physical Properties

CIMSTAR 3800 and all metalworking fluids are highly complex mixtures of chemicals. Only limited information exists about the chemical components of individual metalworking fluids because of the highly competitive and proprietary nature of the metalworking fluid industry. The identity and proportion of chemical species in these mixtures are dependent on a number of factors including the manufacturer and the cooling and lubrication requirements of the machining process. Metalworking fluids are classified into the general categories of straight oils, soluble oils, semisynthetic fluids, or synthetic fluids based upon the amount of highly refined oil they contain^1-3^. Straight oils contain 60% to 100% oil. The petroleum oils used in straight oil metalworking fluids are usually mineral oils from highly refined napthenic or paraffinic oils. The soluble oils (emulsifiable) and semisynthetic metalworking fluids contain 5% to 85% oil, and the synthetic fluids contain no oil.

CIMSTAR 3800 is classified as a semisynthetic metalworking fluid because it contains lower amounts of oil and higher amounts of water than the soluble or straight oil metalworking fluids. The manufacturer recommends diluting the CIMSTAR 3800 concentrate to 5% to 10% in water. The concentrated semisynthetic metalworking fluids generally are diluted to 5% to 20% in water. These solutions form oil-water emulsions with the water acting as a cooling agent and the oil providing lubrication. The semisynthetic metalworking fluids may also be formulated with mineral oils, fatty acids, sulfur, chlorine, and phosphorus derivatives to provide enhanced lubrication for higher speeds and feed rates^4^. Other additives can include detergents to lower surface tension, polyol ester as an “oiliness agent,” petroleum sulfonate as an emulsifier, alkanolamines to provide reserve alkalinity and inhibit corrosion, chlorinated paraffins as “extreme pressure agents,” long chain fatty alcohols as defoamers, triazoles as a metal passivator, antioxidants, dyes, and biocides^5^.

The composition of in-use metalworking fluids is considerably different from unused metalworking fluids. Because metalworking fluids are expensive, single use is not economically feasible. The useable lifetime of metalworking fluids is extended by recycling the fluids in a circulating system that filters out solid contaminants. However, physical and chemical effects can cause the components of in-use metalworking fluids to deteriorate. Environmental contaminants such as wear debris, rust, weld spatter, metal chips and abrasives, as well as contaminants entering through broken seals, dirty oil filter pipes, and chemical residue on metal parts can accelerate metalworking fluid breakdown. In addition, excessive temperatures can cause oxidation of metalworking fluid oils and constituents leading to the formation of acids, resins, varnishes, sludges, and carbonaceous deposits. Additives may be depleted with use, requiring routine product addition or supplemental additions to maintain metalworking fluid performance.

Water-based metalworking fluids are excellent nutritional sources for many kinds of bacteria and fungi, and contamination of in-use metalworking fluids is a problem in the metalworking industries. Bacteria, bacterial endotoxins, and fungi in metalworking fluid aerosols are a concern because of potential respiratory effects when inhaled by workers and skin infections following dermal contact. Antimicrobial agents are often added to metalworking fluids to control the growth of microbes and to extend the usable life of these fluids. Some microbiocidal or microbiostatic activities of antimicrobial agents occur through the release of formaldehyde. Formaldehyde is an airway irritant and a recognized cause of occupational asthma^6^. Studies suggest that exposure to certain antimicrobial agents can cause allergic or irritant contact dermatitis^7^.

Compositions of metalworking fluids are being continuously changed to improve various functions and reduce potential toxicity. Efforts to reduce exposures to potential carcinogens in metalworking fluids have been ongoing. Removal of polycyclic aromatic hydrocarbons (PAHs) from metalworking fluids began in the 1950s, and United States Environmental Protection Agency (USEPA) regulations in the 1980s were directed at reducing nitrosamine exposures. In addition, efforts to reduce volatile organic compounds have resulted in the increased use of water as a major component of currently used metalworking fluids. For these reasons, toxicity and carcinogenicity data on metalworking fluids obtained prior to the 1980s may not apply to metalworking fluids currently in use. Although many carcinogenic components have been removed, the newer metalworking fluids have not been tested so the cancer risk is not clear.

## Production, Use, and Human Exposure

CIMSTAR 3800 is a semisynthetic metalworking fluid manufactured by one of the four largest metalworking fluid manufacturers and was considered a high-production formulation based on selection criteria used by the National Institute for Occupational Safety and Health (NIOSH). Metalworking fluid production and use data are considered proprietary information by the metalworking fluid manufacturers and these data are not available. The Independent Lubricant Manufacturers Association reported that 95 to 103 million gallons of metalworking fluids were produced annually in the United States from 1994 to 1999^8^. In 1999, five companies each reported producing more than 5 million gallons of these fluids. The largest category of metalworking fluids in terms of industry consumption is the metal removal fluids with more than 100 million gallons consumed annually^8^. Metal removal fluids are typically classified as either nonmiscible or miscible with water. Nonmiscible metal removal fluids are straight oils or neat oils and typically mineral oils. Miscible metal removal fluids are subdivided into water-soluble oils, semisynthetic fluids, and synthetic fluids. It is estimated that 80 million gallons of miscible metal removal fluids are sold each year in the United States and that this constitutes approximately 75% of the total metal removal fluid market.

Metalworking operations require application of lubricant and coolant liquids on the surface of the workpiece and the tool to remove heat, remove fine swarf (metal chips), and provide corrosion inhibition at the newly cut surface. CIMSTAR 3800 is recommended for use in general machining and grinding of automotive aluminum parts. It is also used on light to moderate machining and grinding of light steel, stainless steels, hardened steels, and other materials.

The National Occupational Exposure Survey^9^ estimates that 1.2 million workers are potentially exposed to metalworking fluids. A more recent exposure survey has not been conducted; however, health hazard evaluations from the NIOSH^10^ indicate that exposures to metalworking fluid aerosols have decreased over time.

Exposure to metalworking fluids occurs primarily from inhalation of aerosols and dermal contact with aerosols or wetted equipment. Workers can receive significant exposure to metalworking fluids by inhalation of aerosols^11^. Aerosols form when a metalworking fluid is subjected to high shear forces or excess heat during use. The characteristics of these aerosols are dependent upon the particular metalworking fluid and the machining process for which it is being used; however, some aerosols can be stable and long lasting^12^. Dermal exposure to metalworking fluids can occur through contact with contaminated equipment, from splashes, or exposure to aerosols. The components and alkalinity of metal-working fluids are well-known causes of dermatitis in workers^13; 14^. CIMSTAR 3800 concentrate is diluted with water prior to use, and the aerosols generated in the workplace are composed of 90% to 95% water. In the current studies, it was not feasible to generate liquid aerosols containing up to 90% water without saturating the chamber air; therefore, aerosols were generated from the undiluted concentrate and diluted with clean air to produce the desired concentrations. As a result, the exposure concentrations in the current studies were considerably higher than those encountered in the workplace.

## Regulatory Status

NIOSH recommends an exposure limit (REL) for all metalworking fluid aerosols of 0.4 mg/m^3^ for thoracic particulate mass as a time-weighted average concentration for up to 10 hours per day during a 40-hour work week. Because of the limited availability of thoracic samplers, measurement of total particulate mass is an acceptable substitute. The NIOSH REL for total particulate mass is 0.5 mg/m^315^.

## Absorption, Distribution, Metabolism, and Excretion

No studies evaluating the absorption, distribution, metabolism, or excretion of metalworking fluids in experimental animals or humans were found in the literature.

## Toxicity

### Experimental Animals

Animal models have been used to evaluate the respiratory toxicity of different classes of metalworking fluids. Schaper and Detwiler^16^ used a mouse model of pulmonary irritation^17^ to compare the effects of different classes of metalworking fluids on pulmonary function of mice. Inhalation of straight oil aerosols did not cause as great a response (increased breathing rate) as exposure to semisynthetic fluids, synthetic fluids, or soluble oils. There were no significant differences in pulmonary irritation caused by used versus unused metalworking fluids. In a subsequent study^18^, the same mouse model was used to evaluate the sensory irritation and pulmonary irritation properties of 10 metalworking fluids and to identify the contribution of three major components. Sensory irritation was caused mainly by tall oil fatty acids, whereas pulmonary irritation was caused primarily by sodium sulfonate. Paraffinic oils decreased the irritant properties of both tall oil fatty acids and sodium sulfonate.

Lim et al.^19^ investigated the respiratory toxicity of a water-soluble metalworking fluid in F344 rats exposed to aerosol concentrations of 0, 20, 60, or 180 mg/m^3^ 6 hours per day, 5 days per week for 13 weeks. Pulmonary inflammation consisting of increases in lung weights, bronchoalveolar lavage (BAL) neutrophils, and foamy macrophages and thickening of the alveolar walls was observed at the two highest concentrations.

The effects of metalworking fluids contaminated with endotoxins have been investigated in experimental animals by several groups of investigators. Acute inhalation exposure of mice to a high concentration of in-use metalworking fluid aerosol contaminated with endotoxin caused a significant elevation of neutrophils, TNF-α, and IL-6 in BAL fluid^20^. Acute exposure of rats to a low concentration of metalworking fluid containing endotoxin also caused an increase in BAL neutrophils^21^. Lim et al.^22^ investigated the effects of repeated exposure to a water-soluble metalworking fluid with and without endotoxin for 2 weeks. Endotoxin-contaminated metalworking fluid caused a significantly elevated inflammatory response in the lung relative to uncontaminated metalworking fluid.

### Humans

Occupational exposure to metalworking fluid aerosols is associated with a variety of nonmalignant respiratory conditions. Hypersensitivity pneumonitis involves an immunologic reaction in the lung to inhaled antigen and may require prior sensitization to the antigen. This disease is characterized in its acute phase by alveolar inflammation and influenza-like symptoms. In its chronic phase (following repeated exposures), it is characterized by pulmonary fibrosis associated with respiratory impairment. Two cases of hypersensitivity pneumonitis associated with metalworking fluids were reported during a 3-year period to an occupational respiratory disease surveillance program operating in the United Kingdom^23^. Many more cases in North America have been recently recognized^24-27^.

A variety of components, additives, and contaminants of metalworking fluids are sensitizers or irritants known to induce new-onset asthma, aggravate preexisting asthma, or irritate the airways of non-asthmatic workers. These sensitizers, irritants, or toxicants include ethanolamine and other amines, colophony, pine oil, tall oil, metals and metallic salts (e.g., chromium, nickel, cobalt, and tungsten carbide), castor oil, formaldehyde, chlorine, various acids, and fungal and other microbial contaminants (including gram-negative bacterial endotoxin)^28-30^. However, only a few of these agents have been documented as causes of metalworking fluid-associated asthma.

Considered in aggregate, several studies provide evidence indicative of an elevated risk of asthma among workers exposed to metalworking fluid aerosol concentrations currently found in large metalworking shops. As suggested by published clinical case reports, asthma induced by metalworking fluids appears to involve known sensitizers in some cases; however, various other agents acting possibly through irritant or inflammatory mechanisms may be responsible for a high proportion of metalworking fluid-associated asthma cases. Some evidence from cross-sectional studies strongly suggests a tendency for affected workers to transfer away from jobs with exposure to metalworking fluids.

With respect to metalworking fluid type, exposure to metalworking fluid aerosols in operations using synthetic fluids has been associated with asthma^31-33^. There is also evidence suggesting a causal association between asthma and exposure to soluble metalworking fluid aerosols, but it is somewhat less consistent than that for synthetic metalworking fluid exposures. Case reports have documented asthma caused by exposure to soluble oil metalworking fluids^28; 34^ or to common components of soluble oil metalworking fluids^35^. A surveillance program in Michigan received 13 case reports of occupational asthma attributed to soluble oil metalworking fluids during 1988 to 1994^33^, although some of the plants in which these patients worked may have also been using straight oil metalworking fluids. Of the seven relevant epidemiologic studies, results consistent with statistically significant elevated risk estimates were presented only by Greaves et al.^32^ (for cumulative exposure) and Rosenman et al.^33^. Findings of three of the other five studies indicated elevated, though not statistically significant, risk estimates for asthma, with point estimates ranging upward from 2.1^36-39^. Thus, the overall evidence also suggests an association between asthma and exposure to straight oil metalworking fluid aerosol^33; 34; 40^.

Epidemiologic studies of respiratory symptoms present generally consistent, and in the case of the more recent studies, compelling evidence that occupational exposure to metalworking fluid aerosols causes symptoms consistent with airway irritation, chronic bronchitis, and asthma. The evidence suggests that at least three classes of metalworking fluids (straight oil, soluble oil, and synthetic) are capable of inducing respiratory symptoms at aerosol exposure concentrations that are currently typical of large metalworking shops. To date, there is no convincing evidence that identifies any particular component or components of metalworking fluid aerosol as the predominant cause of these symptoms, although some irritant components of metalworking fluid are clearly suspect^41^. One large multiplant study in the United States with mean exposures for the major types of metalworking fluids ranging from 0.41 to 0.55 mg/m^3^ (thoracic fraction) found statistically significant quantitative exposure-response relationships between cumulative concentration of metalworking fluid aerosols and respiratory symptoms^32^. Likewise, another United States study found significant exposure-response relationships between aerosol exposure concentration and chest symptoms^41^. In addition, other studies have shown the onset or worsening of many symptoms in workers over the course of a work shift^33; 36; 41^ and substantial symptomatic improvement in affected workers when away from work^32^. Thus, controlling worker exposures can prevent chronic effects induced by metalworking fluid aerosol exposure and may reverse early metalworking fluid-induced airway effects.

## Reproductive and Developmental Toxicity

No studies on metalworking fluid reproductive or developmental toxicity in experimental animals or humans were found in the literature.

## Carcinogenicity

### Experimental Animals

There have been no carcinogenicity studies of CIMSTAR 3800 in animals. Six studies have examined the carcinogenicity of metalworking fluids in experimental animals^42-47^. Three of these studies reported findings related only to the skin^43-45^. Of these three studies, one examined unrefined cutting oil^43^, one examined solvent-extracted cutting oil^45^, and the third did not specify how the cutting oil was refined, although the cutting oil was probably highly refined as the PAH content was only 5.22%^44^. The study by Gilman and Vesselinovitch^43^ found that among mice receiving skin applications of soluble cutting oils formulated from unrefined distillates three times weekly for 310 days, 61% developed skin tumors (22% of these had carcinomas) while no tumors occurred in the unexposed control group. Jepsen et al.^45^ reported that among mice receiving skin applications of solvent-extracted cutting oils, 80% developed papillomas after exposure to undiluted soluble oil while there were no papillomas in mice exposed to diluted soluble oil. Jepsen et al.^45^ also studied paraffin- and naphthalene-based straight oil metalworking fluids and found that 45% or 0% of mice developed papillomas after exposure to unused or used paraffin-based solvent-refined straight oil metalworking fluid (level of refining unspecified), respectively. These investigators also reported that 40% or 100% of mice developed papillomas after exposure to unused or used naphthalene-based straight oil metalworking fluid (level of refining unspecified), respectively. Another study found that both unused and used cutting oils were potent skin tumor initiators^44^. These investigators reported that among mice given a single application of a cutting oil and thrice weekly application of the tumor promoting agent 12-O-tetradecanoyl-phorbol-13-acetate, 90% or 60% of mice developed benign skin cancers after exposure to unused or used cutting oil, respectively.

Three other animal studies examined the carcinogenic effects of metalworking fluid exposure on the skin and other organs^42; 46; 47^. In one study of 20 mice receiving skin applications of used cutting oils (type of refining unspecified) one to three times weekly for 6 months, two mice developed pulmonary cancer, and one of the two mice also developed skin cancer; none of the control mice developed cancer^42^. In a 2-year study in Wistar rats, pancreatic carcinoma occurred in nine of 40 rats dosed with undiluted rustproof cutting fluid consisting of sodium nitrite, triethanolamine (TEA), and polyethylene glycol, while none of the control rats developed pancreatic cancer^47^. All three of the components reported to be in this rustproof cutting fluid can be found in some metalworking fluids used in the United States. A third study found no evidence of carcinogenicity from solvent-extracted cutting oils^46^.

Specific components of metalworking fluids [e.g., diethanolamine (DEA), TEA, nitrosoamines, and formaldehyde] have been evaluated for carcinogenic potential on an individual basis. Variable amounts of alkanolamines are present in many metalworking fluids. The carcinogenicity of TEA was investigated because of its potential conversion to the carcinogen N-nitrosodiethanolamine (NDELA). Following dermal exposure for 2 years, there was equivocal evidence of carcinogenic activity of TEA in male F344/N rats based on marginally increased incidences of renal tubule cell adenoma and no evidence of carcinogenicity in female rats^48^. In a 2-year dermal study of TEA in B6C3F1 mice, there was equivocal evidence of carcinogenicity in males based on the occurrence of liver hemangiosarcoma and some evidence of carcinogenicity in females based on increased incidences of hepatocellular adenoma^49^. The carcinogenicity of DEA was also studied in F344/N rats and B6C3F1 mice in a 2-year dermal exposure study^50^. There was no evidence of carcinogenic activity in rats; however, there was clear evidence of carcinogenic activity of DEA in mice based on increased incidences of liver neoplasms in males and females and increased incidences of renal tubule neoplasms in males. DEA is not present in CIMSTAR 3800.

### Humans

There have been no epidemiologic studies to evaluate the carcinogenicity of CIMSTAR 3800 in humans. Substantial evidence exists for increased risk of squamous cell skin cancer^51-53^ especially of the scrotum^54-56^ following exposure to metalworking fluids. The International Agency for Research on Cancer^57^ designated unused and mildly used mineral oil as carcinogenic to humans based on squamous cell carcinoma of the skin, sinonasal cancer, and bladder cancer. NIOSH^15^ concluded that substantial evidence exists for an increased risk of cancer at several tissue sites (larynx, rectum, pancreas, skin, scrotum, and urinary bladder) associated with at least some of the metalworking fluids used before the mid-1970s. The inconsistencies between studies with respect to the tissue sites that were affected, and the variation in the strength of association between the surrogates of exposure and specific sites are most likely related to the diverse nature of the metalworking fluid mixtures studied, the absence of detailed exposure information, and the limitations of the epidemiologic tools with which metalworking fluid exposures have been studied. The evidence is equivocal for an association between metalworking fluid exposure and cancer at several other sites including the stomach, esophagus, lung, prostate gland, brain, colon, and hematopoietic system.

Given the small number of epidemiologic studies that have adequate exposure characterization, the specific metalworking fluid constituents or contaminants responsible for the various site-specific cancer risks remain to be determined. The study with the most statistical power and detailed exposure information included more than 46,000 autoworkers in Michigan^58^. Results of this study suggest that specific classes of metalworking fluids are associated with cancer at certain sites. However, within these metalworking fluid classes, the specific formulations responsible for the elevated cancer risks remain to be identified. Within the Tolbert et al.^58^ study, straight oil exposure was modestly associated with increased risks for laryngeal and rectal cancers, and there was limited evidence that synthetic metalworking fluid exposure was associated with an increased risk for pancreatic cancer. Subsequent case-control studies based on the original cohort have confirmed the association of laryngeal cancer with straight oil metalworking fluids^59^, and the association of pancreatic cancer with synthetic metalworking fluids^60^. The Tolbert et al.^58^ study found less evidence that soluble oil metalworking fluid exposure is associated with cancer at any specific site. The most recent extension of this study up to 2005 added a follow-up for incident cancer. The cohort was limited to white males hired after 1938. The results of this evaluation provided evidence that oil-based metalworking fluids, especially straight mineral oils, were associated with an increased incidence of malignant melanoma^61^. In another evaluation of the same incident cohort, long-term dermal exposure to oil-based metalworking fluids was reported to cause an increased risk of nonseminomatous testicular germ cell cancer^62; 63^.

The studies that provide most of the data suggesting an association between metalworking fluid exposure and cancer involved workers employed as early as the 1930s and as late as the mid-1980s. Because there is a latency period of 10 to 20 years between initial exposure to a carcinogen and the initial appearance of a solid-organ cancer caused by that carcinogen, the excess cancer mortality observed in these cohort studies most likely reflects the cancer risk associated with exposure conditions in the mid-1970s and earlier. Over the last several decades, substantial changes have been made in the metalworking industry, including changes in metalworking fluid composition, reduction of impurities, and reduction of exposure concentrations. These changes have likely reduced the cancer risks. However, since the epidemiologic data do not usually identify the metalworking fluid composition and impurities associated with the cancer risks observed in earlier cohorts, there are insufficient data to conclude that these changes will have eliminated all carcinogenic risks. The risk of cancer from metalworking fluid exposures in the mid-1970s and later remains to be determined because a definitive study has not yet been conducted on workers entering metalworking fluid-exposed jobs during this period. Thus, there is an unclear potential for current metalworking fluids to pose a similar carcinogenic hazard.

## Genetic Toxicity

One epidemiologic study was identified in the literature that evaluated levels of DNA strand breaks, measured by alkaline elution, in 65 metalworkers occupationally exposed to synthetic cutting fluids in seven plants in Germany^64^. In this study, DNA damage levels were correlated with airborne concentrations of NDELA, a genotoxic contaminant present in some metalworking fluids, and with duration of daily exposure to cutting fluids. Workers employed in areas with high concentrations of NDELA (>500 ng/m^3^) had a significantly (P < 0.01) elevated mean number of DNA strand breaks in mononuclear blood cells compared with workers employed in areas with less than 50 ng NDELA/m^3^ (1.69 ± 0.34 versus 0.76 ± 0.05, respectively). In addition, of the 37 nonsmokers among the 65 metalworkers, those who worked with cutting fluids more than 4.5 hours/day had a significantly (P < 0.02) elevated mean number of DNA strand breaks compared with those who worked less than 4.5 hours/day (1.34 ± 0.12 versus 0.91 ± 0.12, respectively). NDELA can be formed in metalworking fluids when DEA or TEA, present in these fluids, react with a nitrosating agent. However, in 1984, the USEPA prohibited the addition of nitrosating agents to metalworking fluids, which precludes extrapolation of this finding to CIMSTAR 3800. Fuchs et al.^64^ did not provide details regarding the composition of the various metalworking fluids to which workers were exposed in their study, and therefore, it is not possible to determine if the correlation between DNA damage and increasing duration of exposure might have been due to ingredients other than NDELA that may also be present in the CIMSTAR 3800 formulation.

## Study Rationale

CIMSTAR 3800 is one of two semisynthetic metalworking fluids nominated by NIOSH for study by the National Toxicology Program. The nomination of CIMSTAR 3800 for inhalation studies is based upon its high production volume, the large number of occupationally exposed workers, the lack of carcinogenicity and chronic toxicology data for this class of complex mixtures, and epidemiologic data indicating an increased incidence of laryngeal cancer in workers exposed to metalworking fluids.