# Appendix K Summary of Peer Review Panel Comments

On May 22, 2014, the draft Technical Report on the toxicology and carcinogenesis studies of CIMSTAR 3800 received public review by the National Toxicology Program’s Technical Reports Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. D.L. Morgan, NIEHS, introduced the toxicology and carcinogenesis studies of CIMSTAR 3800, a semi-synthetic metalworking fluid by discussing the uses of the chemical and the rationale for study, describing the experimental design, reporting on survival and body weight effects, and commenting on compound-related neoplastic and nonneoplastic lesions in rats and mice. The proposed conclusions for the 2-year studies were equivocal evidence of carcinogenic activity in male and female Wistar Han rats, no evidence of carcinogenic activity in male B6C3F1/N mice, and some evidence of carcinogenic activity in female B6C3F1/N mice.

Dr. Mirsalis asked Dr. Morgan about the justification for using inhalation versus dermal exposure, and Dr. Morgan replied that inhalation is likely the most common occupational route of exposure. Dr. P.C. Howard, FDA, asked if the target droplet size was based on industry standards for conducting inhalation toxicology studies, not necessarily the droplet size to which workers could be exposed. Dr. Morgan stated droplet size was based on NTP standards for inhalation studies in rodents.

Dr. Carpenter noted receipt and distribution to the Panel of written comments from Mr. J.L. Leiter on behalf of the Independent Lubricant Manufacturers Association (ILMA).

Dr. F.E. Mirer, CUNY School of Public Health, spoke by telephone on his own behalf and described his background related to the subject of metalworking fluids. He related a history of the project, which dated back to a petition by the United Automobile Workers to NTP for bioassay of respiratory effects and carcinogenicity of representative metalworking fluids and stated that respiratory effects were of as much public health concern as carcinogenicity. He recommended that the report note that nearly 100% of the rats in the 3-month and 2-year studies had some upper respiratory lesions even at the lowest exposures. He said the adjusted incidences should be calculated for non-tumor pathology so the results could be included in a benchmark dose analysis, and only NTP could do so. He argued that the lung neoplasms in female mice should be seen as clear evidence and asked for clearer discussion of composition in the report, listing some of the details for clarification.

Dr. W. Dalbey, DalbeyTox, LLC, speaking on behalf of ILMA, questioned the characterization of exposures in the report, particularly whether a vapor phase was monitored during exposures. He questioned the method used for gravimetric measurement of the aerosol phase, and noted the composition of the aerosol was not apparent. He said the criteria for evidence of carcinogenicity were sometimes unclear in the report, referring to the conclusions related to prostate gland and brain neoplasms in male rats and the lung neoplasms in mice. Similarly, he raised questions about the basis for the equivocal evidence conclusion for skin neoplasms in female rats. He approved of labelling CIMSTAR 3800 “weakly mutagenic.”

Dr. J.K. Howell, GHS Resources, Inc., also spoke on behalf of ILMA. He provided general information about metalworking fluids and the characterization of CIMSTAR 3800. He stressed that metalworking fluids are complex mixtures, with thousands of formulations commercially available. He suggested several editorial changes to the report, including additional references to unintended substances in metalworking fluids and addition of language describing occupational levels of aerosol exposure to metalworking fluids as opposed to experimental concentrations used in the current studies. He questioned the characterization of CIMSTAR 3800 in the report, and recommended adding a table describing the composition of CIMSTAR 3800. He asked for correction on the statement that no biocide was present, citing the updated Material Safety Data Sheet (MSDS).

Dr. Regan, the first primary reviewer, said this was a difficult study from a pathology standpoint and was very well done. She said comments about the incidences of uterine neoplasms should be limited to the combined final numbers. She asked if there were any animals that had both granulosa cell tumors of the ovary and adenocarcinomas or Müllerian tumors of the uterus and if the skin neoplasms in rats were associated with the chronic active inflammation that was observed. She suggested adding a table for the components analyzed in CIMSTAR 3800 along with information indicating if there was any evidence of bacterial or fungal growth or bacterial endotoxin in the test material. She asked whether the historical control data presented also had residual uterine tissue examinations performed.

Dr. Morgan said he could add a table as suggested by Dr. Regan and noted the information on bacterial and fungal counts was in Appendix H; however, the information could be brought into the Materials and Methods section. He said endotoxin was not measured. Regarding the discussion about relative exposures, he noted it was addressed in the Discussion section, but it could be expanded.

Dr. M.F. Cesta, NIEHS, said none of the animals had both granulosa cell tumors of the ovary and adenocarcinomas or Müllerian tumors of the uterus. He stated that none of the skin neoplams in rats were associated with chronic active inflammation. Regarding the historical control data, he said it only included the original sections, not residual sections. Dr. Regan noted the overall historical incidence of adenocarcinomas in rats was seven in 150, and asked if that incidence was based solely on original sections, which Dr. Cesta confirmed.

Dr. Fanucchi, the second primary reviewer, agreed with Dr. Regan’s comments. She said in Appendix H, it was shown that boron was originally used as a marker for the aerosol monitors, and later a gravimetric method was used; she asked how the methods were correlated. She noted that the report reviewed epidemiologic studies that suggest laryngeal cancer may be associated with occupational exposure to machining fluids, but the observed increased incidences of metaplasia in the larynges of treated animals in the current studies were not considered in the evidence of carcinogenicity. Dr. Fanucchi also asked about the presence of a biocide in CIMSTAR 3800, noting that two compounds tentatively identified in the chemical analysis of the test material may act as biocides. She noted the 2-year studies began in 2008, and a 2008 MSDS did not list a biocide.

Dr. Morgan said a biocide had tentatively been identified, and the report could be changed to reflect its presence. He said the switch to the gravimetric method had been made 4 months into the 2-year studies and was done to eliminate drift in the relative amounts of compounds. Dr. Fanucchi said what was written was unclear as to whether boron was a bad marker, and she asked how it would be known that the first 4 months matched with the remainder of the studies. Dr. Morgan said chamber concentrations were measured with and without animals present and he said that boron worked well in the 3-month studies with fewer animals in the chambers. After 4 months of the 2-year studies, with more animals present in the chambers, drift was noted, and a switch was made to the gravimetric method. He said the issue could be clarified in the report.

Dr. Cesta said that squamous metaplasia is not considered to be a preneoplastic lesion, and it does not lead to laryngeal neoplasia. Dr. Fanucchi asked for this point to be clarified in the report. Dr. Conner said that laryngeal changes are commonly seen in respiratory studies.

Dr. Mahrt, the third primary reviewer, asked whether NTP considered looking at the literature or other sources for Wistar Han rats to add to the information on historical controls. Dr. Morgan said that had not been done, as such information would be very study-dependent and may not be relevant to the NTP study.

Dr. Mahrt asked for clarity in the report on the historical controls involved with the original uterine sectioning and if there were some historical controls with the residual longitudinal uterine sectioning. Dr. Cesta responded it could be clarified in the report which animals were included in the historical controls.

Dr. Regan moved that the conclusion regarding incidences of benign or malignant granular cell tumors (combined) of the brain in male Wistar Han rats be changed from equivocal evidence to no evidence. Dr. Mirsalis seconded the motion, noting that the incidence of three tumors at the lowest exposure was not strong. Dr. Regan added there was also the occurrence of such tumors in the chamber control female rats, and Dr. Mahrt agreed, noting there were limited historical control data. The panel voted six to zero to accept the conclusions as amended.