# Appendix J Sentinel Animal Program

## J.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected from each animal and allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately and evaluated for the presence of pathogens. For the 3-month study, samples were tested in-house or sent to BioReliance Corporation (Rockville, MD). For the 2-year study, samples were tested in-house or sent to the Research Animal Diagnostic Laboratory, University of Missouri (Columbia, MO). The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed (Table J-1).

Table J-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

| Method/Test | Time of Collection
Rats
Three-month Study
ELISA
| Mycoplasma pulmonis | 2 weeks
| PVM (pneumonia virus of mice) | 2 weeks, study termination
| RCV/SDA (rat coronavirus/ sialodacryoadenitis virus) | 2 weeks, study termination
| RPV (rat parvovirus) | 2 weeks
| Sendai | 2 weeks, study termination
Immunofluorescence Assay
| Parvovirus | Study termination
Two-year Study
ELISA
| M. pulmonis | 2 weeks
| PVM | 2 weeks
| RCV/SDA | 2 weeks
| RPV | 2 weeks
| Sendai | 2 weeks
Multiplex Fluorescent Immunoassay
| KRV (Kilham’s rat virus) | 6, 12, and 18 months, study termination
| M. pulmonis | 6, 12, and 18 months, study termination
| Parvo NS-1 | 6, 12, and 18 months, study termination
| PVM | 6, 12, and 18 months, study termination
| RMV (rat minute virus) | 6, 12, and 18 months, study termination
| RPV | 6, 12, and 18 months, study termination
| RTV (rat theilovirus) | 6, 12, and 18 months, study termination
| RCV/SDA | 6, 12, and 18 months, study termination
| Sendai | 6, 12, and 18 months, study termination
| TMEV (Theiler’s murine encephalomyelitis virus) | 6, 12, and 18 months, study termination
| Toolan’s H-1 | 6, 12, and 18 months, study termination
Immunofluorescence Assay
| M. pulmonis | 12 months
| RPV | Study termination
| RTV | Study termination
Mice
Three-month Study
ELISA
| Ectromelia virus | Study termination
| EDIM (epizootic diarrhea of infant mice) | Study termination
| LCM (lymphocytic choriomeningitis virus) | Study termination
| MAd-1 (mouse adenovirus) | Study termination
| MHV (mouse hepatitis virus) | 2 weeks, study termination
| MMV VP2 (mouse minute virus viral protein 2) | Study termination
| MPV (mouse parvovirus) | 2 weeks
| MPV VP2 (mouse parvovirus viral protein 2) | Study termination
| M. pulmonis | 2 weeks
| PVM | 2 weeks, study termination
| REO3 (reovirus 3) | Study termination
| Sendai | 2 weeks, study termination
| TMEV | 2 weeks, study termination
Immunofluorescence Assay
| EDIM | Study termination
| MAd-1 | Study termination
| MPV | Study termination
| PVM | Study termination
Two-year Study
ELISA
| GDVII (mouse poliovirus, strain GDVII) | 2 weeks
| MHV | 2 weeks
| MPV | 2 weeks
| PVM | 2 weeks
| Sendai | 2 weeks
| M. pulmonis | 2 weeks
Multiplex Fluorescent Immunoassay
| Ectromelia virus | 6, 12, and 18 months, study termination
| EDIM | 6, 12, and 18 months, study termination
| LCM | 6, 12, and 18 months, study termination
| M. pulmonis | 6, 12, and 18 months, study termination
| MHV | 6, 12, and 18 months, study termination
| MNV (mouse norovirus) | 6, 12, and 18 months, study termination
| Parvo NS-1 | 6, 12, and 18 months, study termination
| MPV | 6, 12, and 18 months, study termination
| MVM (minute virus of mice) | 6, 12, and 18 months, study termination
| PVM | 6, 12, and 18 months, study termination
| REO3 | 6, 12, and 18 months, study termination
| Sendai | 6, 12, and 18 months, study termination
| TMEV/GDVII (Theiler’s murine encephalomyelitis virus/mouse poliovirus, strain GDVII) | 6, 12, and 18 months, study termination
Immunofluorescence Assay
| Sendai | 12 months
| MPV | 18 months
| MVM | 6 and 18 months
| MNV | Study termination
Polymerase Chain Reaction
| Helicobacter species | 18 months

## J.2 Results

All test results were negative.