# Appendix I Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table I-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground hard winter wheat | 22.26
Ground #2 yellow shelled corn | 22.18
Wheat middlings | 15.0
Oat hulls | 8.5
Alfalfa meal (dehydrated, 17% protein) | 7.5
Purified cellulose | 5.5
Soybean meal (49% protein) | 5.0
Fish meal (60% protein) | 4.0
Corn oil (without preservatives) | 3.0
Soy oil (without preservatives) | 3.0
Dried brewer’s yeast | 1.0
Calcium carbonate (USP) | 0.9
Vitamin premix^a^ | 0.5
Mineral premix^b^ | 0.5
Calcium phosphate, dibasic (USP) | 0.4
Sodium chloride | 0.3
Choline chloride (70% choline) | 0.26
Methionine | 0.2

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table I-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 4,000 IU | Stabilized vitamin A palmitate or acetate
D | 1,000 IU | D-activated animal sterol
K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl acetate | 100 IU | –
Niacin | 23 mg | –
Folic acid | 1.1 mg | –
d-Pantothenic acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table I-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by weight) | 14.6 ± 0.55 | 13.7–15.9 | 25
Crude fat (% by weight) | 8.2 ± 0.25 | 7.7–8.6 | 25
Crude fiber (% by weight) | 9.3 ± 0.90 | 7.1–11.1 | 25
Ash (% by weight) | 5.1 ± 0.16 | 4.9–5.4 | 25
Amino Acids (% of total diet)
Arginine | 0.786 ± 0.070 | 0.67–0.97 | 23
Cystine | 0.220 ± 0.024 | 0.15–0.25 | 23
Glycine | 0.700 ± 0.040 | 0.62–0.80 | 23
Histidine | 0.351 ± 0.080 | 0.27–0.68 | 23
Isoleucine | 0.546 ± 0.043 | 0.43–0.66 | 23
Leucine | 1.095 ± 0.066 | 0.96–1.24 | 23
Lysine | 0.700 ± 0.116 | 0.31–0.86 | 23
Methionine | 0.409 ± 0.045 | 0.26–0.49 | 23
Phenylalanine | 0.628 ± 0.039 | 0.54–0.72 | 23
Threonine | 0.506 ± 0.042 | 0.43–0.61 | 23
Tryptophan | 0.150 ± 0.028 | 0.11–0.20 | 23
Tyrosine | 0.405 ± 0.063 | 0.28–0.54 | 23
Valine | 0.664 ± 0.042 | 0.55–0.73 | 23
Essential Fatty Acids (% of total diet)
Linoleic | 3.96 ± 0.254 | 3.49–4.55 | 23
Linolenic | 0.30 ± 0.031 | 0.21–0.35 | 23
Vitamins
Vitamin A (IU/kg) | 3,684 ± 94.6 | 2,110–5,720 | 25
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 80.3 ± 21.6 | 27.0–124.0 | 23
Thiamine (ppm)^b^ | 7.2 ± 1.26 | 5.1–11.0 | 25
Riboflavin (ppm) | 7.7 ± 2.87 | 4.20–17.50 | 23
Niacin (ppm) | 79.2 ± 8.97 | 66.4–98.2 | 23
Pantothenic acid (ppm) | 27 ± 12.35 | 17.4–81.0 | 23
Pyridoxine (ppm)^b^ | 9.54 ± 1.94 | 6.44–13.7 | 23
Folic acid (ppm) | 1.61 ± 0.47 | 1.15–3.27 | 23
Biotin (ppm) | 0.32 ± 0.10 | 0.20–0.704 | 23
Vitamin B_12_ (ppb) | 53.4 ± 38.7 | 18.3–174.0 | 23
Choline (ppm)^b^ | 2,773 ± 590 | 1,160–3,790 | 23
Minerals
Calcium (%) | 0.901 ± 0.038 | 0.81–0.97 | 25
Phosphorus (%) | 0.558 ± 0.061 | 0.49–0.82 | 25
Potassium (%) | 0.667 ± 0.030 | 0.626–0.733 | 23
Chloride (%) | 0.385 ± 0.038 | 0.300–0.474 | 23
Sodium (%) | 0.189 ± 0.016 | 0.160–0.222 | 23
Magnesium (%) | 0.216 ± 0.060 | 0.185–0.490 | 23
Sulfur (%) | 0.170 ± 0.030 | 0.116–0.209 | 14
Iron (ppm) | 186 ± 38.64 | 135–311 | 23
Manganese (ppm) | 51.02 ± 10.19 | 21.0–73.1 | 23
Zinc (ppm) | 53.61 ± 8.34 | 43.3–78.5 | 23
Copper (ppm) | 7.1 ± 2.540 | 3.21–16.3 | 23
Iodine (ppm) | 0.503 ± 0.201 | 0.158–0.972 | 23
Chromium (ppm) | 0.696 ± 0.270 | 0.330–1.380 | 23
Cobalt (ppm) | 0.248 ± 0.163 | 0.094–0.864 | 23

^a^ From formulation.

^b^ As hydrochloride (thiamine and pyridoxine) or chloride (choline).

Table I-4 Contaminant Levels in NTP-2000 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.24 ± 0.038 | 0.16–0.31 | 25
Cadmium (ppm) | 0.06 ± 0.009 | 0.05–0.10 | 25
Lead (ppm) | 0.12 ± 0.161 | 0.06–0.90 | 25
Mercury (ppm) | <0.02 | – | 25
Selenium (ppm) | 0.2 ± 0.46 | 0.14–0.34 | 25
Aflatoxins (ppb) | <5.00 | – | 25
Nitrate nitrogen (ppm)^c^ | 22.02 ± 8.46 | 10.0–42.3 | 25
Nitrite nitrogen (ppm)^c^ | <0.61 | – | 25
BHA (ppm)^d^ | <1.0 | – | 25
BHT (ppm)^d^ | <1.0 | – | 25
Aerobic plate count (CFU/g) | 10 ± 0 | 10 | 25
Coliform (MPN/g) | 3.0 ± 0 | 3.0 | 25
Escherichia coli (MPN/g) | <10 | – | 25
Salmonella (MPN/g) | Negative | – | 25
Total nitrosoamines (ppb)^e^ | 10 ± 4.49 | 2.0–17.2 | 25
N-Nitrosodimethylamine (ppb)^e^ | 2.8 ± 2.77 | 0.9–11.1 | 25
N-Nitrosopyrrolidine (ppb)^e^ | 7.8 ± 3.50 | 1.0–13.9 | 25
Pesticides (ppm)
α-BHC | <0.01 | – | 25
β-BHC | <0.02 | – | 25
γ-BHC | <0.01 | – | 25
δ-BHC | <0.01 | – | 25
Heptachlor | <0.01 | – | 25
Aldrin | <0.01 | – | 25
Heptachlor epoxide | <0.01 | – | 25
DDE | <0.01 | – | 25
DDD | <0.01 | – | 25
DDT | <0.01 | – | 25
HCB | <0.01 | – | 25
Mirex | <0.01 | – | 25
Methoxychlor | <0.05 | – | 25
Dieldrin | <0.01 | – | 25
Endrin | <0.01 | – | 25
Telodrin | <0.01 | – | 25
Chlordane | <0.05 | – | 25
Toxaphene | <0.10 | – | 25
Estimated PCBs | <0.20 | – | 25
Ronnel | <0.01 | – | 25
Ethion | <0.02 | – | 25
Trithion | <0.05 | – | 25
Diazinon | <0.10 | – | 25
Methyl chlorpyrifos | 0.131 ± 0.122 | 0.020–0.553 | 25
Methyl parathion | <0.02 | – | 25
Ethyl parathion | <0.02 | – | 25
Malathion | 0.10 ± 0.089 | 0.020–0.395 | 25
Endosulfan I | <0.01 | – | 25
Endosulfan II | <0.01 | – | 25
Endosulfan sulfate | <0.03 | – | 25

^a^ All samples were irradiated. CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride.

^b^ For values less than the limit of detection, the detection limit is given as the mean.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.