# Appendix H Chemical Characterization and Generation of Chamber Concentrations

## H.1 Procurement and Characterization of CIMSTAR 3800

CIMSTAR 3800 was obtained from Milacron (Cincinnati, OH) in three lots (60224BBN, 71205BN, and 90317JN). Lot 60224BBN was used during the 3-month studies, and lots 71205BN and 90317JN were used during the 2-year studies. Characterization and stability analyses of the test material were conducted by the analytical chemistry laboratory at Chemir Analytical Services (Maryland Heights, MO) and by the study laboratory at Battelle Toxicology Northwest (Richland, WA). Reports on analyses performed in support of the CIMSTAR 3800 studies are on file at the National Institute of Environmental Health Sciences.

Spectra of lots 60224BBN, 71205BN, and 90317JN of the test material, a yellow-orange liquid, were obtained by the analytical chemistry laboratory using Fourier transform infrared (FTIR) spectroscopy. FTIR spectroscopy was used to determine a fingerprint which was used to estimate the relative presence of various functional groups and create a reference for future comparison for the same lot or different lots. In general, the spectra were consistent with the presence of organic amines and spectra of the three lots were similar to each other; a representative FTIR spectrum is presented in Figure H-1.

Analyses for all lots performed by the analytical chemistry laboratory included Karl Fischer titration for water content; the determination of pH, specific gravity and refractive index; elemental analysis for carbon, hydrogen, nitrogen and sulfur using a C, H, N, S analyzer; elemental and metal analysis using inductively coupled plasma/optical emission spectrometry (ICP/OES); chloride, nitrate, and nitrite analysis by ion chromatography (IC); and iodide by ion specific electrode (ISE) titration (Fisher Accumet Research AR25 pH/mV/Ion Meter, Fisher Scientific, Pittsburgh, PA). The study laboratory determined the initial identification of general organic components using gas chromatography (GC) with flame ionization detection (FID) by system A and the identification of the major components using GC with mass spectrometry (MS) by system B (lot 60224BBN) (Table H-1). The identification and quantitation of alkanolamines were determined using high performance liquid chromatography (HPLC) with MS detection by systems A (lot 60224BBN) or B (lots 71205BN, and 90317JN) (Table H-2). The quantitation of methanol was determined using GC/FID by a system similar to system A (lot 60224BBN) or GC/MS by system C (lots 71205BN and 90317JN) (Table H-1). The assessment of fatty acid methyl esters was determined using GC/FID by system D. The total amount of hexane extractable material was determined using United States Environmental Protection Agency Method #1664^117^, and the amounts of bacteria and fungi were determined using a Sani-Check BF test kit (Biosan Laboratories, Warren, MI); samples were diluted to 10% with sterile water and applied to paddles coated on one side with media for the determination of bacteria and on the other side for the determination of fungi, then incubated for 7 days at 25° to 30°C.

I) For ICP/OES (Perkin-Elmer, Waltham, MA) analysis, samples were weighed into clean, acid-rinsed volumetric flasks, and analyzed. In ICP analysis, high frequency energy transferred by inductive coupling to a flow of inert gas containing the sample as an aerosol causes vaporization, exciting the free atoms to emit light; the intensity of this light is related to the concentration of the emitting atoms.

II) For IC analysis, chloride, nitrate, and nitrite were extracted from samples using ethyl ether at a high pH, excess base was neutralized with a strong cation exchanger type acid from Dowex DR-2-30, and analyzed using aqueous buffers to gradually elute ions of interest separated in an ion exchange column with conductivity detection (Dionex, Thermo Fisher Scientific, Inc., Waltham, MA).

For lot 60224BBN, the water content was 60%, pH was 9.1, specific gravity was 1.025 at 60°F, and refractive index was 1.400. Metal analysis by ICP/OES indicated boron at 0.8% with trace amounts of phosphorous, tin, and thallium; elemental analysis indicated 29.8% carbon, 10.5% hydrogen, 1.4% nitrogen, and 0.09% sulfur; IC results indicated that chloride, nitrate, and nitrite were less than 0.01%; and ISE titration indicated 26 ppm iodide. GC/FID analysis for alkanolamines indicated six separate peaks and a cluster of peaks. Using standard addition and GC/MS, the peaks were identified as methanol (0.3% by weight), ethanolamine, oxazolidine compound (tentative identification, no standard available), 1-amino-2-propanol, 5-methyloxazolidine (tentative identification, no standard available), triethanolamine, and the cluster of peaks as mineral oils (mostly fatty acid methyl esters and aliphatics). Quantitation of the major alkanolamimes using HPLC/MS indicated 4.7% ethanolamine, 1.8% 1-amino-2-propanol, and 3.4% triethanolamine by weight, representing approximately 10% of the test material mass. Quantitation of the mineral oils using GC/FID indicated 0.24% methyl palmitate, 0.71% methyl stearate, 2.6% methyl oleate, and 1.68% methyl linoleate. The total amount of hexane extractable materials was determined to be approximately 26% by weight. The amount of bacteria was less than 100 colony forming units (CFU)/mL and the amount of fungi was less than 10 CFU/mL.

For lot 71205BN, the water content was 60%, pH was 9.0, specific gravity was 1.025, and refractive index was 1.400. Metal analysis by ICP/OES indicated boron at 0.6% with trace amounts of calcium and tin; elemental analysis indicated 26.9% carbon, 10.0% hydrogen, 1.4% nitrogen, and 0.20% sulfur; IC results indicated that chloride, nitrate, and nitrite were less than 0.01%; and ISE titration indicated less than 5 ppm iodide. GC/FID analysis for alkanolamines indicated six peaks plus a cluster of peaks. GC/MS indicated 0.3% methanol by weight. Quantitation of the major alkanolamimes using HPLC/MS indicated 5.7% ethanolamine, 1.4% 1-amino-2-propanol, and 3.3% triethanolamine by weight, representing approximately 10% of the test material mass. Quantitation of the mineral oils using GC/FID indicated 0.21% methyl palmitate, 0.77% methyl stearate, 2.26% methyl oleate, and 1.54% methyl linoleate by weight. The total amount of hexane extractable materials was approximately 25% by weight. The amount of bacteria was less than 1,000 CFU/mL and the amount of fungi was less than 100 CFU/mL.

For lot 90317JN, the water content was 60%, pH was 9.0, specific gravity was 1.026, and refractive index was 1.408. ICP/OES indicated boron at 0.9%; elemental analysis indicated 28.4% carbon, 10.4% hydrogen, 2.3% nitrogen, and 0.10% sulfur; IC results indicated that chloride, nitrate, and nitrite were less than 0.01%; and ISE titration indicated less than 0.05% iodide. GC/MS indicated 0.35% methanol by weight. Quantitation of the major alkanolamimes using HPLC/MS indicated 5.4% ethanolamine, 1.6% 1-amino-2-propanol, and 3.2% triethanolamine, representing approximately 10% of the test material mass. Quantitation of the mineral oils using GC/FID indicated 0.20% methyl palmitate, 0.78% methyl stearate, 2.66% methyl oleate, and 1.77% methyl linoleate. The total amount of hexane extractable materials was approximately 26% by weight. The amount of bacteria was less than 1,000 CFU/mL and the amount of fungi was less than 100 CFU/mL.

The test material was determined to be primarily composed of water, alkanolamines, and oil. Boron was present at approximately 0.6%. The material was basic with a pH of approximately 9.0. In general, the FTIR spectra were consistent with the presence of organic amines, and contained less than 0.01% of water soluble nitrates, nitrites, or chlorides. The mass balance percentages based on elemental and compound contributions resulted in 96% and 96% (lot 60224BBN) and 92% and 96% (lot 71205BN) coverage, respectively. There were no significant differences between the three lots. Taken together, these data indicate that all three lots of the test material were CIMSTAR 3800 with the expected composition of organic amines (Table H-3).

Periodic reanalyses of lots 71205BN and 90317JN were performed by the analytical chemistry laboratory and the study laboratory at least every 6 months during the 2-year studies. For each lot, FTIR spectra were obtained and compared to reference spectra of the same lot and other lots; determinations were made for the pH, specific gravity, and refractive index; determination and quantitation of alkanolamines was performed using HPLC/MS by system B (Table H-2); assessment of mineral oils (fatty acid methyl esters) was performed using GC/FID by system D (Table H-1); and the amounts of bacteria and fungi were determined using a Sani-Check BF test kit. To ensure stability, the bulk test material was stored at approximately 63°F, protected from light, in metal drums, and no degradation of the bulk test material was detected.

## H.2 Aerosol Generation and Exposure System

The generation and delivery system used in the 3-month and 2-year studies consisted of two generator assemblies configured together so that the output from each assembly was directed to a common distribution line (Figure H-2). Each assembly contained up to three multi-jet nebulizers, of which two were operational and the third was a backup. The bottom of the generator assembly contained the liquid reservoir, the sides of which were surrounded by a band heater that was maintained at a temperature sufficient to keep the liquid test material at room temperature during the aerosolization process. CIMSTAR 3800 was continuously pumped to the liquid reservoir from the chemical cabinet reservoir by metering pumps during the aerosol generation process to ensure a fresh supply of test material and pumping rates that exceeded the rates at which aerosol was removed from the generator assemblies. A constant volume of test material was maintained in each assembly by a siphon tube inserted near the top of the assembly and connected to a vacuum source; excess liquid was removed to a waste container. Ports in the generator assembly introduced heated compressed air to drive the nebulizers and heated dilution air to transport aerosol to the distribution line.

Each nebulizer assembly consisted of a multi-jet thimble nebulizer, a liquid uptake tube, and a compressed air supply port. High velocity compressed air created a vacuum in the liquid uptake tube that drew test material from the liquid reservoir into the multi-jet nebulizer streams where shear force broke the resultant liquid filaments into droplets. Large droplets were impacted on the impaction plate of the nebulizer or the generator assembly walls and were returned to the liquid reservoir. Smaller droplets were drawn into the heated dilution air and transported to the common distribution line made of bonded stainless steel, grounded to prevent electrostatic charge buildup. The common distribution line was divided into two branches to supply aerosol to exposure chambers located on both sides of the exposure room; each branch line was insulated and terminated in a filter protecting the flowmeter controlling the line via the house vacuum supply. A second distribution line flow control system used during nonexposure periods consisted of a HEPA filter protecting the airvac pump that created a vacuum in the distribution lines that exceeded the pressures in the chambers, creating a minimal backflow from each chamber inlet tee ensuring that material did not migrate into the chambers during off exposure periods.

During exposures, at each chamber position, aerosol was removed from the distribution line and injected into a tee fitting where it was directed either to the inlet of the exposure chamber where it was mixed with conditioned air or to siphon flow exhaust. Conditioned air was defined as the mix of air derived from each exposure chamber’s wet and dry air duct supplies. The temperature of the resultant mixture of air was adjusted by passage over a temperature controlled radiator after treatment with Purafil, charcoal, and HEPA filters. Target dewpoint temperature of the wet duct was 60°F and 40°F for the dry duct. Air for the ducts was obtained from the building air supply and was either passed over chillers to lower the dewpoint (dry duct) or injected with steam to raise it (wet duct). The amount of aerosol removed from the distribution line was controlled by a control orifice and siphon flow rotameter. Minor adjustments to chamber concentrations were performed by changing the amount of aerosol drawn off through a HEPA-filter protected siphon flow rotameter.

## H.3 Aerosol Concentration Monitoring

Summaries of the chamber aerosol concentrations are given in Table H-4and Table H-5. The concentration of boron in CIMSTAR 3800 was monitored using real-time aerosol monitors (RAMs) (MicroDust pro, Casella CEL LTD; Kempson; Bedford, England). The monitors were connected to the chambers by a sampling system designed by Battelle incorporating a valve that multiplexed each RAM to a 0 mg/m^3^ chamber or the room, a HEPA-filtered room air blank, and two exposure chambers. The output voltage of the RAM was recorded by a program designed by Battelle (Battelle Exposure Data Acquisition and Control) to select the correct sample stream and acquire a raw voltage signal from each RAM. Equations for the calibration curves resided within the program and were used to convert the measured RAM voltages to exposure chamber concentrations. Concentration control limits within the program were compared to each measured concentration and, if limits were exceeded, an audible alarm was triggered or, in extreme cases, exposure was terminated.

Each RAM was calibrated by constructing a response curve using the measured RAM voltages (voltage readings were corrected by subtracting the RAM zero-offset voltage from measured RAM voltages) and boron in CIMSTAR 3800 concentrations that were determined by analyzing tandem Tissuquartz 2500QAT-UP or Tissuquartz 2500QAO-UP filters (Pall Corporation, East Hills, NY) collected daily from the exposure chambers.

For the 3-month studies and from April to July 24, 2008, in the 2-year studies, boron in CIMSTAR 3800 was extracted from the filters with approximately 0.25% cesium chloride and shaken on an orbital shaker table, filtered using an Acrodisc syringe filter with a polytetrafluoroethylene membrane, 25 mm, 0.45 µm (Pall Corporation), and analyzed on a Thermo Elemental IRIS Intrepid Inductively Coupled Plasma-Optical Emission Spectrometer (ICP/OES) (Thermo Elemental, Waltham, MA). The results were normalized against certified commercial standards of boron and yttrium as an internal standard obtained from the National Institute of Standards and Technology (NIST).

The ICP/OES instrument was calibrated against serially diluted 10 or 100 μg CIMSTAR 3800/mL containing a NIST-traceable spectrometric internal standard (2 mg yttrium/mL). Quality control standards and a reagent blank were analyzed after calibration, after approximately every tenth sample, and at the end of the analysis to determine accuracy and calibration drift during analysis.

After July 24, 2008, the calibration of the RAMs was based on gravimetric determination of the amount of test material on the filters to the end of the studies. Samples were acidified with hydrochloric acid, extracted three times with n-hexane, dried over sodium sulfate, solvent evaporated, desiccated, and weighed.

## H.4 Chamber Atmosphere Characterization

Particle size distribution in each chamber was determined prior to the start of all studies and monthly during the studies. Impactor samples were taken from each exposure chamber using a Mercer-style seven-stage impactor (In-Tox Products, Moriarty, NM) and the stages were initially collected on glass coverslips lightly coated with silicone to prevent particle bounce (stages 1-7) or filters (stage 8) and were analyzed by ICP/OES for boron in CIMSTAR 3800 for the 3-month studies and from April 2008 until July 23, 2008, for the 2-year studies. However, for the remainder of the 2-year studies, gravimetric samples were collected using stainless steel coverslips (stages 1-7) or glass fiber filters coated with Teflon^®^ (stage 8) and analyzed gravimetrically as described previously. The relative mass collected on each stage was analyzed by the CASPACT impactor analysis program developed at Battelle based on probit analysis^65^. The resulting estimates of the mass median aerodynamic diameter and the geometric standard deviation of each set of samples are given in Table H-6, Table H-7, and Table H-8. All samples were within the 1 to 3 µm range required by protocol.

Buildup and decay rates for chamber aerosol concentrations were determined with and without animals present in the chambers. At a chamber air flow rate of 15 cubic feet per minute, the theoretical values for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) was approximately 9.4 minutes for the 3-month and 2-year studies. For rat chambers in the 3-month studies, T_90_ values ranged from 9 to 11 minutes and T_10_ values ranged from 8 to 9 minutes without animals present; for rat/mouse chambers, T_90_ values ranged from 9 to 11 minutes and T_10_ values ranged from 7 to 8 minutes without animals present. For rats and mice in the 3-month studies, T_90_ values ranged from 13 to 17 minutes and T_10_ values ranged from 9 to 10 minutes with animals present.

For rats in the 2-year study, T_90_ values for males ranged from 6.0 to 13.8 minutes and T_10_ values ranged from 6.2 to 9.3 minutes with animals present; T_90_ values for females ranged from 8.3 to 15.9 and T_10_ values ranged from 8.1 to 9.2 minutes with animals present. For mice in the 2-year study, T_90_ values ranged from 8.3 to 15.9 minutes and T_10_ values ranged from 8.1 to 9.2 minutes with animals present. A summary for all exposure chambers with and without animals was made during the 2-year studies. T_90_ values for rats ranged from 6.3 to 15.2 minutes and T_10_ values ranged from 8.8 to 9.2 minutes. For rat/mouse chambers, T_90_ values ranged from 6.3 to 8.4 minutes and T_10_ values ranged from 8.2 to 8.4 minutes. T_90_ values of 18 minutes and 12 minutes were selected for the 3-month and 2-year studies, respectively.

The uniformity of aerosol concentration in the inhalation exposure chambers with animals present was measured once during the 3-month studies and was evaluated before the 2-year studies began without animals present and every 3 months during the 2-year studies. RAM measurements were taken from 12 different chamber positions. Chamber concentration uniformity was acceptable throughout the 3-month and 2-year studies.

The persistence of CIMSTAR 3800 in the exposure chambers was monitored after aerosol delivery ended by monitoring the concentration overnight in the 400 mg/m^3^ rat and mouse chambers during the 3-month studies and the 100 mg/m^3^ rat and mouse chambers during the 2-year studies with and without animals present. The average CIMSTAR 3800 concentration decreased to 1% of the target concentration within 18 (rats and mice, 3-month studies), 14 (male rats, 2-year studies), 16 (female rats and mice, 2-year studies), or 15 (2-year studies without animals) minutes.

Stability studies of the test material in the generation and exposure system were performed before and during the studies by the study laboratory and the analytical chemistry laboratory. Samples of the test atmosphere were taken in the first, middle, and last 2 hours of the generation day from the distribution line, 25 and 400 mg/m^3^ chambers (3-month studies), 10 and 100 mg/m^3^ chambers (2-year studies), and from the generator reservoir at the end of the generation day. Samples were collected using adsorbent gas sampling tubes (ORBO-52, silica gel, Supelco, Bellefonte, PA) for the determination of fatty acid methyl esters using GC/FID by system D (Table H-1). Samples collected on filters (Tissuquartz 2500QAT-UP) were analyzed using ICP/OES for boron, the filter was followed by a bubbler containing a cesium chloride solution. Samples collected using bubblers filled with water were analyzed for methanol using GC/MS by system C (3-month studies). Samples from the generator reservoir and samples collected in bubblers filled with 10 mM nonafluoropentanoic acid and 2% acetonitrile in water were used to analyze for alkanolamines using HPLC/MS by systems A (lot 60224BBN) or B (lots 71205BN and 90317JN) (Table H-2). In addition, samples from the generator reservoir were also analyzed for fatty acid methyl esters, boron, and alkanolamines. The amount of each constituent in the exposure atmosphere was calculated as a percentage of the expected amount based on concentration as determined by the on-line monitor. For the distribution line, the amount of each constituent was calculated as a percentage of the expected amount based on the gravimetric determination. Reservoir results were calculated relative to the test material.

For the 3-month and the 2-year stability studies without animals present in the exposure chambers, the relative amounts of the major constituents in the exposure atmosphere generally reflected that of the bulk test material. The concentrations of all constituents were higher in the liquid reservoirs at the end of the exposure day indicating the loss of water. Boron, triethanolamine, and fatty acid methyl esters were present primarily as particulates while ethanolamine and 1-amino-2-propanol had significant vapor phase contributions. The percentage of methanol in the liquid reservoirs was lower than that in the bulk test material.

Approximately 4 months into the 2-year studies, exposure chamber analyses with animals present indicated a shift in the relative amounts of several of the constituents relative to boron. Characterization of the test material was performed and compared with the results obtained prior to the study; all results were consistent, indicating that the test material was stable. Sampling and test methods used were the same as those used for previous stability testing with one exception, HPLC/MS by system C used earlier was slightly changed to improve the resolution of alkanolamines (system D). Additional samples were taken from the inlet and exhaust and from the top and bottom of the 10, 30, and 100 mg/m^3^ rat/mouse chambers with animals present. The results of the investigation proved that boron was not a good marker for the determination of CIMSTAR 3800 concentrations. The decision was made to calibrate the RAMs using CIMSTAR 3800 concentrations based on gravimetric determinations for the remainder of the 2-year studies.

Samples were collected, prepared, and analyzed gravimetrically. Instruments were calibrated for each method using gravimetrically prepared dilutions of the bulk test material. Results for each constituent were calculated relative to the concentration determined using the on-line monitor. For the distribution line, the amount of each constituent was calculated as a percentage of the expected amount based on the gravimetric determination. For the generator reservoir samples, results were calculated relative to the bulk test material. Constituents were within approximately 30% of the on-line monitor results in the distribution line and were comparable to the results observed during prestart assays. Triethanolamine concentrations were 95% to 107% of the on-line monitor results in the chamber atmosphere samples; fatty acid methyl ester concentrations were within 35% in the 10 mg/m^3^ chambers and 20% in the 100 mg/m^3^ chambers. The relative proportions for boron and the volatile alkanolamines were reduced in the 100 mg/m^3^ chambers and the reductions were greater in the rat/mouse chambers than in the male rat chambers. The greatest degree of reduction was seen in the 10 mg/m^3^ rat/mouse chambers where boron was 34%, ethanolamine was 16%, and 1-amino-2-propanol was 30% of the expected.

Methanol concentrations were increased in the reservoirs as well as the distribution line and exposure chambers. However, other volatile constituents (ethanolamine and 1-amino-2-propanol) were comparable in the reservoirs as well as the distribution line compared to prestart measurements while decreasing in the exposure chamber atmosphere with decreasing exposure concentrations, most significantly in the 10 mg/m^3^ exposure chambers.

The concentrations of all constituents were 94% to 108% relative to the bulk test material in the chemical cabinet reservoir at the end of the exposure day. Concentrations of these constituents were 117% to 150% higher in the liquid reservoirs indicating the loss of water, comparable to prestart measurements.

Table H-1 Gas Chromatography Systems Used in the Inhalation Studies of CIMSTAR 3800^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | RTX^®^-5, 30 m × 0.32 mm, 1.0 µm film (Restek, Bellefonte, PA) | Helium at 10 psi | 45°C for 1 minute, then 6°C/minute to 300°C, held for 5 minutes
System B
Mass spectrometry | RTX^®^-5, 30 m × 0.25 mm, 1.0 µm film (Restek) | Helium at 8 psi | 45°C for 1 minute, then 6°C/minute to 300°C, held for 10 minutes
System C
Mass spectrometry | DB™-WAX, 30 m × 0.25 mm, 0.5 µm film (J&W Scientific, Folsom, CA) | Helium at 1.2 mL/minute | 45°C for 1 minute, then 6°C/minute to 65°C, then 15°C/minute to 130°C, held for 1 minute
System D
Flame ionization | SP2380, 30 m × 0.32 mm, 0.2 µm film (Supelco, Bellefonte, PA) | Helium at 10 psi | 40°C for 2 minutes, then 15°C/minute to 170°C, held for 7 minutes, then 10°C/minute to 270°C, held for 10 minutes

^a^ The gas chromatographs and mass spectrometers were manufactured by Agilent Technologies, Inc. (Palo Alto, CA).

Table H-2 High-Performance Liquid Chromatography Systems Used in the Inhalation Studies of CIMSTAR 3800^a^

Detection System | Column | Solvent System
System A
Ultraviolet light coupled with mass spectrometry | Agilent 1100, Dionex IonPac NS1, 250 mm × 4 mm (Agilent Technologies, Inc., Palo Alto, CA) | A) 10 mM nonafluoropentanoic acid/2% acetonitrile in water and B) 10 mM nonafluoropentanoic acid in acetonitrile; linear gradient from 100% A to 80% A:20% B in 10 minutes, then to 100% A in 2 minutes, held for 3 minutes; flow rate 1.0 mL/minute
System B
Ultraviolet light coupled with mass spectrometry | Agilent 1200, Dionex IonPac NS1, 250 mm × 4 mm (Agilent Technologies, Inc.) | Isocratic 75% 0.1% formic acid/2% acetonitrile in water and 25% 0.1% formic acid in acetonitrile; flow rate 0.5 mL/minute
System C
Ultraviolet light coupled with mass spectrometry | Waters Nova-Pak C18 250 mm × 4 mm, 4 μm (Waters Corporation, Milford, MA) | Isocratic 0.1% formic acid/2% acetonitrile in water; flow rate 0.5 mL/minute
System D
Ultraviolet light coupled with mass spectrometry | Waters Nova-Pak C18 60 Å 300 mm × 3.9 mm, 4 μm (Waters Corporation) | Isocratic 0.1% formic acid/2% acetonitrile in water; flow rate 0.5 mL/minute

^a^ The high-performance liquid chromatographs were manufactured by Agilent Technologies, Inc. (Palo Alto, CA). The mass spectrometers were manufactured by Agilent Technologies (systems A and B) or Fisher Scientific, Inc. (Waltham, PA, systems C and D).

Table H-3 Specific Components of the Three Lots of CIMSTAR 3800 Used in the Inhalation Studies of CIMSTAR 3800^a^

Component | Lot 60224BBN^b^ | Lot 71205BN^c^ | Lot 90317JN^c^
Water | 60.0 | 60.0 | 60.0
Methanol | 0.30 | 0.30 | 0.35
Ethanolamine | 4.7 | 5.7 | 5.6
Triethanolamine | 3.4 | 3.3 | 3.2
1-Amino-2-propanol | 1.8 | 1.4 | 1.6
Methyl palmitate | 0.24 | 0.21 | 0.20
Methyl stearate | 0.71 | 0.77 | 0.78
Methyl oleate | 2.60 | 2.26 | 2.66
Methyl linoleate | 1.68 | 1.54 | 1.77
Hexane extractable material | 26.0 | 25.0 | 26.0
Total | 101.43 | 100.48 | 102.16

^a^ All values are percentages.

^b^ Used in the 3-month studies.

^c^ Used in the 2-year studies.

Table H-4 Summary of Chamber Concentrations in the Three-month Inhalation Studies of CIMSTAR 3800

| Target Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Rat Chambers
| 25 | 728 | 24.9 ± 1.5
| 50 | 713 | 49.8 ± 2.6
| 100 | 727 | 102 ± 4
| 200 | 715 | 198 ± 8
| 400 | 728 | 400 ± 16
Mouse Chambers
| 25 | 752 | 24.9 ± 1.5
| 50 | 736 | 49.7 ± 2.6
| 100 | 751 | 102 ± 4
| 200 | 738 | 197 ± 8
| 400 | 752 | 400 ± 16

^a^ Mean ± standard deviation.

Table H-5 Summary of Chamber Concentrations in the Two-year Inhalation Studies of CIMSTAR 3800

| Target Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Male Rat Chambers
| 10 | 5,328 | 10.1 ± 0.5
| 30 | 5,327 | 29.5 ± 1.3
| 100 | 5,380 | 99.8 ± 3.9
Female Rat Chambers
| 10 | 5,401 | 9.9 ± 0.5
| 30 | 5,400 | 29.6 ± 1.2
| 100 | 5,346 | 99.1 ± 4.2
Mouse Chambers
| 10 | 5,400 | 9.9 ± 0.5
| 30 | 5,399 | 29.7 ± 1.2
| 100 | 5,347 | 99.2 ± 4.2

^a^ Mean ± standard deviation.

Table H-6 Summary of Aerosol Size Measurements for the Rat and Mouse Exposure Chambers in the Three-month Inhalation Studies of CIMSTAR 3800

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
June 2006 | 25 | 1.6 | 2.2
| 50 | 1.7 | 2.1
| 100 | 1.7 | 2.0
| 200 | 1.8 | 2.0
| 400 | 1.6 | 2.0
July 2006 | 25 | 1.6 | 2.2
| 50 | 1.6 | 2.0
| 100 | 1.6 | 2.0
| 200 | 1.7 | 1.9
| 400 | 1.7 | 1.8
August 2006 | 25 | 1.6 | 1.9
| 50 | 1.6 | 2.0
| 100 | 1.6 | 1.9
| 200 | 1.7 | 1.8
| 400 | 1.7 | 1.9

Table H-7 Summary of Aerosol Size Measurements for the Rat Exposure Chambers in the Two-year Inhalation Study of CIMSTAR 3800

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
Male
April 2008 | 10 | 1.8 | 2.4
| 30 | 1.7 | 2.9
| 100 | 1.6 | 2.5
May 2008 | 10 | 1.7 | 2.5
| 30 | 1.7 | 2.3
| 100 | 1.6 | 2.2
June 2008 | 10 | 1.6 | 2.7
| 30 | 1.7 | 2.2
| 100 | 1.6 | 2.2
July 2008 | 10 | 1.6 | 2.7
| 30 | 1.6 | 2.2
| 100 | 1.6 | 2.1
August 2008 | 10 | 1.3 | 2.9
| 30 | 1.6 | 1.9
| 100 | 1.6 | 2.1
September 2008 | 10 | 1.3 | 2.3
| 30 | 1.3 | 2.6
| 100 | 1.5 | 2.2
October 2008 | 10 | 1.7 | 2.8
| 30 | 1.6 | 2.6
| 100 | 1.3 | 2.4
November 2008 | 10 | 1.3 | 2.5
| 30 | 1.6 | 2.3
| 100 | 1.5 | 2.4
December 2008 | 10 | 1.6 | 2.4
| 30 | 1.4 | 2.4
| 100 | 1.5 | 2.4
January 2009 | 10 | 1.3 | 2.4
| 30 | 1.4 | 2.4
| 100 | 1.6 | 2.2
February 2009 | 10 | 1.3 | 2.6
| 30 | 1.3 | 2.6
| 100 | 1.2 | 2.6
March 2009 | 10 | 1.4 | 2.7
| 30 | 1.4 | 2.3
| 100 | 1.6 | 2.3
April 2009 | 10 | 1.5 | 2.4
| 30 | 1.6 | 2.2
| 100 | 1.9 | 2.4
May 2009 | 10 | 1.5 | 2.1
| 30 | 1.6 | 2.0
| 100 | 1.6 | 2.1
June 2009 | 10 | 1.7 | 1.7
| 30 | 1.6 | 1.8
| 100 | 1.7 | 1.7
July 2009 | 10 | 1.4 | 2.2
| 30 | 1.5 | 2.2
| 100 | 1.5 | 2.4
August 2009 | 10 | 1.4 | 2.5
| 30 | 1.6 | 2.2
| 100 | 1.6 | 2.4
September 2009 | 10 | 1.3 | 2.7
| 30 | 1.3 | 2.7
| 100 | 1.8 | 2.0
October 2009 | 10 | 1.6 | 2.4
| 30 | 1.5 | 2.5
| 100 | 1.5 | 2.2
November 2009 | 10 | 1.6 | 2.2
| 30 | 1.9 | 2.6
| 100 | 1.5 | 2.6
December 2009 | 10 | 1.6 | 2.3
| 30 | 1.7 | 2.2
| 100 | 1.7 | 2.2
January 2010 | 10 | 1.5 | 2.4
| 30 | 1.8 | 2.5
| 100 | 1.7 | 2.3
February 2010 | 10 | 1.5 | 2.4
| 30 | 1.6 | 2.3
| 100 | 1.5 | 2.4
March 2010 | 10 | 1.4 | 2.7
| 30 | 1.7 | 2.3
| 100 | 1.7 | 2.5
April 2010 | 10 | 1.6 | 2.3
| 30 | 1.5 | 2.3
| 100 | 1.7 | 2.3
Range | 10 | 1.3–1.8 | 1.7–2.9
| 30 | 1.3–1.9 | 1.8–2.9
| 100 | 1.2–1.9 | 1.7–2.6
Female
April 2008 | 10 | 1.8 | 2.5
| 30 | 1.4 | 2.6
| 100 | 1.6 | 2.3
May 2008 | 10 | 1.6 | 2.5
| 30 | 1.5 | 2.6
| 100 | 1.5 | 2.4
June 2008 | 10 | 1.6 | 2.7
| 30 | 1.6 | 2.3
| 100 | 1.6 | 2.3
July 2008 | 10 | 1.6 | 2.4
| 30 | 1.5 | 2.3
| 100 | 1.6 | 2.1
August 2008 | 10 | 1.7 | 2.6
| 30 | 1.6 | 2.0
| 100 | 1.6 | 2.1
September 2008 | 10 | 1.4 | 2.2
| 30 | 1.3 | 2.3
| 100 | 1.5 | 2.2
October 2008 | 10 | 1.4 | 2.4
| 30 | 1.4 | 2.2
| 100 | 1.3 | 2.2
November 2008 | 10 | 1.4 | 2.4
| 30 | 1.5 | 2.2
| 100 | 1.6 | 2.2
December 2008 | 10 | 1.2 | 2.7
| 30 | 1.9 | 2.7
| 100 | 1.3 | 2.6
January 2009 | 10 | 1.2 | 2.2
| 30 | 1.4 | 2.1
| 100 | 1.5 | 2.1
February 2009 | 10 | 1.4 | 2.5
| 30 | 1.3 | 2.4
| 100 | 1.1 | 2.3
March 2009 | 10 | 1.3 | 2.4
| 30 | 1.4 | 2.3
| 100 | 1.6 | 2.2
April 2009 | 10 | 1.5 | 2.3
| 30 | 1.5 | 2.2
| 100 | 1.4 | 2.4
May 2009 | 10 | 1.4 | 2.1
| 30 | 1.5 | 2.0
| 100 | 1.5 | 2.2
June 2009 | 10 | 1.4 | 2.1
| 30 | 1.5 | 2.0
| 100 | 1.6 | 1.6
July 2009 | 10 | 1.5 | 2.2
| 30 | 1.6 | 1.9
| 100 | 1.5 | 2.2
August 2009 | 10 | 1.5 | 2.1
| 30 | 1.5 | 2.1
| 100 | 1.4 | 2.3
September 2009 | 10 | 1.5 | 2.4
| 30 | 1.4 | 2.4
| 100 | 1.6 | 2.2
October 2009 | 10 | 1.3 | 2.7
| 30 | 1.5 | 2.4
| 100 | 1.4 | 2.7
November 2009 | 10 | 1.4 | 2.4
| 30 | 1.4 | 2.8
| 100 | 2.0 | 2.5
December 2009 | 10 | 1.4 | 2.3
| 30 | 1.6 | 2.1
| 100 | 1.7 | 2.1
January 2010 | 10 | 1.4 | 2.4
| 30 | 1.5 | 2.3
| 100 | 1.6 | 2.3
February 2010 | 10 | 1.5 | 2.4
| 30 | 1.4 | 2.9
| 100 | 1.6 | 2.6
March 2010 | 10 | 1.3 | 2.7
| 30 | 1.5 | 2.5
| 100 | 1.6 | 2.4
April 2010 | 10 | 1.6 | 2.2
| 30 | 1.5 | 2.2
| 100 | 1.6 | 2.3
Range | 10 | 1.2–1.8 | 2.1–2.7
| 30 | 1.3–1.9 | 1.9–2.9
| 100 | 1.1–2.0 | 1.6–2.7

Table H-8 Summary of Aerosol Size Measurements for the Mouse Exposure Chambers in the Two-year Inhalation Study of CIMSTAR 3800

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
Female
April 2008 | 10 | 1.8 | 2.5
| 30 | 1.4 | 2.6
| 100 | 1.6 | 2.3
May 2008 | 10 | 1.6 | 2.5
| 30 | 1.5 | 2.6
| 100 | 1.5 | 2.4
June 2008 | 10 | 1.6 | 2.7
| 30 | 1.6 | 2.3
| 100 | 1.6 | 2.3
July 2008 | 10 | 1.6 | 2.4
| 30 | 1.5 | 2.3
| 100 | 1.6 | 2.1
August 2008 | 10 | 1.7 | 2.6
| 30 | 1.6 | 2.0
| 100 | 1.6 | 2.1
September 2008 | 10 | 1.4 | 2.2
| 30 | 1.3 | 2.3
| 100 | 1.5 | 2.2
October 2008 | 10 | 1.4 | 2.4
| 30 | 1.4 | 2.2
| 100 | 1.3 | 2.2
November 2008 | 10 | 1.4 | 2.4
| 30 | 1.5 | 2.2
| 100 | 1.6 | 2.2
December 2008 | 10 | 1.2 | 2.7
| 30 | 1.9 | 2.7
| 100 | 1.3 | 2.6
January 2009 | 10 | 1.2 | 2.2
| 30 | 1.4 | 2.1
| 100 | 1.5 | 2.1
February 2009 | 10 | 1.4 | 2.5
| 30 | 1.3 | 2.4
| 100 | 1.1 | 2.3
March 2009 | 10 | 1.3 | 2.4
| 30 | 1.4 | 2.3
| 100 | 1.6 | 2.2
April 2009 | 10 | 1.5 | 2.3
| 30 | 1.5 | 2.2
| 100 | 1.4 | 2.4
May 2009 | 10 | 1.4 | 2.1
| 30 | 1.5 | 2.0
| 100 | 1.5 | 2.2
June 2009 | 10 | 1.4 | 2.1
| 30 | 1.5 | 2.0
| 100 | 1.6 | 1.6
July 2009 | 10 | 1.5 | 2.2
| 30 | 1.6 | 1.9
| 100 | 1.5 | 2.2
August 2009 | 10 | 1.5 | 2.1
| 30 | 1.5 | 2.1
| 100 | 1.4 | 2.3
September 2009 | 10 | 1.5 | 2.4
| 30 | 1.4 | 2.4
| 100 | 1.6 | 2.2
October 2009 | 10 | 1.3 | 2.7
| 30 | 1.5 | 2.4
| 100 | 1.4 | 2.7
November 2009 | 10 | 1.4 | 2.4
| 30 | 1.4 | 2.8
| 100 | 2.0 | 2.5
December 2009 | 10 | 1.4 | 2.3
| 30 | 1.6 | 2.1
| 100 | 1.7 | 2.1
January 2010 | 10 | 1.4 | 2.4
| 30 | 1.5 | 2.3
| 100 | 1.6 | 2.3
February 2010 | 10 | 1.5 | 2.4
| 30 | 1.4 | 2.9
| 100 | 1.6 | 2.6
March 2010 | 10 | 1.3 | 2.7
| 30 | 1.5 | 2.5
| 100 | 1.6 | 2.4
April 2010 | 10 | 1.6 | 2.2
| 30 | 1.5 | 2.2
| 100 | 1.6 | 2.3
May 2010 | 10 | 1.6 | 2.3
| 30 | 1.7 | 2.2
| 100 | 1.8 | 2.2
Range | 10 | 1.2–1.8 | 2.1–2.7
| 30 | 1.3–1.9 | 1.9–2.9
| 100 | 1.1–2.0 | 1.6–2.7

Figure H-1

Fourier Transform Infrared Absorption Spectrum of CIMSTAR 3800

Figure H-2

Schematic of the Aerosol Generation and Delivery System in the Three-month and Two-year Inhalation Studies of CIMSTAR 3800