# Appendix G Organ Weights and Organ-Weight-To-Body-Weight Ratios

Table G-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/NTac Rats in the Three-month Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 349 ± 6 | 353 ± 9 | 354 ± 7 | 354 ± 7 | 352 ± 5 | 350 ± 6
Heart
Absolute | 0.99 ± 0.02 | 0.98 ± 0.03 | 1.00 ± 0.02 | 0.99 ± 0.02 | 0.97 ± 0.01 | 0.98 ± 0.02
Relative | 2.83 ± 0.03 | 2.78 ± 0.03 | 2.81 ± 0.03 | 2.80 ± 0.02 | 2.76 ± 0.03 | 2.81 ± 0.02
R. Kidney
Absolute | 1.07 ± 0.02 | 1.09 ± 0.03 | 1.09 ± 0.03 | 1.13 ± 0.03 | 1.07 ± 0.01 | 1.10 ± 0.03
Relative | 3.07 ± 0.03 | 3.09 ± 0.04 | 3.08 ± 0.04 | 3.18 ± 0.05 | 3.04 ± 0.03 | 3.14 ± 0.04
Liver
Absolute | 11.55 ± 0.31 | 11.54 ± 0.39 | 11.71 ± 0.33 | 12.23 ± 0.40 | 11.68 ± 0.20 | 11.82 ± 0.29
Relative | 33.08 ± 0.41 | 32.61 ± 0.39 | 32.99 ± 0.41 | 34.44 ± 0.57 | 33.21 ± 0.24 | 33.73 ± 0.51
Lung
Absolute | 1.89 ± 0.06 | 1.93 ± 0.08 | 2.06 ± 0.09 | 1.95 ± 0.08 | 1.87 ± 0.04 | 1.94 ± 0.05
Relative | 5.42 ± 0.19 | 5.46 ± 0.16 | 5.79 ± 0.20 | 5.49 ± 0.15 | 5.32 ± 0.08 | 5.53 ± 0.10
Spleen
Absolute | 0.641 ± 0.012 | 0.670 ± 0.018 | 0.658 ± 0.012 | 0.690 ± 0.015 | 0.652 ± 0.012 | 0.672 ± 0.017
Relative | 1.84 ± 0.03 | 1.90 ± 0.02 | 1.86 ± 0.01 | 1.95 ± 0.03* | 1.85 ± 0.02 | 1.92 ± 0.03
R. Testis
Absolute | 1.414 ± 0.023 | 1.444 ± 0.027 | 1.440 ± 0.021 | 1.424 ± 0.026 | 1.417 ± 0.017 | 1.411 ± 0.024
Relative | 4.059 ± 0.061 | 4.103 ± 0.095 | 4.070 ± 0.069 | 4.023 ± 0.061 | 4.035 ± 0.058 | 4.030 ± 0.048
Thymus
Absolute | 0.327 ± 0.006 | 0.337 ± 0.015 | 0.349 ± 0.011 | 0.325 ± 0.015 | 0.347 ± 0.016 | 0.341 ± 0.014
Relative | 0.938 ± 0.016 | 0.954 ± 0.039 | 0.985 ± 0.026 | 0.918 ± 0.037 | 0.989 ± 0.047 | 0.974 ± 0.039
Female
Necropsy body wt | 188 ± 5 | 190 ± 5 | 195 ± 5 | 189 ± 5 | 185 ± 5 | 184 ± 4
Heart
Absolute | 0.62 ± 0.02 | 0.62 ± 0.02 | 0.64 ± 0.01 | 0.62 ± 0.02 | 0.61 ± 0.01 | 0.61 ± 0.01
Relative | 3.28 ± 0.05 | 3.26 ± 0.04 | 3.29 ± 0.05 | 3.30 ± 0.05 | 3.32 ± 0.05 | 3.34 ± 0.05
R. Kidney
Absolute | 0.61 ± 0.02 | 0.63 ± 0.02 | 0.65 ± 0.01 | 0.62 ± 0.02 | 0.62 ± 0.01 | 0.62 ± 0.02
Relative | 3.25 ± 0.07 | 3.33 ± 0.05 | 3.33 ± 0.06 | 3.29 ± 0.06 | 3.34 ± 0.07 | 3.35 ± 0.04
Liver
Absolute | 6.03 ± 0.10 | 5.97 ± 0.20 | 6.25 ± 0.14 | 5.98 ± 0.19 | 6.13 ± 0.20 | 6.03 ± 0.16
Relative | 32.20 ± 0.72 | 31.39 ± 0.41 | 32.11 ± 0.64 | 31.63 ± 0.65 | 33.11 ± 0.41 | 32.81 ± 0.71
Lung
Absolute | 1.21 ± 0.05 | 1.23 ± 0.05 | 1.26 ± 0.04 | 1.21 ± 0.04 | 1.16 ± 0.04 | 1.18 ± 0.03
Relative | 6.39 ± 0.11 | 6.47 ± 0.14 | 6.49 ± 0.16 | 6.41 ± 0.09 | 6.24 ± 0.09 | 6.41 ± 0.09
Spleen
Absolute | 0.424 ± 0.010 | 0.453 ± 0.021 | 0.445 ± 0.012 | 0.431 ± 0.010 | 0.451 ± 0.009 | 0.450 ± 0.010
Relative | 2.27 ± 0.07 | 2.38 ± 0.06 | 2.29 ± 0.06 | 2.28 ± 0.02 | 2.45 ± 0.05 | 2.45 ± 0.06
Thymus
Absolute | 0.238 ± 0.009 | 0.246 ± 0.007 | 0.280 ± 0.015* | 0.256 ± 0.010 | 0.248 ± 0.008 | 0.250 ± 0.009
Relative | 1.268 ± 0.048 | 1.300 ± 0.040 | 1.430 ± 0.058 | 1.357 ± 0.044 | 1.347 ± 0.047 | 1.360 ± 0.031

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 39.5 ± 0.9 | 38.1 ± 1.3 | 38.6 ± 0.7 | 37.4 ± 0.6 | 37.8 ± 0.6 | 32.9 ± 0.9**
Heart
Absolute | 0.17 ± 0.01 | 0.18 ± 0.00 | 0.17 ± 0.01 | 0.17 ± 0.01 | 0.17 ± 0.01 | 0.16 ± 0.01
Relative | 4.29 ± 0.11 | 4.73 ± 0.16 | 4.33 ± 0.18 | 4.62 ± 0.20 | 4.48 ± 0.17 | 4.86 ± 0.14
R. Kidney
Absolute | 0.32 ± 0.01 | 0.34 ± 0.00 | 0.32 ± 0.01 | 0.33 ± 0.01 | 0.31 ± 0.01 | 0.30 ± 0.01
Relative | 8.21 ± 0.16 | 8.88 ± 0.31 | 8.44 ± 0.31 | 8.84 ± 0.22 | 8.19 ± 0.24 | 9.05 ± 0.20
Liver
Absolute | 1.70 ± 0.06 | 1.69 ± 0.05 | 1.61 ± 0.04 | 1.67 ± 0.06 | 1.59 ± 0.05 | 1.52 ± 0.07*
Relative | 43.08 ± 0.95 | 44.55 ± 1.03 | 41.67 ± 0.58 | 44.69 ± 1.38 | 42.11 ± 1.15 | 46.22 ± 1.54
Lung
Absolute | 0.21 ± 0.01 | 0.24 ± 0.02 | 0.22 ± 0.01 | 0.23 ± 0.01* | 0.24 ± 0.01* | 0.23 ± 0.01*
Relative | 5.23 ± 0.14 | 6.28 ± 0.47 | 5.62 ± 0.10 | 6.28 ± 0.21** | 6.27 ± 0.16** | 7.04 ± 0.21**
Spleen
Absolute | 0.077 ± 0.003 | 0.086 ± 0.007 | 0.074 ± 0.002 | 0.075 ± 0.002 | 0.072 ± 0.003 | 0.065 ± 0.002*
Relative | 1.95 ± 0.05 | 2.28 ± 0.21 | 1.92 ± 0.05 | 2.02 ± 0.08 | 1.92 ± 0.10 | 1.97 ± 0.05
R. Testis
Absolute | 0.115 ± 0.001 | 0.112 ± 0.002 | 0.108 ± 0.009 | 0.112 ± 0.003 | 0.114 ± 0.002 | 0.110 ± 0.003
Relative | 2.921 ± 0.050 | 2.958 ± 0.089 | 2.808 ± 0.248 | 3.001 ± 0.056 | 3.010 ± 0.061 | 3.360 ± 0.076*
Thymus
Absolute | 0.054 ± 0.002 | 0.047 ± 0.002 | 0.051 ± 0.003 | 0.044 ± 0.002 | 0.052 ± 0.002 | 0.039 ± 0.003**
Relative | 1.362 ± 0.049 | 1.241 ± 0.051 | 1.316 ± 0.068 | 1.185 ± 0.059 | 1.378 ± 0.064 | 1.169 ± 0.073
Female
Necropsy body wt | 33.0 ± 1.2 | 31.6 ± 0.7 | 31.8 ± 0.8 | 31.9 ± 0.7 | 30.5 ± 0.8* | 28.1 ± 0.5**
Heart
Absolute | 0.14 ± 0.00 | 0.15 ± 0.00 | 0.15 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00
Relative | 4.38 ± 0.18 | 4.67 ± 0.14 | 4.71 ± 0.14 | 4.46 ± 0.13 | 4.54 ± 0.12 | 4.84 ± 0.08
R. Kidney
Absolute | 0.21 ± 0.01 | 0.20 ± 0.01 | 0.21 ± 0.01 | 0.21 ± 0.00 | 0.21 ± 0.01 | 0.20 ± 0.01
Relative | 6.45 ± 0.21 | 6.32 ± 0.25 | 6.56 ± 0.23 | 6.50 ± 0.12 | 6.83 ± 0.19 | 7.15 ± 0.23
Liver
Absolute | 1.43 ± 0.05 | 1.38 ± 0.04 | 1.46 ± 0.05 | 1.39 ± 0.04 | 1.37 ± 0.04 | 1.29 ± 0.04
Relative | 43.26 ± 0.74 | 43.84 ± 0.83 | 45.82 ± 1.12 | 43.51 ± 1.00 | 44.99 ± 0.87 | 45.80 ± 1.00
Lung
Absolute | 0.21 ± 0.01 | 0.23 ± 0.01 | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.23 ± 0.01 | 0.23 ± 0.00
Relative | 6.46 ± 0.18 | 7.36 ± 0.50 | 6.83 ± 0.18 | 6.88 ± 0.16 | 7.59 ± 0.24** | 8.26 ± 0.15**
Spleen
Absolute | 0.097 ± 0.003 | 0.095 ± 0.002 | 0.101 ± 0.004 | 0.091 ± 0.003 | 0.094 ± 0.004 | 0.082 ± 0.004**
Relative | 2.97 ± 0.13 | 3.02 ± 0.09 | 3.18 ± 0.11 | 2.85 ± 0.06 | 3.09 ± 0.12 | 2.91 ± 0.12
Thymus
Absolute | 0.050 ± 0.004 | 0.053 ± 0.003 | 0.051 ± 0.002 | 0.053 ± 0.003 | 0.050 ± 0.002 | 0.043 ± 0.003
Relative | 1.514 ± 0.094 | 1.689 ± 0.101 | 1.622 ± 0.068 | 1.672 ± 0.076 | 1.653 ± 0.060 | 1.523 ± 0.096

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).