# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for F344/NTac Rats in the Three-month Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Hematology
Hematocrit (%) | 48.2 ± 0.2 | 47.3 ± 0.3 | 47.6 ± 0.4 | 47.4 ± 0.3 | 47.5 ± 0.3 | 48.1 ± 0.4
Packed cell volume (%) | 46.7 ± 0.3 | 45.7 ± 0.4 | 46.3 ± 0.5 | 46.0 ± 0.4 | 45.9 ± 0.3 | 46.7 ± 0.3
Hemoglobin (g/dL) | 15.3 ± 0.1 | 15.0 ± 0.1 | 15.1 ± 0.1 | 15.1 ± 0.1 | 15.1 ± 0.1 | 15.2 ± 0.1
Erythrocytes (10^6^/μL) | 9.49 ± 0.08 | 9.29 ± 0.04 | 9.38 ± 0.10 | 9.34 ± 0.09 | 9.34 ± 0.05 | 9.40 ± 0.06
Reticulocytes (10^3^/μL) | 248 ± 9 | 291 ± 7* | 259 ± 11 | 242 ± 12 | 258 ± 7 | 258 ± 11
Nucleated erythrocytes (10^3^/μL) | 7.96 ± 0.30 | 7.48 ± 0.34 | 8.53 ± 0.43 | 8.01 ± 0.39 | 8.05 ± 0.19 | 8.75 ± 0.23
Nucleated erythrocytes/100 leukocytes | 0.0 ± 0.0 | 0.2 ± 0.1 | 0.1 ± 0.1 | 0.1 ± 0.1 | 0.3 ± 0.2 | 0.0 ± 0.0
Mean cell volume (fL) | 49.2 ± 0.3 | 49.3 ± 0.3 | 49.3 ± 0.2 | 49.3 ± 0.2 | 49.2 ± 0.2 | 49.7 ± 0.3
Mean cell hemoglobin (pg) | 16.1 ± 0.1 | 16.2 ± 0.1 | 16.1 ± 0.1 | 16.2 ± 0.1 | 16.2 ± 0.0 | 16.1 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.8 ± 0.1 | 32.8 ± 0.1 | 32.6 ± 0.1 | 32.8 ± 0.1 | 32.8 ± 0.1 | 32.5 ± 0.1
Platelets (10^3^/μL) | 766 ± 11 | 745 ± 25 | 749 ± 18 | 727 ± 15 | 779 ± 17 | 814 ± 11
Leukocytes (10^3^/μL) | 7.96 ± 0.30 | 7.47 ± 0.34 | 8.52 ± 0.43 | 8.00 ± 0.38 | 8.03 ± 0.19 | 8.75 ± 0.23
Segmented neutrophils (10^3^/μL) | 1.68 ± 0.10 | 1.83 ± 0.10 | 1.77 ± 0.12 | 1.73 ± 0.15 | 1.91 ± 0.13 | 2.19 ± 0.14*
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 5.89 ± 0.27 | 5.32 ± 0.31 | 6.43 ± 0.36 | 5.90 ± 0.38 | 5.85 ± 0.26 | 6.24 ± 0.26
Monocytes (10^3^/μL) | 0.25 ± 0.07 | 0.23 ± 0.05 | 0.17 ± 0.06 | 0.26 ± 0.08 | 0.14 ± 0.05 | 0.19 ± 0.06
Basophils (10^3^/μL) | 0.010 ± 0.004 | 0.004 ± 0.002 | 0.006 ± 0.002 | 0.006 ± 0.002 | 0.005 ± 0.002 | 0.004 ± 0.002
Eosinophils (10^3^/μL) | 0.13 ± 0.01 | 0.09 ± 0.01 | 0.15 ± 0.03 | 0.11 ± 0.02 | 0.12 ± 0.02 | 0.12 ± 0.02
Clinical Chemistry
Urea nitrogen (mg/dL) | 15.5 ± 0.4 | 14.1 ± 0.4 | 13.7 ± 0.5* | 15.0 ± 0.4 | 14.3 ± 0.3 | 14.1 ± 0.4
Creatinine (mg/dL) | 0.39 ± 0.02 | 0.44 ± 0.02 | 0.39 ± 0.02 | 0.40 ± 0.03 | 0.38 ± 0.01 | 0.44 ± 0.02
Serum glucose (mg/dL) | 132 ± 4 | 123 ± 3 | 123 ± 3 | 127 ± 3 | 120 ± 2* | 116 ± 3**
Total protein (g/dL) | 7.7 ± 0.1 | 7.6 ± 0.1 | 7.6 ± 0.1 | 7.6 ± 0.1 | 7.7 ± 0.1 | 7.7 ± 0.1
Albumin (g/dL) | 4.9 ± 0.0 | 4.8 ± 0.0 | 4.8 ± 0.0 | 4.8 ± 0.0 | 4.9 ± 0.0 | 4.9 ± 0.1
Globulin (g/dL) | 2.8 ± 0.0 | 2.8 ± 0.0 | 2.8 ± 0.1 | 2.8 ± 0.0 | 2.8 ± 0.0 | 2.8 ± 0.1
Albumin/ globulin ratio | 1.8 ± 0.0 | 1.8 ± 0.0 | 1.8 ± 0.0 | 1.7 ± 0.0 | 1.8 ± 0.0 | 1.7 ± 0.0
Alanine aminotransferase (IU/L) | 110 ± 7 | 90 ± 3* | 86 ± 3** | 94 ± 7* | 85 ± 6** | 87 ± 8**
Alkaline phosphatase (IU/L) | 272 ± 6 | 263 ± 4 | 253 ± 6 | 265 ± 8 | 266 ± 6 | 261 ± 8
Creatine kinase (IU/L) | 292 ± 27 | 200 ± 18 | 247 ± 52 | 426 ± 113 | 234 ± 50 | 243 ± 24
Sorbitol dehydrogenase (IU/L) | 27 ± 2 | 20 ± 1** | 19 ± 1** | 19 ± 2** | 15 ± 1** | 15 ± 1**
Bile acids (µmol/L) | 5.6 ± 0.6 | 4.8 ± 0.3 | 5.5 ± 0.3 | 4.2 ± 0.2 | 4.6 ± 0.2 | 3.9 ± 0.2**
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Hematology
Hematocrit (%) | 47.4 ± 0.4 | 47.4 ± 0.3 | 46.8 ± 0.4 | 47.0 ± 0.4 | 47.3 ± 0.4 | 46.6 ± 0.3
Packed cell volume (%) | 47.1 ± 0.4 | 47.1 ± 0.4 | 46.5 ± 0.4 | 46.3 ± 0.4 | 46.8 ± 0.5 | 46.4 ± 0.3
Hemoglobin (g/dL) | 15.5 ± 0.1 | 15.5 ± 0.1 | 15.3 ± 0.1 | 15.2 ± 0.1 | 15.4 ± 0.1 | 15.1 ± 0.1
Erythrocytes (10^6^/μL) | 8.81 ± 0.06 | 8.79 ± 0.07 | 8.74 ± 0.08 | 8.74 ± 0.06 | 8.75 ± 0.08 | 8.66 ± 0.06
Reticulocytes (10^3^/μL) | 203 ± 11 | 216 ± 11 | 221 ± 12 | 217 ± 12 | 228 ± 11 | 236 ± 4
Nucleated erythrocytes (10^3^/μL) | 8.87 ± 0.50 | 9.64 ± 0.76 | 8.14 ± 0.45 | 9.69 ± 0.47 | 9.48 ± 0.37 | 9.29 ± 0.55
Nucleated erythrocytes/100 leukocytes | 0.1 ± 0.1 | 0.8 ± 0.2* | 0.3 ± 0.2 | 0.2 ± 0.1 | 0.1 ± 0.1 | 0.6 ± 0.2
Mean cell volume (fL) | 53.5 ± 0.2 | 53.6 ± 0.3 | 53.2 ± 0.2 | 52.9 ± 0.2 | 53.4 ± 0.3 | 53.6 ± 0.3
Mean cell hemoglobin (pg) | 17.6 ± 0.1 | 17.6 ± 0.1 | 17.5 ± 0.1 | 17.4 ± 0.1 | 17.5 ± 0.1 | 17.5 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.9 ± 0.1 | 32.8 ± 0.1 | 32.9 ± 0.1 | 32.8 ± 0.1 | 32.8 ± 0.1 | 32.7 ± 0.1
Platelets (10^3^/μL) | 738 ± 12 | 758 ± 15 | 750 ± 13 | 742 ± 15 | 779 ± 12 | 786 ± 22
Leukocytes (10^3^/μL) | 8.86 ± 0.50 | 9.57 ± 0.76 | 8.12 ± 0.45 | 9.67 ± 0.47 | 9.47 ± 0.37 | 9.24 ± 0.56
Segmented neutrophils (10^3^/μL) | 1.73 ± 0.10 | 2.00 ± 0.18 | 1.68 ± 0.09 | 1.90 ± 0.11 | 1.67 ± 0.11 | 1.46 ± 0.10
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 6.77 ± 0.45 | 7.30 ± 0.62 | 6.17 ± 0.39 | 7.54 ± 0.43 | 7.50 ± 0.28 | 7.46 ± 0.47
Monocytes (10^3^/μL) | 0.24 ± 0.08 | 0.13 ± 0.02 | 0.16 ± 0.06 | 0.11 ± 0.02 | 0.16 ± 0.06 | 0.19 ± 0.05
Basophils (10^3^/μL) | 0.005 ± 0.003 | 0.001 ± 0.001 | 0.001 ± 0.001 | 0.003 ± 0.002 | 0.001 ± 0.001 | 0.001 ± 0.001
Eosinophils (10^3^/μL) | 0.12 ± 0.02 | 0.15 ± 0.02 | 0.11 ± 0.01 | 0.12 ± 0.03 | 0.14 ± 0.03 | 0.12 ± 0.03
Clinical Chemistry
Urea nitrogen (mg/dL) | 15.0 ± 0.4 | 14.3 ± 0.3 | 15.1 ± 0.5 | 16.1 ± 0.3 | 15.9 ± 0.3 | 14.6 ± 0.5
Creatinine (mg/dL) | 0.44 ± 0.02 | 0.46 ± 0.02 | 0.44 ± 0.02 | 0.41 ± 0.02 | 0.41 ± 0.02 | 0.42 ± 0.02
Serum glucose (mg/dL) | 129 ± 4 | 128 ± 3 | 132 ± 5 | 125 ± 5 | 128 ± 3 | 130 ± 5
Total protein (g/dL) | 7.8 ± 0.1 | 7.9 ± 0.1 | 7.8 ± 0.1 | 7.6 ± 0.1 | 7.7 ± 0.1 | 7.7 ± 0.1
Albumin (g/dL) | 5.2 ± 0.1 | 5.2 ± 0.0 | 5.2 ± 0.1 | 5.0 ± 0.1 | 5.2 ± 0.1 | 5.2 ± 0.1
Globulin (g/dL) | 2.7 ± 0.0 | 2.7 ± 0.0 | 2.6 ± 0.1 | 2.5 ± 0.1 | 2.5 ± 0.0 | 2.5 ± 0.1
Albumin/globulin ratio | 2.0 ± 0.0 | 1.9 ± 0.0 | 2.0 ± 0.0 | 2.0 ± 0.0 | 2.0 ± 0.0 | 2.1 ± 0.0*
Alanine aminotransferase (IU/L) | 68 ± 4 | 82 ± 5 | 67 ± 5 | 62 ± 3 | 84 ± 4 | 77 ± 3
Alkaline phosphatase (IU/L) | 238 ± 7 | 217 ± 9 | 241 ± 6 | 234 ± 6 | 224 ± 7 | 230 ± 8
Creatine kinase (IU/L) | 226 ± 20 | 157 ± 6 | 180 ± 23 | 193 ± 19 | 216 ± 20 | 204 ± 21
Sorbitol dehydrogenase (IU/L) | 20 ± 1 | 19 ± 1 | 17 ± 1 | 15 ± 1** | 15 ± 0** | 14 ± 1**
Bile acids (µmol/L) | 8.1 ± 0.7 | 6.6 ± 0.4 | 6.5 ± 0.5 | 6.6 ± 1.4* | 6.2 ± 0.5 | 6.0 ± 0.4

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

Table F-2 Hematology Data for Mice in the Three-month Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
Male
n | 10 | 8 | 10 | 10 | 9 | 7
Hematocrit (%) | 49.7 ± 0.7 | 50.2 ± 0.9 | 50.0 ± 0.7 | 50.6 ± 0.4 | 51.2 ± 0.5 | 48.4 ± 0.8
Packed cell volume (%) | 50.6 ± 0.6 | 50.9 ± 0.7 | 51.2 ± 0.7 | 51.1 ± 0.5 | 51.8 ± 0.8 | 49.7 ± 0.9
Hemoglobin (g/dL) | 15.7 ± 0.2 | 15.7 ± 0.3 | 15.9 ± 0.2 | 16.0 ± 0.1 | 16.0 ± 0.3 | 15.4 ± 0.3
Erythrocytes (10^6^/µL) | 10.39 ± 0.10 | 10.19 ± 0.23 | 10.41 ± 0.15 | 10.49 ± 0.11 | 10.52 ± 0.20 | 10.31 ± 0.17
Reticulocytes (10^3^/µL) | 242 ± 14 | 266 ± 16 | 253 ± 22 | 261 ± 15 | 258 ± 18 | 274 ± 8
Nucleated erythrocytes (10^3^/µL) | 2.03 ± 0.35 | 2.27 ± 0.35 | 2.17 ± 0.24 | 2.42 ± 0.50 | 2.39 ± 0.33 | 1.77 ± 0.23
Nucleated erythrocytes/ 100 leukocytes | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Howell-Jolly bodies (% erythrocytes) | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0
Mean cell volume (fL) | 48.7 ± 0.2 | 50.0 ± 0.7 | 49.2 ± 0.3 | 48.7 ± 0.2 | 49.3 ± 0.5 | 48.2 ± 0.2
Mean cell hemoglobin (pg) | 15.1 ± 0.1 | 15.4 ± 0.2 | 15.3 ± 0.1 | 15.3 ± 0.1 | 15.2 ± 0.1 | 15.0 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 31.0 ± 0.1 | 30.8 ± 0.2 | 31.1 ± 0.1 | 31.3 ± 0.1 | 30.9 ± 0.2 | 31.0 ± 0.2
Platelets (10^3^/µL) | 848 ± 17 | 819 ± 57 | 814 ± 16 | 844 ± 15 | 867 ± 17 | 815 ± 11
Leukocytes (10^3^/µL) | 2.03 ± 0.35 | 2.27 ± 0.35 | 2.17 ± 0.24 | 2.42 ± 0.50 | 2.39 ± 0.33 | 1.77 ± 0.23
Segmented neutrophils (10^3^/µL) | 0.38 ± 0.10 | 0.25 ± 0.04 | 0.26 ± 0.04 | 0.34 ± 0.09 | 0.24 ± 0.03 | 0.21 ± 0.04
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 1.56 ± 0.26 | 1.94 ± 0.31 | 1.85 ± 0.21 | 2.02 ± 0.41 | 2.07 ± 0.31 | 1.49 ± 0.24
Monocytes (10^3^/µL) | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.02
Basophils (10^3^/µL) | 0.008 ± 0.002 | 0.016 ± 0.012 | 0.010 ± 0.005 | 0.007 ± 0.002 | 0.008 ± 0.002 | 0.004 ± 0.002
Eosinophils (10^3^/µL) | 0.04 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.04 ± 0.01 | 0.02 ± 0.01
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%) | 51.2 ± 0.2 | 51.9 ± 0.4 | 51.9 ± 0.4 | 50.7 ± 0.4 | 51.0 ± 0.4 | 49.9 ± 0.4
Packed cell volume (%) | 52.1 ± 0.3 | 52.7 ± 0.4 | 52.3 ± 0.4 | 51.6 ± 0.4 | 51.4 ± 0.4 | 50.6 ± 0.4*
Hemoglobin (g/dL) | 16.4 ± 0.1 | 16.6 ± 0.1 | 16.5 ± 0.1 | 16.2 ± 0.1 | 16.3 ± 0.1 | 15.9 ± 0.1**
Erythrocytes (10^6^/µL) | 10.50 ± 0.09 | 10.65 ± 0.07 | 10.57 ± 0.09 | 10.42 ± 0.08 | 10.55 ± 0.08 | 10.34 ± 0.06
Reticulocytes (10^3^/µL) | 270 ± 8 | 291 ± 13 | 285 ± 9 | 278 ± 9 | 288 ± 9 | 276 ± 16
Nucleated erythrocytes (10^3^/µL) | 2.78 ± 0.22 | 3.00 ± 0.34 | 3.04 ± 0.39 | 2.43 ± 0.28 | 3.15 ± 0.69 | 2.52 ± 0.24
Nucleated erythrocytes/ 100 leukocytes | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Howell-Jolly bodies (% erythrocytes) | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0
Mean cell volume (fL) | 49.7 ± 0.3 | 49.5 ± 0.2 | 49.5 ± 0.2 | 49.6 ± 0.2 | 48.8 ± 0.2** | 49.0 ± 0.2*
Mean cell hemoglobin (pg) | 15.6 ± 0.1 | 15.6 ± 0.0 | 15.7 ± 0.1 | 15.5 ± 0.1 | 15.5 ± 0.1 | 15.4 ± 0.0
Mean cell hemoglobin concentration (g/dL) | 31.4 ± 0.1 | 31.5 ± 0.1 | 31.7 ± 0.1 | 31.3 ± 0.2 | 31.7 ± 0.2 | 31.5 ± 0.2
Platelets (10^3^/µL) | 776 ± 20 | 796 ± 12 | 788 ± 13 | 792 ± 18 | 773 ± 15 | 754 ± 15
Leukocytes (10^3^/µL) | 2.78 ± 0.22 | 2.98 ± 0.34 | 3.04 ± 0.39 | 2.43 ± 0.28 | 3.15 ± 0.69 | 2.52 ± 0.24
Segmented neutrophils (10^3^/µL) | 0.36 ± 0.05 | 0.30 ± 0.04 | 0.28 ± 0.04 | 0.28 ± 0.05 | 0.21 ± 0.02 | 0.24 ± 0.03
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.34 ± 0.19 | 2.55 ± 0.30 | 2.68 ± 0.37 | 2.10 ± 0.23 | 2.89 ± 0.66 | 2.22 ± 0.21
Monocytes (10^3^/µL) | 0.04 ± 0.01 | 0.07 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01
Basophils (10^3^/µL) | 0.019 ± 0.007 | 0.025 ± 0.009 | 0.013 ± 0.003 | 0.008 ± 0.002 | 0.008 ± 0.003 | 0.010 ± 0.002
Eosinophils (10^3^/µL) | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.01

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.