# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

Testing was performed as reported by Zeiger et al.^113^ with slight modifications. CIMSTAR 3800 was sent to the laboratory as a coded aliquot. It was incubated with the Salmonella typhimurium tester strains TA98 and TA100 and the Escherichia coli strain WP2 uvrA/pKM101 either in buffer or 10% S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat liver) for 20 minutes at 37°C. Top agar supplemented with l-histidine and d-biotin (or tryptophan for the E. coli strain) was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of CIMSTAR 3800. The high dose was limited by assay design to 10,000 µg/plate. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

## E.2 Peripheral Blood Micronucleus Test Protocol

At the termination of the 3-month studies, blood samples were collected from male and female rats and mice, placed in EDTA-coated tubes, fixed in ultracold methanol and frozen at −80°C until analysis. Thawed blood samples were analyzed for frequency of micronucleated reticulocytes (polychromatic erythrocytes, PCEs) and mature erythrocytes (normochromatic erythrocytes, NCEs) using a flow cytometer^114^; both the mature erythrocyte population and the immature reticulocyte population can be analyzed separately by employing special cell surface markers to differentiate the two cell types. Because the very young reticulocyte population can be targeted using this technique, rat blood samples can be analyzed for damage in the bone marrow that occurred within the past 24 to 48 hours, before the rat spleen appreciably alters the percentage of micronucleated reticulocytes in circulation^115^. In mice, both the reticulocyte and mature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. These achieve steady state in the peripheral blood of mice following 4 weeks of continuous exposure. Approximately 20,000 PCEs and 1 × 10^6^ NCEs are analyzed per sample for frequency of micronucleated cells, and the percent PCEs is calculated as a measure of bone marrow toxicity resulting from chemical exposure.

Based on prior experience with the large number of cells scored using flow cytometric scoring techniques^116^, it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. Levene’s test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with dose and Williams’ test is used to test for pairwise differences between each treatment group and the control group. In the case of unequal variances, Jonckheere’s test is used to test for linear trend and Dunn’s test is used for pairwise comparisons of each treatment group with the control group. To correct for multiple pairwise comparisons, the P value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is greater than 1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the controls are considered statistically significant at P ≤ 0.025.

In the micronucleus test (for each data set: PCEs, NCEs, percentage of PCEs), a positive result is preferably based on the presence of both a significant trend as well as at least one significantly elevated dose group compared with the corresponding control group. The presence of either a significant trend or a single significant dose group generally results in an equivocal call. The absence of both a trend and a significant dose group results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

## E.3 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## E.4 Results

CIMSTAR 3800 (dose range tested, 1,000 to 10,000 µg/plate) was weakly mutagenic in E. coli strain WP2 uvrA/pKM101 in the absence of exogenous metabolic activation (S9); no mutagenic activity was observed in S. typhimurium strains TA98 and TA100 tested over the same dose range, with or without S9, or in the E. coli strain with S9 (Table E-1).

In vivo, no increases in the frequencies of micronucleated reticulocytes or erythrocytes were observed in peripheral blood samples from male or female F344/NTac rats or B6C3F1/N mice exposed to CIMSTAR 3800 via inhalation (25 to 400 mg/m^3^) for 3 months (Table E-2 and Table E-3). In female rats, a significant trend was observed for micronucleated erythrocytes (P = 0.003). However, in rats, the appropriate cell population to evaluate for frequency of micronucleated cells in peripheral blood is the very young newly emerged reticulocyte population because the rat spleen is very efficient at quickly sequestering and destroying damaged erythrocytes. Thus, despite the very slight increase in micronucleated erythrocytes in 400 mg/m^3^ female rats, the absence of supporting data in the female micronucleated reticulocyte data set and in the male rats suggests that the increase is not biologically significant.

In addition to the micronucleus endpoint, the percentage of reticulocytes among circulating red blood cells was calculated as a measure of bone marrow toxicity or perturbations in erythropoiesis (Table E-2 and Table E-3). No significant alterations in the percentage of reticulocytes among red blood cells was seen with CIMSTAR 3800, suggesting an absence of treatment-related bone marrow toxicity. The very small and inconsistent changes in percentage of reticulocytes noted in both the male and female mice, in the absence of any observed hematologic effects, were not considered biologically significant.

Table E-1 Mutagenicity of CIMSTAR 3800 in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 92 ± 1 | 96 ± 5 | 80 ± 3 | 126 ± 2
| 1,000 | 110 ± 5 | 101 ± 12 | 97 ± 10 | 127 ± 9
| 2,500 | 105 ± 5 | 79 ± 8 | 119 ± 15 | 132 ± 2
| 5,000 | 74 ± 7 | 73 ± 6 | 107 ± 10 | 140 ± 7
| 7,500 | 63 ± 6 | 73 ± 7 | 113 ± 4 | 136 ± 6
| 10,000 | 54 ± 4 | 32 ± 8 | 103 ± 1 | 151 ± 7
Trial summary | | Negative | Negative | Negative | Negative
Positive control^b^ | | 376 ± 7 | 745 ± 56 | 853 ± 37 | 776 ± 53
TA98
| 0 | 27 ± 4 | 34 ± 1 | 35 ± 2 | 30 ± 0
| 1,000 | 22 ± 1 | 36 ± 3 | 35 ± 3 | 35 ± 2
| 2,500 | 21 ± 1 | 31 ± 5 | 31 ± 3 | 36 ± 1
| 5,000 | 33 ± 4 | 30 ± 3 | 35 ± 1 | 41 ± 2
| 7,500 | 22 ± 4 | 27 ± 4 | 30 ± 3 | 43 ± 5
| 10,000 | 4 ± 0 | 11 ± 2 | 29 ± 2 | 39 ± 1
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 574 ± 17 | 740 ± 46 | 652 ± 29 | 776 ± 56
Escherichia coli WP2 uvrA/pKM101 (analogous to TA102)
| 0 | 164 ± 5 | 216 ± 11 | 200 ± 1 | 275 ± 5
| 1,000 | 205 ± 6 | 280 ± 12 | 218 ± 7 | 247 ± 14
| 2,500 | 240 ± 28 | 352 ± 12 | 250 ± 27 | 314 ± 39
| 5,000 | 269 ± 9 | 358 ± 12 | 262 ± 20 | 310 ± 7
| 7,500 | 283 ± 14 | 342 ± 22 | 235 ± 27 | 346 ± 10
| 10,000 | 232 ± 15 | 371 ± 10 | 287 ± 9 | 316 ± 9
Trial summary | | Weakly Positive | Weakly Positive | Equivocal | Negative
Positive control | | 701 ± 80 | 950 ± 26 | 777 ± 19 | 875 ± 51

^a^ Study was performed at SITEK Research Laboratories. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of F344/NTac Rats Following Treatment with CIMSTAR 3800 by Inhalation for Three Months^a^

| Dose (mg/m^3^) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^d^ | PCEs^b^(%) | P Value^c^
Male
Air^e^ | 0 | 6 | 0.32 ± 0.06 | | 0.08 ± 0.03 | | 1.829 ± 0.12
CIMSTAR 3800 | 25 | 5 | 0.39 ± 0.05 | 0.4618 | 0.14 ± 0.03 | 0.7029 | 1.788 ± 0.14 | 1.0000
| 50 | 5 | 0.42 ± 0.03 | 0.5440 | 0.12 ± 0.01 | 0.7029 | 1.973 ± 0.11 | 0.6911
| 100 | 5 | 0.28 ± 0.05 | 0.5801 | 0.03 ± 0.00 | 1.0000 | 1.888 ± 0.14 | 0.7333
| 200 | 5 | 0.21 ± 0.05 | 0.5982 | 0.04 ± 0.02 | 1.0000 | 2.130 ± 0.05 | 0.3089
| 400 | 5 | 0.32 ± 0.07 | 0.6106 | 0.05 ± 0.01 | 1.0000 | 1.993 ± 0.19 | 0.3145
| | | P = 0.849^f^ | | P = 0.993^g^ | | P = 0.243^f^
Female
Air | 0 | 5 | 0.30 ± 0.07 | | 0.06 ± 0.02 | | 0.931 ± 0.07
CIMSTAR 3800 | 25 | 5 | 0.32 ± 0.10 | 0.7841 | 0.04 ± 0.01 | 0.9517 | 0.932 ± 0.06 | 0.9759
| 50 | 5 | 0.28 ± 0.06 | 0.8602 | 0.02 ± 0.00 | 0.9792 | 0.994 ± 0.05 | 0.8457
| 100 | 5 | 0.19 ± 0.03 | 0.8866 | 0.02 ± 0.01 | 0.9857 | 0.944 ± 0.09 | 0.8879
| 200 | 5 | 0.17 ± 0.03 | 0.8985 | 0.06 ± 0.01 | 0.5357 | 1.019 ± 0.04 | 0.4927
| 400 | 5 | 0.12 ± 0.04 | 0.9080 | 0.08 ± 0.01 | 0.1019 | 1.123 ± 0.11 | 0.1381
| | | P = 0.995^f^ | | P = 0.003^f^ | | P = 0.049^f^

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^114^. NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Dunn’s (males) or Williams’ (females) test.

^e^ Chamber control.

^f^ Dose-related trend; significant at P ≤ 0.025 by linear regression.

^g^ Dose-related trend; significant at P ≤ 0.025 by Jonckheere’s test.

Table E-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Treatment with CIMSTAR 3800 by Inhalation for Three Months^a^

| Dose (mg/m^3^) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^c^ | PCEs^b^(%) | P Value^d^
Male
Air^e^ | 0 | 5 | 2.42 ± 0.15 | | 1.31 ± 0.04 | | 1.904 ± 0.09
CIMSTAR 3800 | 25 | 6 | 1.89 ± 0.21 | 0.9222 | 1.38 ± 0.05 | 0.5601 | 3.133 ± 1.28 | 1.0000
| 50 | 5 | 2.07 ± 0.16 | 0.9589 | 1.33 ± 0.04 | 0.6490 | 1.952 ± 0.07 | 1.0000
| 100 | 5 | 2.10 ± 0.04 | 0.9697 | 1.27 ± 0.03 | 0.6825 | 1.548 ± 0.08 | 0.0745
| 200 | 5 | 2.16 ± 0.16 | 0.9568 | 1.25 ± 0.02 | 0.6997 | 1.627 ± 0.04 | 0.2371
| 400 | 5 | 2.19 ± 0.11 | 0.9455 | 1.26 ± 0.02 | 0.7101 | 1.617 ± 0.06 | 0.3264
| | | P = 0.385^f^ | | P = 0.981^f^ | | P = 0.003^g^
Female
Air | 0 | 5 | 1.74 ± 0.11 | | 0.98 ± 0.04 | | 1.365 ± 0.08
CIMSTAR 3800 | 25 | 5 | 1.63 ± 0.15 | 0.6130 | 0.91 ± 0.03 | 0.8893 | 1.834 ± 0.10 | 0.1029
| 50 | 5 | 1.69 ± 0.15 | 0.6898 | 0.91 ± 0.02 | 0.9415 | 1.593 ± 0.16 | 0.1221
| 100 | 5 | 1.70 ± 0.16 | 0.7032 | 0.91 ± 0.03 | 0.9561 | 1.422 ± 0.11 | 0.1298
| 200 | 5 | 1.81 ± 0.15 | 0.6251 | 0.95 ± 0.02 | 0.9631 | 1.609 ± 0.10 | 0.1171
| 400 | 5 | 1.68 ± 0.09 | 0.6372 | 0.90 ± 0.01 | 0.9677 | 1.758 ± 0.05 | 0.0132
| | | P = 0.452^f^ | | P = 0.766^f^ | | P = 0.145^f^

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^114^. NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Dunn’s (males) or Williams’ (females) test.

^e^ Chamber control.

^f^ Dose-related trend; significant at P ≤ 0.025 by linear regression.

^g^ Dose-related trend; significant at P ≤ 0.025 by Jonckheere’s test.