# Appendix D Summary of Lesions in Female Mice in the Two-year Inhalation Study of CIMSTAR 3800

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | – | – | 1
Moribund | 7 | 8 | 10 | 11
Natural deaths | 4 | 5 | 3 | 5
Survivors
Terminal kill | 39 | 37 | 37 | 33
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (46) | (49) | (41) | (41)
Leiomyosarcoma, metastatic, intestine small, duodenum | – | – | – | 1 (2%)
Intestine large, cecum | (50) | (50) | (49) | (50)
Leiomyoma | – | – | – | 1 (2%)
Intestine large, colon | (49) | (50) | (49) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (47) | (50) | (50) | (49)
Adenoma | 1 (2%) | – | 1 (2%) | –
Leiomyosarcoma | – | – | – | 1 (2%)
Intestine small, ileum | (49) | (50) | (49) | (49)
Carcinoma | – | 1 (2%) | – | –
Intestine small, jejunum | (48) | (50) | (48) | (48)
Liver | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Hepatoblastoma | 1 (2%) | – | – | –
Hepatocellular adenoma | 10 (20%) | 11 (22%) | 9 (18%) | 7 (14%)
Hepatocellular adenoma, multiple | 4 (8%) | 3 (6%) | 5 (10%) | 3 (6%)
Hepatocellular carcinoma | 10 (20%) | 8 (16%) | 2 (4%) | 1 (2%)
Hepatocellular carcinoma, multiple | – | 1 (2%) | – | –
Hepatocholangiocarcinoma | – | – | – | 1 (2%)
Leiomyosarcoma, metastatic, uterus | – | – | 1 (2%) | –
Mesentery | (16) | (23) | (21) | (15)
Hemangioma | – | 2 (9%) | – | –
Hemangiosarcoma | – | – | 1 (5%) | –
Fat, leiomyosarcoma, metastatic, intestine small, duodenum | – | – | – | 1 (7%)
Pancreas | (50) | (50) | (50) | (50)
Leiomyosarcoma, metastatic, intestine small, duodenum | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (49)
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma | – | – | – | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Tooth | (1) | (0) | (2) | (4)
Cardiovascular System
Blood vessel | (46) | (44) | (49) | (44)
Heart | (50) | (50) | (50) | (50)
Endocrine System
Adrenal cortex | (49) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | – | – | 1 (2%) | –
Subcapsular, adenoma | – | 2 (4%) | 1 (2%) | –
Adrenal medulla | (49) | (50) | (49) | (50)
Pheochromocytoma benign | 1 (2%) | 2 (4%) | 1 (2%) | –
Pheochromocytoma malignant | – | – | 1 (2%) | –
Islets, pancreatic | (50) | (50) | (50) | (49)
Adenoma | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Parathyroid gland | (26) | (29) | (22) | (25)
Pituitary gland | (50) | (50) | (49) | (50)
Meningioma malignant, metastatic, brain | – | – | – | 1 (2%)
Pars distalis, adenoma | 5 (10%) | 4 (8%) | 6 (12%) | 9 (18%)
Pars intermedia, adenoma | – | – | 2 (4%) | –
Thyroid gland | (50) | (48) | (50) | (50)
C-cell, adenoma | – | – | – | 1 (2%)
Follicular cell, carcinoma | – | – | – | 3 (6%)
General Body System
Tissue NOS | (3) | (2) | (0) | (0)
Mediastinum, carcinoma | – | 1 (50%) | – | –
Genital System
Clitoral gland | (44) | (45) | (43) | (44)
Ovary | (50) | (50) | (48) | (50)
Cystadenocarcinoma | – | – | 1 (2%) | –
Cystadenoma | 2 (4%) | 1 (2%) | – | –
Granulosa cell tumor benign | 1 (2%) | – | – | –
Leiomyosarcoma, metastatic, uterus | – | – | 1 (2%) | –
Luteoma | 1 (2%) | 1 (2%) | – | –
Uterus | (50) | (50) | (50) | (50)
Carcinoma | – | – | 1 (2%) | –
Hemangiosarcoma | 1 (2%) | 1 (2%) | – | –
Leiomyoma | 1 (2%) | – | – | –
Leiomyosarcoma | – | – | 1 (2%) | –
Polyp stromal | – | 3 (6%) | 2 (4%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Sarcoma | 1 (2%) | – | – | –
Lymph node | (11) | (12) | (16) | (10)
Renal, hemangiosarcoma | – | – | – | 1 (10%)
Lymph node, bronchial | (26) | (27) | (28) | (27)
Carcinoma, metastatic, uncertain primary site | – | – | – | 1 (4%)
Lymph node, mandibular | (41) | (42) | (43) | (35)
Hemangiosarcoma | – | – | – | 1 (3%)
Lymph node, mediastinal | (43) | (46) | (40) | (47)
Lymph node, mesenteric | (48) | (50) | (49) | (49)
Spleen | (50) | (50) | (50) | (49)
Hemangiosarcoma | 1 (2%) | 1 (2%) | – | –
Thymus | (44) | (46) | (45) | (45)
Thymoma benign | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenoma | – | – | – | 1 (2%)
Carcinoma | 2 (4%) | – | 2 (4%) | 1 (2%)
Skin | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | – | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Lip, squamous cell papilloma | 1 (2%) | – | – | –
Subcutaneous tissue, fibrosarcoma | – | 1 (2%) | 1 (2%) | 1 (2%)
Subcutaneous tissue, hemangiosarcoma | 1 (2%) | – | – | –
Subcutaneous tissue, schwannoma malignant | – | 1 (2%) | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Femur, sarcoma | 1 (2%) | – | – | –
Vertebra, rhabdomyosarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Skeletal muscle | (3) | (3) | (1) | (4)
Leiomyosarcoma, metastatic, intestine small, duodenum | – | – | – | 1 (25%)
Rhabdomyosarcoma | – | – | – | 1 (25%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Meningioma malignant | – | – | – | 1 (2%)
Peripheral nerve | (2) | (3) | (1) | (3)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | – | – | 1 (33%)
Spinal cord | (3) | (3) | (1) | (3)
Respiratory System
Larynx | (49) | (49) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 1 (2%) | 3 (6%) | 2 (4%) | 4 (8%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (2%) | – | –
Alveolar/bronchiolar carcinoma | 4 (8%) | 1 (2%) | 4 (8%) | 8 (16%)
Carcinoma, metastatic, mammary gland | – | – | 1 (2%) | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 2 (4%) | 4 (8%) | 1 (2%) | –
Schwannoma malignant, metastatic, skin | – | – | 1 (2%) | –
Nose | (50) | (49) | (50) | (50)
Carcinoma, metastatic, Harderian gland | – | – | 1 (2%) | –
Trachea | (49) | (49) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Carcinoma, metastatic, Harderian gland | – | – | 1 (2%) | –
Harderian gland | (50) | (50) | (50) | (50)
Adenoma | 2 (4%) | 6 (12%) | 3 (6%) | 1 (2%)
Carcinoma | – | 1 (2%) | 1 (2%) | 2 (4%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Ureter | (0) | (0) | (1) | (0)
Urethra | (0) | (1) | (0) | (0)
Sarcoma | – | 1 (100%) | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Lymphoma malignant | 18 (36%) | 18 (36%) | 17 (34%) | 20 (40%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 41 | 42 | 43 | 40
Total primary neoplasms | 74 | 77 | 69 | 73
Total animals with benign neoplasms | 26 | 30 | 28 | 23
Total benign neoplasms | 31 | 40 | 35 | 29
Total animals with malignant neoplasms | 30 | 31 | 28 | 34
Total malignant neoplasms | 43 | 37 | 34 | 44
Total animals with metastatic neoplasms | 2 | 4 | 4 | 4
Total metastatic neoplasms | 2 | 4 | 8 | 10
Total animals with malignant neoplasms of uncertain primary site | – | – | – | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Harderian Gland: Adenoma
Overall rate^a^ | 2/50 (4%) | 6/50 (12%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate^b^ | 4.4% | 13.1% | 6.5% | 2.3%
Terminal rate^c^ | 2/39 (5%) | 5/37 (14%) | 3/37 (8%) | 0/33 (0%)
First incidence (days) | 731 (T) | 677 | 731 (T) | 644
Poly-3 test^d^ | P = 0.160N | P = 0.137 | P = 0.506 | P = 0.511N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 7/50 (14%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate | 4.4% | 15.3% | 8.7% | 6.8%
Terminal rate | 2/39 (5%) | 6/37 (16%) | 3/37 (8%) | 2/33 (6%)
First incidence (days) | 731 (T) | 677 | 644 | 644
Poly-3 test | P = 0.428N | P = 0.082 | P = 0.347 | P = 0.486
Liver: Hepatocellular Adenoma
Overall rate | 14/50 (28%) | 14/50 (28%) | 14/50 (28%) | 10/50 (20%)
Adjusted rate | 29.8% | 29.7% | 29.8% | 22.7%
Terminal rate | 11/39 (28%) | 10/37 (27%) | 10/37 (27%) | 7/33 (21%)
First incidence (days) | 527 | 583 | 576 | 669
Poly-3 test | P = 0.239N | P = 0.582N | P = 0.588N | P = 0.297N
Liver: Hepatocellular Carcinoma
Overall rate | 10/50 (20%) | 9/50 (18%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 21.9% | 19.2% | 4.3% | 2.3%
Terminal rate | 9/39 (23%) | 5/37 (14%) | 1/37 (3%) | 1/33 (3%)
First incidence (days) | 605 | 552 | 644 | 731 (T)
Poly-3 test | P = 0.002N | P = 0.473N | P = 0.012N | P = 0.005N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 20/50 (40%)^e^ | 19/50 (38%) | 15/50 (30%) | 10/50 (20%)
Adjusted rate | 42.6% | 39.6% | 32.0% | 22.7%
Terminal rate | 17/39 (44%) | 12/37 (32%) | 11/37 (30%) | 7/33 (21%)
First incidence (days) | 527 | 552 | 576 | 669
Poly-3 test | P = 0.024N | P = 0.463N | P = 0.195N | P = 0.034N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 1/50 (2%) | 4/50 (8%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 2.2% | 8.8% | 4.3% | 9.2%
Terminal rate | 1/39 (3%) | 4/37 (11%) | 1/37 (3%) | 3/33 (9%)
First incidence (days) | 731 (T) | 731 (T) | 677 | 712
Poly-3 test | P = 0.245 | P = 0.181 | P = 0.506 | P = 0.168
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 4/50 (8%) | 1/50 (2%) | 4/50 (8%) | 8/50 (16%)
Adjusted rate | 8.8% | 2.2% | 8.6% | 18.2%
Terminal rate | 4/39 (10%) | 1/37 (3%) | 3/37 (8%) | 6/33 (18%)
First incidence (days) | 731 (T) | 731 (T) | 460 | 644
Poly-3 test | P = 0.021 | P = 0.176N | P = 0.627N | P = 0.163
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 5/50 (10%) | 6/50 (12%) | 12/50 (24%)
Adjusted rate | 8.8% | 10.9% | 12.8% | 27.2%
Terminal rate | 4/39 (10%) | 5/37 (14%) | 4/37 (11%) | 9/33 (27%)
First incidence (days) | 731 (T) | 731 (T) | 460 | 644
Poly-3 test | P = 0.006 | P = 0.505 | P = 0.391 | P = 0.021
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 5/50 (10%) | 4/50 (8%) | 6/49 (12%) | 9/50 (18%)
Adjusted rate | 11.0% | 8.8% | 13.2% | 20.3%
Terminal rate | 5/39 (13%) | 4/37 (11%) | 5/37 (14%) | 5/33 (15%)
First incidence (days) | 731 (T) | 731 (T) | 681 | 634
Poly-3 test | P = 0.076 | P = 0.495N | P = 0.502 | P = 0.180
Thyroid Gland (Follicular Cell): Carcinoma
Overall rate | 0/50 (0%) | 0/48 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 6.9%
Terminal rate | 0/39 (0%) | 0/36 (0%) | 0/37 (0%) | 2/33 (6%)
First incidence (days) | –^f^ | – | – | 712
Poly-3 test | P = 0.008 | –^g^ | – | P = 0.112
Uterus: Stromal Polyp
Overall rate | 0/50 (0%) | 3/50 (6%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 0.0% | 6.6% | 4.3% | 0.0%
Terminal rate | 0/39 (0%) | 3/37 (8%) | 1/37 (3%) | 0/33 (0%)
First incidence (days) | – | 731 (T) | 576 | –
Poly-3 test | P = 0.293N | P = 0.120 | P = 0.243 | –
All Organs: Hemangiosarcoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 6.6% | 4.4% | 2.2% | 6.9%
Terminal rate | 3/39 (8%) | 2/37 (5%) | 0/37 (0%) | 2/33 (6%)
First incidence (days) | 731 (T) | 731 (T) | 576 | 699
Poly-3 test | P = 0.483 | P = 0.496N | P = 0.297N | P = 0.646
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 6.6% | 8.8% | 2.2% | 6.9%
Terminal rate | 3/39 (8%) | 4/37 (11%) | 0/37 (0%) | 2/33 (6%)
First incidence (days) | 731 (T) | 731 (T) | 576 | 699
Poly-3 test | P = 0.576N | P = 0.505 | P = 0.297N | P = 0.646
All Organs: Malignant Lymphoma
Overall rate | 18/50 (36%) | 18/50 (36%) | 17/50 (34%) | 20/50 (40%)
Adjusted rate | 39.7% | 39.1% | 35.8% | 43.7%
Terminal rate | 17/39 (44%) | 16/37 (43%) | 12/37 (32%) | 13/33 (39%)
First incidence (days) | 705 | 655 | 460 | 536
Poly-3 test | P = 0.348 | P = 0.562N | P = 0.433N | P = 0.429
All Organs: Benign Neoplasms
Overall rate | 26/50 (52%) | 30/50 (60%) | 28/50 (56%) | 23/50 (46%)
Adjusted rate | 54.1% | 63.6% | 59.1% | 51.0%
Terminal rate | 20/39 (51%) | 26/37 (70%) | 22/37 (60%) | 15/33 (46%)
First incidence (days) | 345 | 583 | 576 | 634
Poly-3 test | P = 0.256N | P = 0.228 | P = 0.384 | P = 0.465N
All Organs: Malignant Neoplasms
Overall rate | 30/50 (60%) | 31/50 (62%) | 28/50 (56%) | 34/50 (68%)
Adjusted rate | 64.0% | 63.9% | 57.0% | 72.4%
Terminal rate | 26/39 (67%) | 22/37 (60%) | 19/37 (51%) | 22/33 (67%)
First incidence (days) | 527 | 508 | 460 | 536
Poly-3 test | P = 0.175 | P = 0.579N | P = 0.310N | P = 0.254
All Organs: Benign or Malignant Neoplasms
Overall rate | 41/50 (82%) | 42/50 (84%) | 43/50 (86%) | 40/50 (80%)
Adjusted rate | 84.5% | 85.4% | 86.8% | 84.9%
Terminal rate | 34/39 (87%) | 31/37 (84%) | 31/37 (84%) | 27/33 (82%)
First incidence (days) | 345 | 508 | 460 | 536
Poly-3 test | P = 0.569N | P = 0.567 | P = 0.486 | P = 0.592

(T) = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ A single incidence of hepatoblastoma occurred in an animal that also had a hepatocellular adenoma and a hepatocellular carcinoma.

^f^ Not applicable; no neoplasms in animal group.

^g^ Value of statistic cannot be computed.

Table D-3 Historical Incidence of Thyroid Gland Follicular Cell Neoplasms in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 0/49 | 0/49 | 0/49
CIMSTAR 3800 (May 2008) | 0/50 | 0/50 | 0/50
Cobalt metal (May 2006) | 1/50 | 0/50 | 1/50
Diethylamine (August 2003) | 0/50 | 0/50 | 0/50
Tetralin (June 2003) | 0/50 | 1/50 | 1/50
Vinylidene chloride (June 2005) | 0/50 | 0/50 | 0/50
Total (%) | 1/299 (0.3%) | 1/299 (0.3%) | 2/299 (0.7%)
Mean ± standard deviation | 0.3% ± 0.8% | 0.3% ± 0.8% | 0.7% ± 1.0%
Range | 0%–2% | 0%–2% | 0%–2%
Overall Historical Incidence: All Routes
Total (%) | 2/942 (0.2%) | 2/942 (0.2%) | 4/942 (0.4%)
Mean ± standard deviation | 0.2% ± 0.6% | 0.2% ± 0.6% | 0.4% ± 0.8%
Range | 0%–2% | 0%–2% | 0%–2%

^a^ Data as of June 2013.

Table D-4 Historical Incidence of Alveolar/bronchiolar Neoplasms in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 1/50 | 0/50 | 1/50
CIMSTAR 3800 (May 2008) | 1/50 | 4/50 | 4/50
Cobalt metal (May 2006) | 3/49 | 5/49 | 8/49
Diethylamine (August 2003) | 2/50 | 3/50 | 5/50
Tetralin (June 2003) | 6/50 | 0/50 | 6/50
Vinylidene chloride (June 2005) | 3/50 | 1/50 | 4/50
Total (%) | 16/299 (5.4%) | 13/299 (4.4%) | 28/299 (9.4%)
Mean ± standard deviation | 5.4% ± 3.7% | 4.4% ± 4.3% | 9.4% ± 4.8%
Range | 2%–12% | 0%–10% | 2%–16%
Overall Historical Incidence: All Routes
Total (%) | 54/949 (5.7%) | 38/949 (4.0%) | 90/949 (9.5%)
Mean ± standard deviation | 5.7% ± 3.6% | 4.0% ± 3.6% | 9.5% ± 4.8%
Range | 0%–12% | 0%–14% | 2%–22%

^a^ Data as of June 2013.

Table D-5 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | – | – | 1
Moribund | 7 | 8 | 10 | 11
Natural deaths | 4 | 5 | 3 | 5
Survivors
Terminal kill | 39 | 37 | 37 | 33
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (46) | (49) | (41) | (41)
Epithelium, hyperplasia | – | 1 (2%) | – | –
Intestine large, cecum | (50) | (50) | (49) | (50)
Hyperplasia | – | 1 (2%) | – | –
Inflammation, chronic active | – | – | 1 (2%) | –
Intestine large, colon | (49) | (50) | (49) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Intestine small, duodenum | (47) | (50) | (50) | (49)
Intestine small, ileum | (49) | (50) | (49) | (49)
Inflammation, chronic active | – | – | 1 (2%) | –
Intestine small, jejunum | (48) | (50) | (48) | (48)
Liver | (50) | (50) | (50) | (50)
Amyloid deposition | – | – | – | 1 (2%)
Angiectasis | – | 2 (4%) | 1 (2%) | 2 (4%)
Basophilic focus | 6 (12%) | 5 (10%) | 3 (6%) | 4 (8%)
Clear cell focus | 1 (2%) | – | – | –
Cyst | – | 1 (2%) | – | 1 (2%)
Degeneration | – | 1 (2%) | – | –
Eosinophilic focus | 6 (12%) | 1 (2%) | 5 (10%) | 13 (26%)
Fatty change | 3 (6%) | 2 (4%) | 1 (2%) | 5 (10%)
Hyperplasia | – | 1 (2%) | – | –
Infiltration cellular, lymphocyte | – | 1 (2%) | – | 1 (2%)
Infiltration cellular, mixed cell | – | 1 (2%) | – | –
Inflammation, chronic active | – | – | 1 (2%) | –
Mixed cell focus | 2 (4%) | 4 (8%) | 1 (2%) | –
Necrosis | 2 (4%) | – | 2 (4%) | 4 (8%)
Tension lipidosis | 6 (12%) | 5 (10%) | 5 (10%) | 6 (12%)
Vacuolization cytoplasmic | 1 (2%) | – | – | –
Centrilobular, degeneration, acute | – | 1 (2%) | – | –
Centrilobular, hypertrophy | – | – | 1 (2%) | –
Centrilobular, necrosis | – | 1 (2%) | – | –
Mesentery | (16) | (23) | (21) | (15)
Angiectasis | 1 (6%) | – | – | –
Cyst | 1 (6%) | – | – | –
Fibrosis | – | – | 1 (5%) | –
Inflammation, suppurative | – | – | 1 (5%) | –
Inflammation, chronic active | 1 (6%) | 1 (4%) | 1 (5%) | –
Necrosis | – | 1 (4%) | 1 (5%) | –
Arteriole, inflammation, chronic active | – | – | 1 (5%) | –
Fat, cyst | – | – | 1 (5%) | –
Fat, necrosis | 11 (69%) | 17 (74%) | 7 (33%) | 8 (53%)
Vein, inflammation, chronic active | – | – | – | 1 (7%)
Pancreas | (50) | (50) | (50) | (50)
Cyst | – | 1 (2%) | – | –
Fibrosis | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | 1 (2%)
Lipomatosis | – | 1 (2%) | – | 1 (2%)
Acinus, atrophy | 1 (2%) | – | 1 (2%) | 2 (4%)
Acinus, hyperplasia | – | – | – | 1 (2%)
Acinus, hypertrophy | – | – | 1 (2%) | 1 (2%)
Salivary glands | (50) | (50) | (50) | (49)
Stomach, forestomach | (50) | (50) | (50) | (50)
Fibrosis | 1 (2%) | – | – | –
Hyperplasia, squamous | 1 (2%) | 1 (2%) | 2 (4%) | 2 (4%)
Inflammation, chronic active | – | – | – | 1 (2%)
Ulcer | – | 1 (2%) | 1 (2%) | 1 (2%)
Arteriole, inflammation, chronic active | – | – | 1 (2%) | –
Stomach, glandular | (50) | (50) | (50) | (50)
Degeneration, hyaline | 1 (2%) | – | – | –
Fibrosis | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | – | – | –
Ulcer | – | – | – | 1 (2%)
Arteriole, inflammation, chronic active | – | – | 1 (2%) | –
Glands, mineralization | – | – | 2 (4%) | 1 (2%)
Tooth | (1) | (0) | (2) | (4)
Dysplasia | 1 (100%) | – | 2 (100%) | 3 (75%)
Inflammation, chronic active | – | – | – | 2 (50%)
Cardiovascular System
Blood vessel | (46) | (44) | (49) | (44)
Inflammation, chronic active | – | – | 1 (2%) | –
Aorta, embolus bacterial | 1 (2%) | – | – | 1 (2%)
Aorta, inflammation, suppurative | – | – | – | 1 (2%)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 1 (2%) | 3 (6%) | 8 (16%) | 5 (10%)
Congestion | – | 1 (2%) | – | 1 (2%)
Mineralization | – | – | 1 (2%) | –
Necrosis | 1 (2%) | 1 (2%) | – | 1 (2%)
Thrombosis | – | 1 (2%) | – | –
Artery, inflammation, chronic active | 1 (2%) | – | – | –
Capillary, hyperplasia | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (49) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Atrophy | – | – | 1 (2%) | 1 (2%)
Degeneration, cystic | – | 1 (2%) | – | –
Hyperplasia | 10 (20%) | 5 (10%) | 10 (20%) | 6 (12%)
Vacuolization cytoplasmic | 2 (4%) | 2 (4%) | – | 2 (4%)
Adrenal medulla | (49) | (50) | (49) | (50)
Hyperplasia | 2 (4%) | 1 (2%) | 2 (4%) | 4 (8%)
Islets, pancreatic | (50) | (50) | (50) | (49)
Parathyroid gland | (26) | (29) | (22) | (25)
Cyst | – | 1 (3%) | – | –
Hyperplasia | 1 (4%) | – | – | –
Pituitary gland | (50) | (50) | (49) | (50)
Angiectasis | 2 (4%) | 1 (2%) | – | 4 (8%)
Pars distalis, cyst | – | 1 (2%) | – | 1 (2%)
Pars distalis, hyperplasia | 17 (34%) | 21 (42%) | 19 (39%) | 24 (48%)
Pars intermedia, pars nervosa, cyst | – | – | – | 1 (2%)
Thyroid gland | (50) | (48) | (50) | (50)
Inflammation, chronic active | – | 1 (2%) | 2 (4%) | 2 (4%)
C-cell, hyperplasia | 1 (2%) | 1 (2%) | – | –
Follicle, cyst | – | 1 (2%) | – | –
Follicular cell, hyperplasia | 1 (2%) | 1 (2%) | 2 (4%) | 3 (6%)
General Body System
Tissue NOS | (3) | (2) | (0) | (0)
Mediastinum, infiltration cellular, lymphocyte | 1 (33%) | – | – | –
Mediastinum, thrombosis | 1 (33%) | – | – | –
Genital System
Clitoral gland | (44) | (45) | (43) | (44)
Hyperplasia, basal cell | – | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | 1 (2%) | 1 (2%) | –
Ovary | (50) | (50) | (48) | (50)
Angiectasis | 3 (6%) | 2 (4%) | – | 3 (6%)
Cyst | 14 (28%) | 12 (24%) | 12 (25%) | 16 (32%)
Hemorrhage | 12 (24%) | 16 (32%) | 7 (15%) | 15 (30%)
Infiltration cellular, lymphocyte | – | 1 (2%) | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | 2 (4%) | 3 (6%) | 2 (4%)
Mineralization | 1 (2%) | – | – | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Thrombosis | – | – | – | 1 (2%)
Corpus luteum, hyperplasia | 3 (6%) | 1 (2%) | – | –
Uterus | (50) | (50) | (50) | (50)
Angiectasis | 5 (10%) | 3 (6%) | 1 (2%) | 1 (2%)
Atrophy | 1 (2%) | – | – | –
Decidual reaction | 1 (2%) | – | – | –
Dilatation | 6 (12%) | 5 (10%) | 8 (16%) | 6 (12%)
Hemorrhage | – | – | – | 1 (2%)
Inflammation, suppurative | 1 (2%) | – | – | –
Inflammation, chronic active | 2 (4%) | 2 (4%) | 3 (6%) | 4 (8%)
Thrombosis | 1 (2%) | – | – | –
Endometrium, hyperplasia, cystic | 28 (56%) | 29 (58%) | 33 (66%) | 34 (68%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (11) | (12) | (16) | (10)
Ectasia | – | – | – | 1 (10%)
Hemorrhage | 1 (9%) | – | – | –
Iliac, angiectasis | – | 1 (8%) | – | –
Iliac, ectasia | 1 (9%) | – | – | –
Iliac, hyperplasia, lymphoid | 1 (9%) | 1 (8%) | 1 (6%) | –
Iliac, hyperplasia, plasma cell | – | – | – | 1 (10%)
Lumbar, ectasia | 1 (9%) | 1 (8%) | 2 (13%) | –
Lumbar, hyperplasia, lymphoid | – | 1 (8%) | – | 1 (10%)
Lumbar, infiltration cellular, histiocyte | – | 1 (8%) | – | –
Lumbar, infiltration cellular, mixed cell | – | – | 1 (6%) | –
Pancreatic, inflammation, chronic active | 1 (9%) | – | – | –
Renal, angiectasis | – | 1 (8%) | – | –
Renal, ectasia | 1 (9%) | – | 1 (6%) | –
Renal, hyperplasia, lymphoid | – | 2 (17%) | – | –
Renal, necrosis | – | – | 1 (6%) | –
Lymph node, bronchial | (26) | (27) | (28) | (27)
Infiltration cellular, histiocyte | – | – | – | 1 (4%)
Necrosis | – | – | 1 (4%) | –
Lymph node, mandibular | (41) | (42) | (43) | (35)
Necrosis | – | – | 1 (2%) | –
Lymph node, mediastinal | (43) | (46) | (40) | (47)
Hematopoietic cell proliferation | – | 1 (2%) | – | –
Hyperplasia, lymphoid | – | 1 (2%) | – | 2 (4%)
Infiltration cellular, mixed cell | – | – | – | 1 (2%)
Lymph node, mesenteric | (48) | (50) | (49) | (49)
Angiectasis | – | 1 (2%) | 2 (4%) | 1 (2%)
Ectasia | – | – | 2 (4%) | –
Hematopoietic cell proliferation | – | 1 (2%) | – | –
Hemorrhage | – | 2 (4%) | – | –
Hyperplasia, lymphoid | – | – | 1 (2%) | –
Infiltration cellular, histiocyte | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (49)
Hematopoietic cell proliferation | 4 (8%) | 3 (6%) | 3 (6%) | 2 (4%)
Hyperplasia, lymphoid | – | 1 (2%) | 1 (2%) | 1 (2%)
Infiltration cellular, mast cell | – | – | – | 1 (2%)
Lymphoid follicle, hyperplasia | – | – | 1 (2%) | –
Thymus | (44) | (46) | (45) | (45)
Angiectasis | – | – | 1 (2%) | –
Atrophy | 2 (5%) | – | – | 1 (2%)
Hyperplasia, lymphoid | 1 (2%) | – | – | –
Necrosis | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Hyperplasia | 2 (4%) | – | – | 1 (2%)
Skin | (50) | (50) | (50) | (50)
Infiltration cellular, mast cell | – | – | – | 1 (2%)
Inflammation, chronic active | – | – | 1 (2%) | 2 (4%)
Ulcer | 1 (2%) | – | 1 (2%) | 3 (6%)
Epidermis, hyperplasia | 1 (2%) | – | – | –
Subcutaneous tissue, fibrosis | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 23 (46%) | 25 (50%) | 27 (54%) | 23 (46%)
Cartilage, femur, metaphysis, hyperplasia | 1 (2%) | – | – | –
Cranium, inflammation, chronic active | 1 (2%) | – | 2 (4%) | 1 (2%)
Femur, fracture | 1 (2%) | – | – | –
Femur, tibia, arthrosis | – | – | – | 1 (2%)
Maxilla, hyperostosis | – | – | 1 (2%) | –
Pelvis, degeneration | – | – | – | 1 (2%)
Vertebra, fracture | – | – | – | 1 (2%)
Skeletal muscle | (3) | (3) | (1) | (4)
Degeneration | – | – | – | 1 (25%)
Infiltration cellular, lymphocyte | 3 (100%) | 1 (33%) | – | –
Infiltration cellular, polymorphonuclear | – | – | – | 1 (25%)
Arteriole, inflammation, chronic active | – | – | 1 (100%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 3 (6%) | 1 (2%) | 2 (4%) | 3 (6%)
Meninges, inflammation, chronic active | – | – | – | 1 (2%)
Peripheral nerve | (2) | (3) | (1) | (3)
Degeneration | – | 1 (33%) | – | 1 (33%)
Infiltration cellular, mixed cell | 1 (50%) | – | – | –
Infiltration cellular, polymorphonuclear | – | 1 (33%) | – | –
Spinal cord | (3) | (3) | (1) | (3)
Infiltration cellular, lymphocyte | – | 1 (33%) | – | –
Respiratory System
Larynx | (49) | (49) | (50) | (50)
Inflammation, chronic active | – | – | – | 10 (20%)
Metaplasia, squamous | 1 (2%) | 49 (100%) | 50 (100%) | 50 (100%)
Necrosis | – | – | – | 4 (8%)
Lung | (50) | (50) | (50) | (50)
Congestion | – | – | – | 1 (2%)
Hemorrhage | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Infiltration cellular, histiocyte | 4 (8%) | 1 (2%) | 1 (2%) | 6 (12%)
Infiltration cellular, lymphocyte | – | 1 (2%) | – | –
Infiltration cellular, mixed cell | – | – | – | 1 (2%)
Metaplasia, osseous | – | 1 (2%) | – | –
Thrombosis | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia | 4 (8%) | 2 (4%) | 5 (10%) | 4 (8%)
Alveolus, infiltration cellular, histiocyte | 1 (2%) | – | – | –
Bronchiole, hyperplasia | 7 (14%) | 4 (8%) | 22 (44%) | 41 (82%)
Interstitium, inflammation, chronic active | 1 (2%) | – | – | 1 (2%)
Perivascular, inflammation, chronic active | 4 (8%) | 3 (6%) | – | 11 (22%)
Nose | (50) | (49) | (50) | (50)
Inflammation, chronic active | 9 (18%) | – | 3 (6%) | 5 (10%)
Necrosis | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Olfactory epithelium, accumulation, hyaline droplet | 25 (50%) | 40 (82%) | 50 (100%) | 49 (98%)
Olfactory epithelium, atrophy | 1 (2%) | 1 (2%) | – | 1 (2%)
Olfactory epithelium, metaplasia, respiratory | 3 (6%) | 4 (8%) | 12 (24%) | 23 (46%)
Respiratory epithelium, accumulation, hyaline droplet | 34 (68%) | 48 (98%) | 50 (100%) | 50 (100%)
Respiratory epithelium, hyperplasia | 39 (78%) | 48 (98%) | 39 (78%) | 39 (78%)
Respiratory epithelium, metaplasia, squamous | – | 1 (2%) | – | 1 (2%)
Respiratory epithelium, necrosis | – | 1 (2%) | – | –
Trachea | (49) | (49) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Atrophy | – | – | 2 (4%) | –
Cornea, inflammation, chronic active | – | 1 (2%) | – | 1 (2%)
Lens, degeneration | 2 (4%) | – | 2 (4%) | 1 (2%)
Harderian gland | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | 1 (2%) | –
Hyperplasia | 2 (4%) | 1 (2%) | 6 (12%) | –
Inflammation, suppurative | – | – | 1 (2%) | –
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Accumulation, hyaline droplet | 1 (2%) | 1 (2%) | – | –
Infarct | 1 (2%) | 4 (8%) | 4 (8%) | 1 (2%)
Inflammation, suppurative | – | – | – | 1 (2%)
Metaplasia, osseous | – | 1 (2%) | 2 (4%) | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Nephropathy | 47 (94%) | 46 (92%) | 49 (98%) | 47 (94%)
Glomerulus, amyloid deposition | 1 (2%) | – | – | 1 (2%)
Ureter | (0) | (0) | (1) | (0)
Urethra | (0) | (1) | (0) | (0)
Urinary bladder | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | 1 (2%) | –
Arteriole, inflammation, chronic active | – | – | 1 (2%) | –
Artery, serosa, inflammation, chronic active | – | 1 (2%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.