# Appendix C Summary of Lesions in Male Mice in the Two-year Inhalation Study of CIMSTAR 3800

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 5 | 12 | 7 | 4
Natural deaths | 6 | 7 | 7 | 6
Survivors
Terminal kill | 39 | 31 | 36 | 40
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Squamous cell papilloma | – | – | – | 1 (2%)
Gallbladder | (44) | (44) | (44) | (44)
Intestine large, cecum | (50) | (50) | (49) | (49)
Intestine large, colon | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Serosa, carcinoma, metastatic, kidney | – | – | 1 (2%) | –
Intestine large, rectum | (50) | (50) | (50) | (49)
Intestine small, duodenum | (49) | (48) | (48) | (47)
Adenoma | 1 (2%) | – | – | 1 (2%)
Carcinoma | – | – | 1 (2%) | –
Hemangiosarcoma | – | – | 1 (2%) | –
Intestine small, ileum | (50) | (50) | (49) | (48)
Hemangioma | – | – | 1 (2%) | –
Intestine small, jejunum | (50) | (48) | (49) | (48)
Adenoma | – | 1 (2%) | 1 (2%) | –
Carcinoma | – | 1 (2%) | – | –
Liver | (50) | (50) | (50) | (49)
Hemangiosarcoma, multiple | – | 1 (2%) | – | –
Hepatoblastoma | – | 1 (2%) | 1 (2%) | –
Hepatocellular adenoma | 10 (20%) | 18 (36%) | 15 (30%) | 14 (29%)
Hepatocellular adenoma, multiple | 14 (28%) | 6 (12%) | 10 (20%) | 16 (33%)
Hepatocellular carcinoma | 9 (18%) | 15 (30%) | 7 (14%) | 13 (27%)
Hepatocellular carcinoma, multiple | 2 (4%) | 2 (4%) | 1 (2%) | 2 (4%)
Hepatocholangiocarcinoma | – | – | 2 (4%) | –
Sarcoma | – | – | 1 (2%) | –
Mesentery | (4) | (5) | (3) | (4)
Hemangioma | 1 (25%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | 1 (25%) | – | – | –
Sarcoma, metastatic, liver | – | – | 1 (33%) | –
Pancreas | (50) | (50) | (50) | (50)
Carcinoma, metastatic, kidney | – | – | 1 (2%) | –
Carcinoma, metastatic, stomach, glandular | 1 (2%) | – | – | –
Sarcoma, metastatic, liver | – | – | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Stomach, glandular | (50) | (50) | (50) | (50)
Carcinoma | 1 (2%) | – | – | –
Tooth | (50) | (47) | (49) | (50)
Cardiovascular System
Blood vessel | (45) | (49) | (48) | (48)
Aorta, carcinoma, metastatic, kidney | – | – | 1 (2%) | –
Heart | (50) | (50) | (50) | (50)
Carcinoma, metastatic, kidney | – | – | 1 (2%) | –
Carcinoma, metastatic, stomach, glandular | 1 (2%) | – | – | –
Pericardium, alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | 1 (2%) | –
Endocrine System
Adrenal cortex | (49) | (50) | (50) | (50)
Adenoma | 2 (4%) | – | – | 4 (8%)
Sarcoma, metastatic, liver | – | – | 1 (2%) | –
Bilateral, subcapsular, adenoma | 1 (2%) | – | – | –
Extra adrenal tissue, carcinoma, metastatic, kidney | – | – | 1 (2%) | –
Subcapsular, adenoma | 7 (14%) | 4 (8%) | 5 (10%) | 6 (12%)
Subcapsular, adenoma, multiple | 1 (2%) | – | – | –
Adrenal medulla | (48) | (50) | (50) | (50)
Pheochromocytoma benign | – | – | 1 (2%) | –
Bilateral, pheochromocytoma benign | 1 (2%) | – | – | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | 2 (4%) | 2 (4%) | 1 (2%) | 1 (2%)
Parathyroid gland | (34) | (28) | (27) | (21)
Pituitary gland | (50) | (50) | (50) | (48)
Thyroid gland | (50) | (50) | (49) | (50)
General Body System
Tissue NOS | (0) | (2) | (0) | (1)
Mediastinum, alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (50%) | – | 1 (100%)
Mediastinum, hepatocellular carcinoma, metastatic, liver | – | 1 (50%) | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Penis | (0) | (0) | (0) | (1)
Preputial gland | (50) | (49) | (48) | (49)
Prostate gland | (50) | (49) | (50) | (50)
Seminal vesicle | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Testes | (50) | (50) | (50) | (50)
Interstitial cell, adenoma | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Mast cell tumor malignant, metastatic, skin | – | – | – | 1 (2%)
Lymph node | (4) | (3) | (1) | (1)
Renal, sarcoma, metastatic, liver | – | – | 1 (100%) | –
Lymph node, bronchial | (26) | (31) | (26) | (18)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (3%) | 1 (4%) | –
Lymph node, mandibular | (31) | (36) | (34) | (33)
Lymph node, mediastinal | (39) | (39) | (32) | (35)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (3%) | 1 (3%) | – | 1 (3%)
Carcinoma, metastatic, stomach, glandular | 1 (3%) | – | – | –
Lymph node, mesenteric | (49) | (50) | (48) | (49)
Carcinoma, metastatic, stomach, glandular | 1 (2%) | – | – | –
Hemangiosarcoma | – | 1 (2%) | – | –
Spleen | (50) | (50) | (49) | (49)
Hemangiosarcoma | – | 2 (4%) | – | –
Thymus | (41) | (38) | (39) | (41)
Carcinoma, metastatic, stomach, glandular | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (1) | (0) | (1) | (0)
Skin | (50) | (49) | (50) | (50)
Carcinoma, metastatic, kidney | – | – | 1 (2%) | –
Carcinoma, metastatic, stomach, glandular | 1 (2%) | – | – | –
Melanoma benign | 1 (2%) | – | – | 1 (2%)
Subcutaneous tissue, fibroma | – | – | 1 (2%) | –
Subcutaneous tissue, fibrous histiocytoma | – | – | 1 (2%) | –
Subcutaneous tissue, hemangiosarcoma | – | – | – | 1 (2%)
Subcutaneous tissue, mast cell tumor malignant | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Maxilla, carcinoma, metastatic, Harderian gland | – | 1 (2%) | – | –
Skeletal muscle | (1) | (3) | (2) | (3)
Carcinoma, metastatic, kidney | – | – | 1 (50%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Peripheral nerve | (1) | (2) | (1) | (2)
Spinal cord | (1) | (3) | (1) | (2)
Respiratory System
Larynx | (50) | (50) | (49) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 5 (10%) | 2 (4%) | 8 (16%) | 9 (18%)
Alveolar/bronchiolar carcinoma | 7 (14%) | 7 (14%) | 8 (16%) | 5 (10%)
Alveolar/bronchiolar carcinoma, multiple | 1 (2%) | 1 (2%) | – | 5 (10%)
Carcinoma, metastatic, Harderian gland | 1 (2%) | – | – | –
Carcinoma, metastatic, kidney | – | – | 1 (2%) | –
Carcinoma, metastatic, stomach, glandular | 1 (2%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | 5 (10%) | 9 (18%) | 1 (2%) | 3 (6%)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Mast cell tumor malignant, metastatic, uncertain primary site | – | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Pleura | (1) | (0) | (0) | (0)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (100%) | – | – | –
Trachea | (50) | (50) | (47) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (49) | (50)
Adenoma | 7 (14%) | 3 (6%) | 4 (8%) | 2 (4%)
Carcinoma | 4 (8%) | 5 (10%) | 1 (2%) | 1 (2%)
Bilateral, adenoma | – | – | – | 1 (2%)
Bilateral, carcinoma | 1 (2%) | – | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Carcinoma, metastatic, stomach, glandular | 1 (2%) | – | – | –
Renal tubule, adenoma | – | – | 1 (2%) | 1 (2%)
Renal tubule, carcinoma | – | – | 1 (2%) | –
Ureter | (0) | (0) | (0) | (1)
Urinary bladder | (50) | (50) | (50) | (49)
Hemangiosarcoma | 1 (2%) | – | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | – | 1 (2%) | –
Lymphoma malignant | 3 (6%) | 5 (10%) | 1 (2%) | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 46 | 46 | 40 | 44
Total primary neoplasms | 83 | 80 | 75 | 86
Total animals with benign neoplasms | 39 | 33 | 33 | 38
Total benign neoplasms | 53 | 39 | 48 | 57
Total animals with malignant neoplasms | 26 | 31 | 17 | 22
Total malignant neoplasms | 30 | 41 | 27 | 29
Total animals with metastatic neoplasms | 8 | 11 | 4 | 6
Total metastatic neoplasms | 17 | 15 | 16 | 7
Total animals with malignant neoplasms of uncertain primary site | – | – | – | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Adrenal Cortex: Adenoma
Overall rate^a^ | 9/49 (18%) | 4/50 (8%) | 5/50 (10%) | 10/50 (20%)
Adjusted rate^b^ | 19.5% | 9.2% | 11.3% | 21.3%
Terminal rate^c^ | 8/39 (21%) | 3/31 (10%) | 4/36 (11%) | 9/40 (23%)
First incidence (days) | 669 | 591 | 698 | 623
Poly-3 test^d^ | P = 0.212 | P = 0.136N | P = 0.212N | P = 0.517
Harderian Gland: Adenoma
Overall rate | 7/50 (14%) | 3/50 (6%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate | 15.0% | 7.0% | 9.0% | 6.4%
Terminal rate | 7/39 (18%) | 3/31 (10%) | 3/36 (8%) | 2/40 (5%)
First incidence (days) | 729 (T) | 729 (T) | 715 | 607
Poly-3 test | P = 0.210N | P = 0.191N | P = 0.290N | P = 0.156N
Harderian Gland: Carcinoma
Overall rate | 5/50 (10%) | 5/50 (10%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 10.7% | 11.4% | 2.3% | 2.2%
Terminal rate | 4/39 (10%) | 2/31 (7%) | 1/36 (3%) | 1/40 (3%)
First incidence (days) | 709 | 632 | 729 (T) | 729 (T)
Poly-3 test | P = 0.053N | P = 0.588 | P = 0.114N | P = 0.103N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 12/50 (24%) | 8/50 (16%) | 5/50 (10%) | 4/50 (8%)
Adjusted rate | 25.7% | 18.3% | 11.3% | 8.5%
Terminal rate | 11/39 (28%) | 5/31 (16%) | 4/36 (11%) | 3/40 (8%)
First incidence (days) | 709 | 632 | 715 | 607
Poly-3 test | P = 0.027N | P = 0.276N | P = 0.065N | P = 0.025N
Liver: Hepatocellular Adenoma
Overall rate | 24/50 (48%) | 24/50 (48%) | 25/50 (50%) | 30/49 (61%)
Adjusted rate | 49.5% | 51.7% | 55.0% | 62.1%
Terminal rate | 20/39 (51%) | 14/31 (45%) | 20/36 (56%) | 24/50 (63%)
First incidence (days) | 499 | 547 | 636 | 344
Poly-3 test | P = 0.110 | P = 0.497 | P = 0.370 | P = 0.145
Liver: Hepatocellular Carcinoma
Overall rate | 11/50 (22%) | 17/50 (34%) | 8/50 (16%) | 15/49 (31%)
Adjusted rate | 23.0% | 36.7% | 17.5% | 31.5%
Terminal rate | 5/39 (13%) | 7/31 (23%) | 4/36 (11%) | 9/40 (23%)
First incidence (days) | 565 | 547 | 438 | 572
Poly-3 test | P = 0.362 | P = 0.107 | P = 0.344N | P = 0.239
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 32/50 (64%) | 32/50 (64%) | 31/50 (62%) | 35/49 (71%)
Adjusted rate | 65.0% | 67.0% | 66.4% | 71.6%
Terminal rate | 23/39 (59%) | 18/31 (58%) | 23/36 (64%) | 27/40 (68%)
First incidence (days) | 499 | 547 | 438 | 344
Poly-3 test | P = 0.281 | P = 0.503 | P = 0.529 | P = 0.316
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 11/50 (22%) | 18/50 (36%) | 8/50 (16%) | 15/49 (31%)
Adjusted rate | 23.0% | 38.9% | 17.5% | 31.5%
Terminal rate | 5/39 (3%) | 8/31 (26%) | 4/36 (11%) | 9/40 (23%)
First incidence (days) | 565 | 547 | 438 | 572
Poly-3 test | P = 0.403 | P = 0.071 | P = 0.344N | P = 0.239
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 32/50 (64%) | 33/50 (66%) | 31/50 (62%) | 35/49 (71%)
Adjusted rate | 65.0% | 69.1% | 66.4% | 71.6%
Terminal rate | 23/39 (59%) | 19/31 (61%) | 23/36 (64%) | 27/40 (68%)
First incidence (days) | 499 | 547 | 438 | 344
Poly-3 test | P = 0.315 | P = 0.416 | P = 0.529 | P = 0.316
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 5/50 (10%) | 2/50 (4%) | 8/50 (16%) | 9/50 (18%)
Adjusted rate | 10.7% | 4.6% | 17.8 | 19.0%
Terminal rate | 5/39 (13%) | 2/31 (7%) | 6/36 (17%) | 7/40 (18%)
First incidence (days) | 729 (T) | 729 (T) | 573 | 590
Poly-3 test | P = 0.068 | P = 0.249N | P = 0.250 | P = 0.200
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 8/50 (16%) | 8/50 (16%) | 8/50 (16%) | 10/50 (20%)
Adjusted rate | 16.8% | 18.0% | 17.2% | 20.9%
Terminal rate | 6/39 (15%) | 4/31 (13%) | 3/36 (8%) | 6/40 (15%)
First incidence (days) | 541 | 547 | 534 | 590
Poly-3 test | P = 0.354 | P = 0.552 | P = 0.590 | P = 0.403
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 13/50 (26%) | 9/50 (18%) | 14/50 (28%) | 17/50 (34%)
Adjusted rate | 27.4% | 20.2% | 30.1% | 35.3%
Terminal rate | 11/39 (28%) | 5/31 (16%) | 8/36 (22%) | 12/40 (30%)
First incidence (days) | 541 | 547 | 534 | 590
Poly-3 test | P = 0.120 | P = 0.288N | P = 0.476 | P = 0.270
All Organs: Hemangiosarcoma
Overall rate | 1/50 (2%) | 4/50 (8%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 2.1% | 9.0% | 2.3% | 2.2%
Terminal rate | 0/39 (0%) | 1/31 (3%) | 1/36 (3%) | 1/40 (3%)
First incidence (days) | 559 | 547 | 729 (T) | 729 (T)
Poly-3 test | P = 0.347N | P = 0.162 | P = 0.746 | P = 0.757
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 2/50 (4%) | 4/50 (8%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 4.2% | 9.0% | 4.5% | 2.2%
Terminal rate | 1/39 (3%) | 1/31 (3%) | 2/36 (6%) | 1/40 (3%)
First incidence (days) | 559 | 547 | 729 (T) | 729 (T)
Poly-3 test | P = 0.241N | P = 0.311 | P = 0.671 | P = 0.506N
All Organs: Malignant Lymphoma
Overall rate | 3/50 (6%) | 5/50 (10%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 6.4% | 11.4% | 2.3% | 2.2%
Terminal rate | 2/39 (5%) | 3/31 (10%) | 1/36 (3%) | 1/40 (3%)
First incidence (days) | 724 | 628 | 729 (T) | 729 (T)
Poly-3 test | P = 0.125N | P = 0.321 | P = 0.324N | P = 0.307N
All Organs: Benign Neoplasms
Overall rate | 39/50 (78%) | 33/50 (66%) | 33/50 (66%) | 38/50 (76%)
Adjusted rate | 79.7% | 69.8% | 70.7% | 76.8%
Terminal rate | 32/39 (82%) | 21/31 (68%) | 25/36 (69%) | 31/40 (78%)
First incidence (days) | 499 | 547 | 534 | 344
Poly-3 test | P = 0.478 | P = 0.182N | P = 0.211N | P = 0.458N
All Organs: Malignant Neoplasms
Overall rate | 26/50 (52%) | 31/50 (62%) | 17/50 (34%) | 23/50 (46%)
Adjusted rate | 52.7% | 64.7% | 35.6% | 46.9%
Terminal rate | 16/39 (41%) | 16/31 (52%) | 9/36 (25%) | 15/40 (38%)
First incidence (days) | 541 | 547 | 438 | 572
Poly-3 test | P = 0.170N | P = 0.159 | P = 0.066N | P = 0.355N
All Organs: Benign or Malignant Neoplasms
Overall rate | 46/50 (92%) | 46/50 (92%) | 40/50 (80%) | 44/50 (88%)
Adjusted rate | 92.0% | 93.5% | 82.3% | 88.1%
Terminal rate | 35/39 (90%) | 28/31 (90%) | 28/36 (78%) | 35/40 (88%)
First incidence (days) | 499 | 547 | 438 | 344
Poly-3 test | P = 0.306N | P = 0.542 | P = 0.122N | P = 0.379N

T = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, and lung; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

Table C-3 Historical Incidence of Alveolar/Bronchiolar Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 6/50 | 8/50 | 13/50
CIMSTAR 3800 (May 2008) | 5/50 | 8/50 | 13/50
Cobalt metal (May 2006) | 7/50 | 11/50 | 16/50
Diethylamine (August 2003) | 4/50 | 12/50 | 15/50
Tetralin (June 2003) | 10/50 | 11/50 | 20/50
Vinylidene chloride (June 2005) | 7/50 | 9/50 | 13/50
Total (%) | 39/300 (13.0%) | 59/300 (19.7%) | 90/300 (30.0%)
Mean ± standard deviation | 13.0% ± 4.2% | 19.7% ± 3.4% | 30.0% ± 5.5%
Range | 8%–20% | 16%–24% | 26%–40%
Overall Historical Incidence: All Routes
Total (%) | 145/950 (15.3%) | 132/950 (13.9%) | 263/950 (27.7%)
Mean ± standard deviation | 15.3% ± 6.2% | 13.9% ± 7.1% | 27.7% ± 5.7%
Range | 2%–26% | 4%–24% | 16%–40%

^a^ Data as of June 2013.

Table C-4 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 5 | 12 | 7 | 4
Natural deaths | 6 | 7 | 7 | 6
Survivors
Terminal kill | 39 | 31 | 36 | 40
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (44) | (44) | (44) | (44)
Cytoplasmic alteration | – | – | – | 1 (2%)
Inflammation, suppurative | 1 (2%) | – | – | 1 (2%)
Intestine large, cecum | (50) | (50) | (49) | (49)
Hemorrhage | – | – | 1 (2%) | –
Intestine large, colon | (50) | (50) | (50) | (50)
Ulcer | – | 1 (2%) | – | –
Intestine large, rectum | (50) | (50) | (50) | (49)
Cyst | – | 1 (2%) | – | –
Fibrosis | – | 1 (2%) | – | –
Intestine small, duodenum | (49) | (48) | (48) | (47)
Artery, infiltration cellular, lymphocyte | 1 (2%) | – | – | –
Intestine small, ileum | (50) | (50) | (49) | (48)
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Inflammation, chronic active | – | – | 2 (4%) | 2 (4%)
Epithelium, hyperplasia | 1 (2%) | – | – | –
Lymphoid follicle, hyperplasia | 1 (2%) | – | – | –
Peyer’s patch, hyperplasia, lymphoid | 1 (2%) | – | – | –
Intestine small, jejunum | (50) | (48) | (49) | (48)
Inflammation, chronic active | – | – | 1 (2%) | –
Serosa, inflammation, granulomatous | – | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (49)
Angiectasis | – | 1 (2%) | – | –
Basophilic focus | 1 (2%) | 3 (6%) | – | 4 (8%)
Clear cell focus | 10 (20%) | 9 (18%) | 3 (6%) | 6 (12%)
Congestion | – | 1 (2%) | 1 (2%) | –
Cyst | – | 1 (2%) | 1 (2%) | –
Eosinophilic focus | 14 (28%) | 3 (6%) | 20 (40%) | 17 (35%)
Fatty change | 24 (48%) | 22 (44%) | 24 (48%) | 25 (51%)
Hepatodiaphragmatic nodule | 1 (2%) | – | 1 (2%) | –
Hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | –
Infiltration cellular, lymphocyte | – | – | 1 (2%) | –
Inflammation, chronic | 1 (2%) | – | – | –
Inflammation, chronic active | – | – | – | 1 (2%)
Mixed cell focus | 6 (12%) | 4 (8%) | 11 (22%) | 5 (10%)
Necrosis | 5 (10%) | 7 (14%) | 6 (12%) | 7 (14%)
Tension lipidosis | 3 (6%) | 2 (4%) | 5 (10%) | 7 (14%)
Mesentery | (4) | (5) | (3) | (4)
Inflammation, chronic active | – | 1 (20%) | 1 (33%) | –
Arteriole, inflammation, chronic active | – | 1 (20%) | – | –
Artery, inflammation, chronic active | – | – | – | 1 (25%)
Fat, necrosis | 1 (25%) | 2 (40%) | 2 (67%) | 3 (75%)
Pancreas | (50) | (50) | (50) | (50)
Fibrosis | 1 (2%) | – | – | –
Lipomatosis | – | 1 (2%) | – | –
Necrosis | – | – | – | 1 (2%)
Acinus, hypertrophy | 1 (2%) | 1 (2%) | – | –
Artery, inflammation, chronic active | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Infiltration cellular, lymphocyte | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Cyst, squamous | – | 1 (2%) | – | –
Hyperplasia, squamous | 2 (4%) | 2 (4%) | 1 (2%) | 3 (6%)
Inflammation, chronic active | 1 (2%) | 2 (4%) | 1 (2%) | –
Ulcer | – | – | 1 (2%) | –
Stomach, glandular | (50) | (50) | (50) | (50)
Erosion | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | 2 (4%)
Ulcer | – | – | – | 1 (2%)
Arteriole, serosa, inflammation, chronic active | – | 1 (2%) | – | –
Glands, mineralization | – | – | 2 (4%) | 1 (2%)
Tooth | (50) | (47) | (49) | (50)
Dysplasia | 43 (86%) | 35 (74%) | 41 (84%) | 40 (80%)
Inflammation, chronic active | 3 (6%) | 1 (2%) | 6 (12%) | 5 (10%)
Cardiovascular System
Blood vessel | (45) | (49) | (48) | (48)
Inflammation, chronic active | 1 (2%) | – | – | –
Aorta, inflammation, chronic active | – | 1 (2%) | – | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 2 (4%) | 3 (6%) | 1 (2%) | 2 (4%)
Inflammation, suppurative | – | – | 1 (2%) | –
Inflammation, chronic active | – | – | – | 1 (2%)
Thrombosis | 1 (2%) | – | – | 2 (4%)
Artery, inflammation, chronic active | – | 1 (2%) | – | 1 (2%)
Valve, fibrosis | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (49) | (50) | (50) | (50)
Hyperplasia | 24 (49%) | 23 (46%) | 26 (52%) | 24 (48%)
Capsule, inflammation, chronic active | 1 (2%) | – | – | –
Adrenal medulla | (48) | (50) | (50) | (50)
Hyperplasia | – | 1 (2%) | – | 2 (4%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Parathyroid gland | (34) | (28) | (27) | (21)
Cyst | 1 (3%) | – | – | –
Pituitary gland | (50) | (50) | (50) | (48)
Angiectasis | – | – | – | 1 (2%)
Pars distalis, cyst | 1 (2%) | – | – | 1 (2%)
Pars distalis, hyperplasia | 5 (10%) | 8 (16%) | 7 (14%) | 2 (4%)
Pars intermedia, hypertrophy | – | 1 (2%) | – | –
Thyroid gland | (50) | (50) | (49) | (50)
Inflammation, chronic active | – | – | 1 (2%) | –
Follicular cell, hyperplasia | – | – | 1 (2%) | 1 (2%)
General Body System
Tissue NOS | (0) | (2) | (0) | (1)
Genital System
Epididymis | (50) | (50) | (50) | (50)
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | 2 (4%)
Spermatocele | – | 1 (2%) | – | –
Penis | (0) | (0) | (0) | (1)
Congestion | – | – | – | 1 (100%)
Preputial gland | (50) | (49) | (48) | (49)
Ectasia | 8 (16%) | 4 (8%) | 7 (15%) | 7 (14%)
Inflammation, chronic active | 9 (18%) | 4 (8%) | 11 (23%) | 4 (8%)
Prostate gland | (50) | (49) | (50) | (50)
Seminal vesicle | (50) | (50) | (50) | (50)
Dilatation | – | – | 1 (2%) | 1 (2%)
Testes | (50) | (50) | (50) | (50)
Angiectasis | – | – | – | 1 (2%)
Nuclear alteration, focal | – | 1 (2%) | – | –
Germinal epithelium, atrophy | 1 (2%) | 4 (8%) | – | 3 (6%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hyperplasia | – | – | 1 (2%) | –
Hyperplasia, granulocytes | – | – | – | 1 (2%)
Lymph node | (4) | (3) | (1) | (1)
Lumbar, infiltration cellular, mixed cell | 1 (25%) | – | – | –
Lumbar, inflammation, pyogranulomatous | – | – | – | 1 (100%)
Lumbar, lymphoid follicle, hyperplasia | 1 (25%) | – | – | –
Lymphoid follicle, renal, hyperplasia | 1 (25%) | – | – | –
Pancreatic, inflammation, pyogranulomatous | – | – | – | 1 (100%)
Renal, inflammation, pyogranulomatous | – | – | – | 1 (100%)
Lymph node, bronchial | (26) | (31) | (26) | (18)
Infiltration cellular, polymorphonuclear | 1 (4%) | – | – | –
Lymph node, mandibular | (31) | (36) | (34) | (33)
Hyperplasia, lymphoid | – | 2 (6%) | 1 (3%) | –
Infiltration, cellular, plasma cell | – | 1 (3%) | – | –
Inflammation, pyogranulomatous | – | – | – | 1 (3%)
Lymph node, mediastinal | (39) | (39) | (32) | (35)
Hematopoietic cell proliferation | – | – | 1 (3%) | –
Hyperplasia, plasma cell | – | – | 1 (3%) | –
Infiltration cellular, mixed cell | – | – | 1 (3%) | –
Infiltration, pyogranulomatous | – | – | – | 1 (3%)
Lymphoid follicle, hyperplasia | 1 (3%) | – | – | –
Lymph node, mesenteric | (49) | (50) | (48) | (49)
Fibrosis | 1 (2%) | – | – | –
Hemorrhage | – | 1 (2%) | 1 (2%) | –
Hyperplasia, plasma cell | – | – | 1 (2%) | –
Infiltration cellular, histiocyte | – | – | 1 (2%) | –
Inflammation, pyogranulomatous | – | – | – | 1 (2%)
Lymphoid follicle, hyperplasia | 1 (2%) | – | – | –
Spleen | (50) | (50) | (49) | (49)
Congestion | – | – | 1 (2%) | –
Fibrosis | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 1 (2%) | 1 (2%) | 3 (6%) | 1 (2%)
Lymphoid follicle, hyperplasia | 3 (6%) | 2 (4%) | 1 (2%) | 1 (2%)
Thymus | (41) | (38) | (39) | (41)
Atrophy | – | – | 1 (3%) | 1 (2%)
Integumentary System
Mammary gland | (1) | (0) | (1) | (0)
Skin | (50) | (49) | (50) | (50)
Abscess | – | – | – | 1 (2%)
Angiectasis | – | – | 1 (2%) | –
Inflammation, chronic active | 2 (4%) | 4 (8%) | 1 (2%) | 3 (6%)
Ulcer | 1 (2%) | 4 (8%) | 2 (4%) | –
Epidermis, hyperplasia | – | – | – | 1 (2%)
Sebaceous gland, hyperplasia | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 7 (14%) | 7 (14%) | 10 (20%) | 7 (14%)
Cranium, fracture | – | 1 (2%) | – | –
Cranium, inflammation, chronic active | 3 (6%) | 2 (4%) | 3 (6%) | 5 (10%)
Joint, vertebra, fracture | – | 1 (2%) | – | –
Maxilla, necrosis | – | 1 (2%) | – | –
Skeletal muscle | (1) | (3) | (2) | (3)
Infiltration cellular, lymphocyte | – | 1 (33%) | – | –
Infiltration cellular, mixed cell | – | – | – | 1 (33%)
Inflammation, chronic active | – | – | – | 1 (33%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | – | 1 (2%) | –
Thrombosis | – | – | 1 (2%) | –
Arteriole, inflammation, chronic active | – | 1 (2%) | – | –
Ventricle, dilatation | – | – | 1 (2%) | –
Venule, infiltration cellular, lymphoid | – | 1 (2%) | – | –
Peripheral nerve | (1) | (2) | (1) | (2)
Spinal cord | (1) | (3) | (1) | (2)
Respiratory System
Larynx | (50) | (50) | (49) | (50)
Hyperplasia | – | – | 1 (2%) | –
Inflammation, suppurative | – | 1 (2%) | – | 1 (2%)
Inflammation, chronic active | – | 2 (4%) | 3 (6%) | 8 (16%)
Metaplasia, squamous | – | 50 (100%) | 49 (100%) | 50 (100%)
Necrosis | – | 1 (2%) | 1 (2%) | 1 (2%)
Lung | (50) | (50) | (50) | (50)
Congestion | – | – | 1 (2%) | –
Erythrophagocytosis | – | 1 (2%) | – | –
Hemorrhage | – | – | 2 (4%) | 1 (2%)
Infiltration cellular, histiocyte | 5 (10%) | 5 (10%) | 1 (2%) | 9 (18%)
Inflammation, acute | – | – | 1 (2%) | –
Thrombosis | 1 (2%) | – | – | –
Alveolar epithelium, hyperplasia | 4 (8%) | 4 (8%) | 6 (12%) | 7 (14%)
Bronchiole, hyperplasia | 11 (22%) | 11 (22%) | 32 (64%) | 44 (88%)
Interstitium, inflammation, chronic active | 1 (2%) | – | 1 (2%) | 1 (2%)
Perivascular, inflammation, chronic active | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Inflammation, chronic active | 6 (12%) | 8 (16%) | 4 (8%) | 12 (24%)
Necrosis | 2 (4%) | 2 (4%) | – | 1 (2%)
Nasopharyngeal duct, necrosis | – | – | – | 1 (2%)
Olfactory epithelium, accumulation, hyaline droplet | 4 (8%) | 31 (62%) | 43 (86%) | 49 (98%)
Olfactory epithelium, atrophy | 1 (2%) | – | – | 4 (8%)
Olfactory epithelium, metaplasia, respiratory | 7 (14%) | 15 (30%) | 25 (50%) | 37 (74%)
Olfactory epithelium, necrosis | – | 1 (2%) | – | –
Respiratory epithelium, accumulation, hyaline droplet | 7 (14%) | 36 (72%) | 50 (100%) | 50 (100%)
Respiratory epithelium, hyperplasia | 38 (76%) | 44 (88%) | 36 (72%) | 41 (82%)
Respiratory epithelium, metaplasia, squamous | – | 3 (6%) | – | 1 (2%)
Turbinate, atrophy | – | – | – | 1 (2%)
Turbinate, degeneration | 1 (2%) | 1 (2%) | – | –
Pleura | (1) | (0) | (0) | (0)
Trachea | (50) | (50) | (47) | (50)
Ulcer | – | – | – | 1 (2%)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | – | –
Cornea, hyperplasia, squamous | – | – | – | 1 (2%)
Cornea, inflammation, chronic active | – | 4 (8%) | 2 (4%) | 2 (4%)
Cornea, vacuolization cytoplasmic | 2 (4%) | – | – | –
Lens, degeneration | 1 (2%) | 1 (2%) | – | 1 (2%)
Harderian gland | (50) | (50) | (49) | (50)
Cyst | – | 1 (2%) | – | –
Hyperplasia | 2 (4%) | 1 (2%) | 3 (6%) | 2 (4%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Congestion | 1 (2%) | – | – | –
Cyst | 4 (8%) | 2 (4%) | 3 (6%) | 5 (10%)
Dilatation | 1 (2%) | – | – | –
Infarct | 3 (6%) | 1 (2%) | 4 (8%) | 2 (4%)
Inflammation, suppurative | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | – | – | –
Metaplasia, osseous | 1 (2%) | 1 (2%) | – | –
Nephropathy | 48 (96%) | 48 (96%) | 45 (90%) | 48 (96%)
Artery, hemorrhage | 1 (2%) | – | – | –
Artery, inflammation, chronic active | 1 (2%) | 3 (6%) | – | –
Capsule, fibrosis | – | 1 (2%) | – | –
Capsule, hemorrhage | – | 1 (2%) | – | –
Papilla, necrosis | – | 1 (2%) | – | –
Pelvis, inflammation, suppurative | – | 1 (2%) | – | –
Ureter | (0) | (0) | (0) | (1)
Inflammation, chronic active | – | – | – | 1 (100%)
Urinary bladder | (50) | (50) | (50) | (49)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.