# Appendix B Summary of Lesions in Female Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

Table B-1 Summary of the Incidence of Neoplasms in Female Wistar Han Rats in the Two year Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | 1 | – | –
Moribund | 13 | 16 | 14 | 19
Natural deaths | 2 | – | – | 1
Survivors
Died last week of study | 1 | 1 | – | 1
Terminal kill | 34 | 32 | 36 | 29
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (49) | (50) | (50) | (49)
Intestine large, colon | (49) | (49) | (50) | (49)
Intestine large, rectum | (46) | (50) | (47) | (46)
Intestine small, duodenum | (49) | (50) | (50) | (49)
Intestine small, ileum | (49) | (50) | (50) | (49)
Intestine small, jejunum | (49) | (50) | (50) | (49)
Liver | (50) | (50) | (50) | (50)
Hepatocellular adenoma | – | 2 (4%) | 1 (2%) | –
Mesentery | (7) | (8) | (8) | (5)
Oral mucosa | (0) | (0) | (0) | (1)
Pancreas | (49) | (50) | (50) | (50)
Carcinoma, metastatic, uterus | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Leiomyosarcoma | 1 (2%) | – | – | –
Stomach, glandular | (50) | (50) | (50) | (50)
Leiomyosarcoma | 1 (2%) | – | – | –
Tongue | (1) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Chemodectoma benign | – | – | 1 (2%) | –
Hemangioma | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | 2 (4%) | 2 (4%) | 2 (4%) | 1 (2%)
Adrenal medulla | (49) | (50) | (49) | (49)
Pheochromocytoma benign | 1 (2%) | – | 1 (2%) | –
Pheochromocytoma malignant | 1 (2%) | 1 (2%) | – | –
Islets, pancreatic | (49) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Parathyroid gland | (47) | (44) | (40) | (42)
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, adenoma | 35 (70%) | 33 (66%) | 36 (72%) | 30 (60%)
Pars intermedia, adenoma | 1 (2%) | – | – | 2 (4%)
Thyroid gland | (50) | (50) | (50) | (49)
C-cell, adenoma | 3 (6%) | 2 (4%) | 4 (8%) | 4 (8%)
C-cell, carcinoma | – | – | – | 3 (6%)
Follicular cell, adenoma | 1 (2%) | – | 3 (6%) | 1 (2%)
Follicular cell, carcinoma | 1 (2%) | 1 (2%) | – | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (46) | (50) | (49)
Ovary | (50) | (50) | (50) | (50)
Granulosa cell tumor benign | 1 (2%) | – | 1 (2%) | –
Granulosa cell tumor malignant | – | 2 (4%) | – | 1 (2%)
Uterus | (50) | (50) | (50) | (50)
Fibroma | – | – | 1 (2%) | –
Leiomyoma | – | – | 1 (2%) | –
Polyp stromal | 4 (8%) | 6 (12%) | 3 (6%) | 3 (6%)
Polyp stromal, multiple | 1 (2%) | – | – | 1 (2%)
Sarcoma stromal | 2 (4%) | – | – | –
Sarcoma stromal, multiple | – | – | – | 1 (2%)
Endometrium, adenocarcinoma | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Endometrium, malignant mixed Müllerian tumor | – | – | – | 1 (2%)
Vagina | (0) | (1) | (0) | (1)
Polyp | – | – | – | 1 (100%)
Squamous cell carcinoma | – | 1 (100%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Bronchial associated lymphoid tissue | (0) | (0) | (0) | (5)
Lymph node | (2) | (2) | (1) | (0)
Lymph node, bronchial | (38) | (35) | (32) | (35)
Lymph node, mandibular | (49) | (47) | (43) | (49)
Lymph node, mediastinal | (49) | (46) | (45) | (47)
Lymph node, mesenteric | (49) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | 1 (2%) | 1 (2%) | –
Spleen | (50) | (50) | (50) | (50)
Thymus | (48) | (48) | (45) | (45)
Thymoma benign | 5 (10%) | 4 (8%) | 7 (16%) | 3 (7%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenoma | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Carcinoma | 3 (6%) | 5 (10%) | 5 (10%) | 3 (6%)
Carcinoma, multiple | 1 (2%) | – | 4 (8%) | 1 (2%)
Fibroadenoma | 6 (12%) | 8 (16%) | 9 (18%) | 8 (16%)
Fibroadenoma, multiple | 3 (6%) | 2 (4%) | 4 (8%) | 2 (4%)
Skin | (50) | (50) | (50) | (50)
Keratoacanthoma | – | – | – | 1 (2%)
Squamous cell papilloma | – | – | – | 3 (6%)
Subcutaneous tissue, lipoma | – | – | – | 1 (2%)
Subcutaneous tissue, liposarcoma | 1 (2%) | – | – | –
Subcutaneous tissue, sarcoma | – | 2 (4%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (0) | (1) | (0) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Granular cell tumor benign | 2 (4%) | 1 (2%) | – | 1 (2%)
Granular cell tumor malignant | – | – | – | 2 (4%)
Oligodendroglioma malignant | – | – | – | 1 (2%)
Peripheral nerve | (2) | (9) | (5) | (6)
Spinal cord | (2) | (9) | (5) | (6)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | – | – | 1 (2%)
Squamous cell carcinoma | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50)
Trachea | (49) | (50) | (50) | (50)
Special Senses System
Eye | (49) | (50) | (50) | (50)
Harderian gland | (49) | (50) | (50) | (50)
Zymbal’s gland | (0) | (0) | (0) | (1)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Renal tubule, adenoma | 1 (2%) | – | – | –
Transitional epithelium, papilloma | – | 1 (2%) | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Lymphoma malignant | 2 (4%) | – | – | –
Mesothelioma malignant | – | 1 (2%) | – | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 43 | 40 | 44 | 43
Total primary neoplasms | 85 | 78 | 87 | 79
Total animals with benign neoplasms | 42 | 39 | 43 | 40
Total benign neoplasms | 70 | 62 | 76 | 64
Total animals with malignant neoplasms | 11 | 15 | 11 | 13
Total malignant neoplasms | 15 | 16 | 11 | 15
Total animals with metastatic neoplasms | – | – | – | 1
Total metastatic neoplasms | – | – | – | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Mammary Gland: Fibroadenoma
Overall rate^a^ | 9/50 (18%) | 10/50 (20%) | 13/50 (26%) | 10/50 (20%)
Adjusted rate^b^ | 19.8% | 22.2% | 27.6% | 21.4%
Terminal rate^c^ | 6/35 (17%) | 5/32 (16%) | 10/36 (28%) | 4/29 (14%)
First incidence (days) | 619 | 627 | 642 | 633
Poly-3 test^d^ | P = 0.563 | P = 0.490 | P = 0.261 | P = 0.527
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 11/50 (22%) | 11/50 (22%) | 13/50 (26%) | 10/50 (20%)
Adjusted rate | 24.0% | 24.4% | 27.6% | 21.4%
Terminal rate | 7/35 (20%) | 6/32 (19%) | 10/36 (28%) | 4/29 (14%)
First incidence (days) | 619 | 627 | 642 | 633
Poly-3 test | P = 0.399N | P = 0.579 | P = 0.438 | P = 0.479N
Mammary Gland: Carcinoma
Overall rate | 4/50 (8%) | 5/50 (10%) | 9/50 (18%) | 4/50 (8%)
Adjusted rate | 8.9% | 11.4% | 19.2% | 8.7%
Terminal rate | 3/35 (9%) | 3/32 (9%) | 7/36 (19%) | 1/29 (3%)
First incidence (days) | 698 | 683 | 673 | 639
Poly-3 test | P = 0.437N | P = 0.485 | P = 0.130 | P = 0.629N
Mammary Gland: Adenoma or Carcinoma
Overall rate | 6/50 (12%) | 6/50 (12%) | 10/50 (20%) | 5/50 (10%)
Adjusted rate | 13.2% | 13.6% | 21.3% | 10.8%
Terminal rate | 4/35 (11%) | 4/32 (13%) | 8/36 (22%) | 2/29 (7%)
First incidence (days) | 645 | 683 | 673 | 639
Poly-3 test | P = 0.368N | P = 0.599 | P = 0.226 | P = 0.487N
Mammary Gland: Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 13/50 (26%) | 16/50 (32%) | 21/50 (42%) | 14/50 (28%)
Adjusted rate | 28.3% | 35.2% | 44.1% | 29.5%
Terminal rate | 9/35 (26%) | 9/32 (28%) | 16/36 (44%) | 5/29 (17%)
First incidence (days) | 619 | 627 | 642 | 633
Poly-3 test | P = 0.417N | P = 0.314 | P = 0.082 | P = 0.541
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 35/50 (70%) | 33/50 (66%) | 36/50 (72%) | 30/50 (60%)
Adjusted rate | 72.7% | 67.4% | 73.2% | 62.4%
Terminal rate | 24/35 (69%) | 17/32 (53%) | 25/36 (69%) | 15/29 (52%)
First incidence (days) | 499 | 530 | 563 | 586
Poly-3 test | P = 0.186N | P = 0.365N | P = 0.568 | P = 0.192N
Skin: Squamous Cell Papilloma
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 6.5%
Terminal rate | 0/35 (0%) | 0/32 (0%) | 0/36 (0%) | 2/29 (7%)
First incidence (days) | –^e^ | – | – | 673
Poly-3 test | P = 0.008 | –^f^ | – | P = 0.122
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 4/50 (8%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 8.7%
Terminal rate | 0/35 (0%) | 0/32 (0%) | 0/36 (0%) | 2/29 (7%)
First incidence (days) | – | – | – | 673
Poly-3 test | P = 0.002 | – | – | P = 0.063
Thymus: Benign Thymoma
Overall rate | 5/48 (10%) | 4/48 (8%) | 7/45 (16%) | 3/45 (7%)
Adjusted rate | 11.4% | 9.6% | 16.8% | 7.3%
Terminal rate | 3/34 (9%) | 3/30 (10%) | 5/31 (16%) | 1/24 (4%)
First incidence (days) | 610 | 729 | 708 | 639
Poly-3 test | P = 0.338N | P = 0.532N | P = 0.341 | P = 0.393N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 4/50 (8%) | 4/49 (8%)
Adjusted rate | 6.6% | 4.5% | 8.6% | 8.8%
Terminal rate | 1/35 (3%) | 0/32 (0%) | 4/36 (11%) | 3/29 (10%)
First incidence (days) | 619 | 568 | 731 (T) | 670
Poly-3 test | P = 0.357 | P = 0.509N | P = 0.512 | P = 0.497
Thyroid Gland (C-Cell): Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/49 (6%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 6.6%
Terminal rate | 0/35 (0%) | 0/32 (0%) | 0/36 (0%) | 2/29 (7%)
First incidence (days) | – | – | – | 691
Poly-3 test | P = 0.008 | – | – | P = 0.119
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 4/50 (8%) | 7/49 (14%)
Adjusted rate | 6.6% | 4.5% | 8.6% | 15.4%
Terminal rate | 1/35 (3%) | 0/32 (0%) | 4/36 (11%) | 5/29 (17%)
First incidence (days) | 619 | 568 | 731 (T) | 670
Poly-3 test | P = 0.050 | P = 0.509N | P = 0.512 | P = 0.156
Thyroid Gland (Follicular Cell): Adenoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 3/50 (6%) | 1/49 (2%)
Adjusted rate | 2.2% | 0.0% | 6.4% | 2.2%
Terminal rate | 1/35 (3%) | 0/32 (0%) | 2/36 (6%) | 1/29 (3%)
First incidence (days) | 731 (T) | – | 642 | 731 (T)
Poly-3 test | P = 0.599 | P = 0.506N | P = 0.320 | P = 0.760N
Thyroid Gland (Follicular Cell): Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 1/50 (2%) | 3/50 (6%) | 1/49 (2%)
Adjusted rate | 4.5% | 2.3% | 6.4% | 2.2%
Terminal rate | 2/35 (6%) | 1/32 (3%) | 2/36 (6%) | 1/29 (3%)
First incidence (days) | 731 (T) | 731 (T) | 642 | 731 (T)
Poly-3 test | P = 0.455N | P = 0.510N | P = 0.519 | P = 0.499N
Uterus: Stromal Polyp (Original Evaluation)
Overall rate | 5/50 (10%) | 6/50 (12%) | 3/50 (6%) | 4/50 (8%)
Adjusted rate | 11.1% | 13.6% | 6.4% | 8.8%
Terminal rate | 4/35 (11%) | 5/32 (16%) | 2/36 (6%) | 2/29 (7%)
First incidence (days) | 709 | 633 | 646 | 725
Poly-3 test | P = 0.374N | P = 0.485 | P = 0.335N | P = 0.491N
Uterus: Stromal Polyp (Residual Evaluation)
Overall rate | 6/50 (12%) | 6/50 (12%) | 7/50 (14%) | 1/50 (2%)
Adjusted rate | 13.2% | 13.7% | 14.8% | 2.2%
Terminal rate | 4/35 (11%) | 6/32 (19%) | 5/36 (14%) | 1/29 (3%)
First incidence (days) | 610 | 731 (T) | 563 | 731 (T)
Poly-3 test | P = 0.034N | P = 0.593 | P = 0.531 | P = 0.055N
Uterus: Stromal Polyp (Original and Residual Evaluations)
Overall rate | 10/50 (20%) | 10/50 (20%) | 7/50 (14%) | 5/50 (10%)
Adjusted rate | 21.9% | 22.7% | 14.8% | 10.9%
Terminal rate | 7/35 (20%) | 9/32 (28%) | 5/36 (14%) | 3/29 (10%)
First incidence (days) | 610 | 633 | 563 | 725
Poly-3 test | P = 0.080N | P = 0.567 | P = 0.267N | P = 0.127N
Uterus: Stromal Polyp or Stromal Sarcoma (Original Evaluation)
Overall rate | 6/50 (12%) | 6/50 (12%) | 3/50 (6%) | 5/50 (10%)
Adjusted rate | 13.2% | 13.6% | 6.4% | 10.9%
Terminal rate | 4/35 (11%) | 5/32 (16%) | 2/36 (6%) | 2/29 (7%)
First incidence (days) | 586 | 633 | 646 | 715
Poly-3 test | P = 0.452N | P = 0.598 | P = 0.228N | P = 0.496N
Uterus: Stromal Polyp or Stromal Sarcoma (Residual Evaluation)
Overall rate | 7/50 (14%) | 6/50 (12%) | 7/50 (14%) | 1/50 (2%)
Adjusted rate | 15.2% | 13.7% | 14.8% | 2.2%
Terminal rate | 4/35 (11%) | 6/32 (19%) | 5/36 (14%) | 1/29 (3%)
First incidence (days) | 586 | 731 (T) | 563 | 731 (T)
Poly-3 test | P = 0.023N | P = 0.539N | P = 0.590N | P = 0.031N
Uterus: Stromal Polyp or Stromal Sarcoma (Original and Residual Evaluations)
Overall rate | 11/50 (22%) | 10/50 (20%) | 7/50 (14%) | 6/50 (12%)
Adjusted rate | 23.9% | 22.7% | 14.8% | 13.1%
Terminal rate | 7/35 (20%) | 9/32 (28%) | 5/36 (14%) | 3/29 (10%)
First incidence (days) | 586 | 633 | 563 | 715
Poly-3 test | P = 0.111N | P = 0.546N | P = 0.197N | P = 0.143N
Uterus: Adenocarcinoma (Residual Evaluation)
Overall rate | 0/50 (0%) | 4/50 (8%) | 5/50 (10%) | 5/50 (10%)
Adjusted rate | 0.0% | 9.2% | 10.7% | 11.0%
Terminal rate | 0/35 (0%) | 4/32 (13%) | 3/36 (8%) | 4/29 (14%)
First incidence (days) | – | 731 (T) | 646 | 725
Poly-3 test | P = 0.126 | P = 0.057 | P = 0.034 | P = 0.032
Uterus: Adenocarcinoma (Original and Residual Evaluations)
Overall rate | 1/50 (2%) | 4/50 (8%) | 5/50 (10%) | 5/50 (10%)
Adjusted rate | 2.2% | 9.2% | 10.7% | 11.0%
Terminal rate | 1/35 (3%) | 4/32 (13%) | 3/36 (8%) | 4/29 (14%)
First incidence (days) | 731 (T) | 731 (T) | 646 | 725
Poly-3 test | P = 0.195 | P = 0.170 | P = 0.111 | P = 0.105
Uterus: Adenocarcinoma or Mixed Malignant Müllerian Tumor (Original Evaluation)
Overall rate | 1/50 (2%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 2.2% | 2.3% | 2.1% | 6.6%
Terminal rate | 1/35 (3%) | 1/32 (3%) | 0/36 (0%) | 3/29 (10%)
First incidence (days) | 731 (T) | 731 (T) | 646 | 731 (T)
Poly-3 test | P = 0.163 | P = 0.755 | P = 0.752N | P = 0.311
Uterus: Adenocarcinoma or Mixed Malignant Müllerian Tumor (Residual Evaluation)
Overall rate | 0/50 (0%) | 4/50 (8%) | 5/50 (10%) | 6/50 (12%)
Adjusted rate | 0.0% | 9.2% | 10.7% | 13.1%
Terminal rate | 0/35 (0%) | 4/32 (13%) | 3/36 (8%) | 5/29 (17%)
First incidence (days) | – | 731 (T) | 646 | 725
Poly-3 test | P = 0.059 | P = 0.057 | P = 0.034 | P = 0.016
Uterus: Adenocarcinoma or Mixed Malignant Müllerian Tumor (Original and Residual Evaluations)
Overall rate | 1/50 (2%) | 4/50 (8%) | 5/50 (10%) | 6/50 (12%)
Adjusted rate | 2.2% | 9.2% | 10.7% | 13.1%
Terminal rate | 1/35 (3%) | 4/32 (13%) | 3/36 (8%) | 5/29 (17%)
First incidence (days) | 731 (T) | 731 (T) | 646 | 725
Poly-3 test | P = 0.102 | P = 0.170 | P = 0.111 | P = 0.058
All Organs: Benign Neoplasms
Overall rate | 42/50 (84%) | 39/50 (78%) | 43/50 (86%) | 40/50 (80%)
Adjusted rate | 87.1% | 79.1% | 87.2% | 82.1%
Terminal rate | 30/35 (86%) | 22/32 (69%) | 31/36 (86%) | 23/29 (79%)
First incidence (days) | 499 | 530 | 563 | 586
Poly-3 test | P = 0.451N | P = 0.215N | P = 0.618 | P = 0.338N
All Organs: Malignant Neoplasms
Overall rate | 11/50 (22%) | 15/50 (30%) | 11/50 (22%) | 13/50 (26%)
Adjusted rate | 24.0% | 32.5% | 23.3% | 27.5%
Terminal rate | 7/35 (20%) | 8/32 (25%) | 8/36 (22%) | 6/29 (21%)
First incidence (days) | 586 | 481 | 646 | 523
Poly-3 test | P = 0.547 | P = 0.251 | P = 0.564N | P = 0.442
All Organs: Benign or Malignant Neoplasms
Overall rate | 43/50 (86%) | 40/50 (80%) | 44/50 (88%) | 43/50 (86%)
Adjusted rate | 88.3% | 80.0% | 88.8% | 86.6%
Terminal rate | 30/35 (86%) | 22/32 (69%) | 31/36 (86%) | 23/29 (79%)
First incidence (days) | 499 | 481 | 563 | 523
Poly-3 test | P = 0.463 | P = 0.197N | P = 0.595 | P = 0.524N

(T) = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for pituitary gland, thymus, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table B-3 Summary of the Incidence of Nonneoplastic Lesions in Female Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | 1 | – | –
Moribund | 13 | 16 | 14 | 19
Natural deaths | 2 | – | – | 1
Survivors
Died last week of study | 1 | 1 | – | 1
Terminal kill | 34 | 32 | 36 | 29
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Inflammation, acute | 1 (2%) | – | – | –
Necrosis | 1 (2%) | – | – | –
Intestine large, cecum | (49) | (50) | (50) | (49)
Intestine large, colon | (49) | (49) | (50) | (49)
Intestine large, rectum | (46) | (50) | (47) | (46)
Intestine small, duodenum | (49) | (50) | (50) | (49)
Muscularis, hypertrophy, focal | – | – | 1 (2%) | –
Intestine small, ileum | (49) | (50) | (50) | (49)
Intestine small, jejunum | (49) | (50) | (50) | (49)
Diverticulum | 1 (2%) | – | – | –
Inflammation, acute | 1 (2%) | – | – | –
Inflammation, chronic | – | – | 1 (2%) | –
Necrosis | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | 4 (8%) | 5 (10%) | 5 (10%) | 1 (2%)
Basophilic focus | 34 (68%) | 33 (66%) | 35 (70%) | 32 (64%)
Clear cell focus | 14 (28%) | 6 (12%) | 17 (34%) | 14 (28%)
Degeneration, cystic | – | – | – | 1 (2%)
Eosinophilic focus | 1 (2%) | – | 1 (2%) | 1 (2%)
Fatty change | 3 (6%) | 1 (2%) | 2 (4%) | 1 (2%)
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Hepatodiaphragmatic nodule | 1 (2%) | – | 1 (2%) | –
Mixed cell focus | 2 (4%) | – | – | –
Necrosis | 1 (2%) | 1 (2%) | 1 (2%) | –
Bile duct, cyst | 1 (2%) | 1 (2%) | – | 1 (2%)
Bile duct, cyst, multiple | – | 4 (8%) | 1 (2%) | 3 (6%)
Bile duct, dilatation | 1 (2%) | – | 2 (4%) | 3 (6%)
Bile duct, hyperplasia | 5 (10%) | 2 (4%) | 3 (6%) | 6 (12%)
Bile duct, inflammation, chronic active | 1 (2%) | – | – | –
Mesentery | (7) | (8) | (8) | (5)
Inflammation, chronic active | – | – | – | 1 (20%)
Fat, necrosis | 7 (100%) | 8 (100%) | 8 (100%) | 4 (80%)
Oral mucosa | (0) | (0) | (0) | (1)
Developmental malformation | – | – | – | 1 (100%)
Inflammation, chronic active | – | – | – | 1 (100%)
Pancreas | (49) | (50) | (50) | (50)
Atrophy | 6 (12%) | 4 (8%) | 2 (4%) | 5 (10%)
Basophilic focus | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Basophilic focus | 1 (2%) | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Hyperplasia, squamous | 1 (2%) | – | – | –
Inflammation, acute | 1 (2%) | – | 2 (4%) | –
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Ulcer | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Stomach, glandular | (50) | (50) | (50) | (50)
Inflammation, acute | 1 (2%) | – | – | –
Inflammation, chronic active | – | – | – | 1 (2%)
Mineralization | 1 (2%) | – | 1 (2%) | –
Necrosis | 2 (4%) | – | – | –
Tongue | (1) | (0) | (0) | (0)
Inflammation, granulomatous | 1 (100%) | – | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 16 (32%) | 17 (34%) | 16 (32%) | 14 (28%)
Mineralization | – | – | – | 1 (2%)
Endocardium, hyperplasia | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Accessory adrenal cortical nodule | 1 (2%) | – | – | –
Angiectasis | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Degeneration, cystic | 26 (52%) | 23 (46%) | 29 (58%) | 35 (70%)
Hyperplasia | 17 (34%) | 20 (40%) | 27 (54%) | 22 (44%)
Hypertrophy | 14 (28%) | 20 (40%) | 24 (48%) | 21 (42%)
Metaplasia, osseous | – | 1 (2%) | – | –
Necrosis | 1 (2%) | 1 (2%) | – | –
Adrenal medulla | (49) | (50) | (49) | (49)
Hyperplasia | 2 (4%) | 2 (4%) | 1 (2%) | –
Islets, pancreatic | (49) | (50) | (50) | (50)
Hyperplasia | – | – | 1 (2%) | 1 (2%)
Parathyroid gland | (47) | (44) | (40) | (42)
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, hyperplasia | 8 (16%) | 11 (22%) | 10 (20%) | 9 (18%)
Pars intermedia, hyperplasia | 1 (2%) | – | – | 1 (2%)
Thyroid gland | (50) | (50) | (50) | (49)
C-cell, hyperplasia | 37 (74%) | 44 (88%) | 43 (86%) | 35 (71%)
Follicular cell, hyperplasia | 2 (4%) | – | 1 (2%) | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (46) | (50) | (49)
Inflammation, chronic | – | – | 1 (2%) | –
Inflammation, chronic active | 6 (12%) | 4 (9%) | 1 (2%) | 1 (2%)
Ovary | (50) | (50) | (50) | (50)
Cyst | 11 (22%) | 9 (18%) | 5 (10%) | 11 (22%)
Interstitial cell, hyperplasia | – | – | – | 1 (2%)
Uterus | (50) | (50) | (50) | (50)
Adenomyosis | – | – | 1 (2%) | –
Cervix, cyst, squamous | – | – | 1 (2%) | –
Cervix, hypertrophy | 2 (4%) | – | 1 (2%) | 1 (2%)
Endometrium, hyperplasia, cystic | 11 (22%) | 4 (8%) | 9 (18%) | 5 (10%)
Vagina | (0) | (1) | (0) | (1)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (2) | (2) | (1) | (0)
Lumbar, ectasia | – | 1 (50%) | – | –
Lumbar, hemorrhage | – | 1 (50%) | – | –
Lumbar, hyperplasia, lymphoid | – | – | 1 (100%) | –
Lumbar, pigmentation, hemosiderin | 1 (50%) | – | – | –
Renal, ectasia | 1 (50%) | – | – | –
Renal, pigmentation, hemosiderin | 1 (50%) | – | – | –
Lymph node, bronchial | (38) | (35) | (32) | (35)
Hyperplasia, lymphohistiocytic | – | – | 7 (22%) | 30 (86%)
Lymph node, mandibular | (49) | (47) | (43) | (49)
Ectasia | – | 1 (2%) | – | 2 (4%)
Lymph node, mediastinal | (49) | (46) | (45) | (47)
Hemorrhage | – | – | 1 (2%) | –
Hyperplasia, lymphohistiocytic | – | – | 4 (9%) | 23 (49%)
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Lymph node, mesenteric | (49) | (50) | (50) | (50)
Ectasia | 1 (2%) | 1 (2%) | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Hematopoietic cell proliferation | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Thymus | (48) | (48) | (45) | (45)
Cyst | – | – | 1 (2%) | –
Hyperplasia, tubular | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Galactocele | 3 (6%) | 1 (2%) | 2 (4%) | 1 (2%)
Hyperplasia | 1 (2%) | – | – | 1 (2%)
Inflammation, chronic active | – | – | – | 2 (4%)
Skin | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Inflammation, chronic active | 2 (4%) | 4 (8%) | 5 (10%) | 4 (8%)
Subcutaneous tissue, hemorrhage | – | 1 (2%) | – | –
Subcutaneous tissue, necrosis | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Callus | 1 (2%) | – | – | –
Skeletal muscle | (0) | (1) | (0) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Meninges, hyperplasia | 1 (2%) | – | – | 1 (2%)
Peripheral nerve | (2) | (9) | (5) | (6)
Spinal cord | (2) | (9) | (5) | (6)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Foreign body | – | – | – | 1 (2%)
Inflammation, acute | – | – | – | 4 (8%)
Metaplasia, squamous | 1 (2%) | 50 (100%) | 50 (100%) | 50 (100%)
Lung | (50) | (50) | (50) | (50)
Inflammation, lymphohistiocytic | 3 (6%) | 20 (40%) | 42 (84%) | 50 (100%)
Alveolar epithelium, hyperplasia | 4 (8%) | 3 (6%) | 1 (2%) | 7 (14%)
Bronchus-associated lymphoid tissue, hyperplasia, lymphohistiocytic | – | – | – | 5 (10%)
Nose | (50) | (50) | (50) | (50)
Inflammation, acute | – | – | – | 1 (2%)
Inflammation, chronic active | 2 (4%) | – | 1 (2%) | –
Thrombosis | 1 (2%) | – | – | –
Glands, olfactory epithelium, hyperplasia | 1 (2%) | 32 (64%) | 48 (96%) | 49 (98%)
Goblet cell, hyperplasia | – | 25 (50%) | 34 (68%) | 42 (84%)
Olfactory epithelium, accumulation, hyaline droplet | 16 (32%) | 50 (100%) | 50 (100%) | 50 (100%)
Respiratory epithelium, accumulation, hyaline droplet | 1 (2%) | 24 (48%) | 31 (62%) | 34 (68%)
Trachea | (49) | (50) | (50) | (50)
Special Senses System
Eye | (49) | (50) | (50) | (50)
Cataract | – | – | 1 (2%) | –
Cornea, inflammation, chronic active | – | – | – | 1 (2%)
Retina, atrophy | 3 (6%) | 4 (8%) | 4 (8%) | 2 (4%)
Harderian gland | (49) | (50) | (50) | (50)
Hyperplasia | 3 (6%) | 3 (6%) | 5 (10%) | 4 (8%)
Zymbal’s gland | (0) | (0) | (0) | (1)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | – | 1 (2%) | 2 (4%) | –
Hydronephrosis | – | 1 (2%) | – | 1 (2%)
Inflammation, suppurative | 1 (2%) | 2 (4%) | – | –
Mineralization | – | 1 (2%) | – | 1 (2%)
Nephropathy | 17 (34%) | 16 (32%) | 19 (38%) | 18 (36%)
Renal tubule, hyperplasia | – | – | – | 1 (2%)
Transitional epithelium, hyperplasia | 1 (2%) | 3 (6%) | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.