# Appendix A Summary of Lesions in Male Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

Table A-1 Summary of the Incidence of Neoplasms in Male Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 17 | 12 | 13 | 15
Natural deaths | – | 4 | 3 | 2
Survivors
Terminal kill | 33 | 34 | 34 | 33
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (48) | (47) | (49)
Intestine large, colon | (50) | (49) | (47) | (49)
Intestine large, rectum | (48) | (47) | (47) | (48)
Intestine small, duodenum | (50) | (48) | (47) | (49)
Intestine small, ileum | (50) | (48) | (47) | (49)
Intestine small, jejunum | (50) | (48) | (47) | (49)
Liver | (50) | (50) | (50) | (50)
Hepatocellular adenoma | – | 1 (2%) | – | –
Hepatocellular carcinoma | – | 1 (2%) | – | –
Mesentery | (7) | (7) | (1) | (2)
Liposarcoma | – | – | – | 1 (50%)
Oral mucosa | (1) | (0) | (1) | (0)
Pancreas | (50) | (50) | (49) | (50)
Adenoma | 1 (2%) | – | – | –
Carcinoma | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Sarcoma | – | – | – | 1 (2%)
Schwannoma malignant | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Leiomyoma | 1 (2%) | – | – | –
Sarcoma | 1 (2%) | – | – | –
Stomach, glandular | (50) | (50) | (49) | (50)
Sarcoma | 1 (2%) | – | – | –
Tooth | (0) | (1) | (0) | (1)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Schwannoma benign | 1 (2%) | – | 2 (4%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (50)
Adenoma | 2 (4%) | – | 2 (4%) | 1 (2%)
Carcinoma | – | 1 (2%) | 1 (2%) | 1 (2%)
Bilateral, carcinoma | 1 (2%) | – | – | –
Adrenal medulla | (50) | (48) | (49) | (50)
Pheochromocytoma benign | 4 (8%) | – | 1 (2%) | 5 (10%)
Pheochromocytoma malignant | – | 1 (2%) | – | –
Islets, pancreatic | (50) | (50) | (49) | (50)
Adenoma | – | – | 2 (4%) | 2 (4%)
Carcinoma | – | – | 1 (2%) | –
Parathyroid gland | (43) | (43) | (44) | (47)
Adenoma | – | 1 (2%) | – | 1 (2%)
Pituitary gland | (49) | (50) | (50) | (50)
Sarcoma, metastatic, salivary glands | – | – | – | 1 (2%)
Pars distalis, adenoma | 16 (33%) | 18 (36%) | 11 (22%) | 17 (34%)
Pars distalis, carcinoma | – | – | 1 (2%) | –
Pars intermedia, adenoma | 2 (4%) | 1 (2%) | 2 (4%) | –
Thyroid gland | (50) | (50) | (49) | (50)
C-cell, adenoma | 6 (12%) | 5 (10%) | 3 (6%) | 5 (10%)
C-cell, adenoma, multiple | 1 (2%) | – | – | –
C-cell, carcinoma | – | – | 1 (2%) | 1 (2%)
Follicular cell, adenoma | 1 (2%) | – | – | –
Follicular cell, carcinoma | – | 1 (2%) | 1 (2%) | 2 (4%)
General Body System
Peritoneum | (1) | (0) | (0) | (0)
Genital System
Coagulating gland | (0) | (0) | (0) | (1)
Epididymis | (50) | (50) | (50) | (50)
Preputial gland | (50) | (50) | (50) | (50)
Prostate gland | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | 2 (4%)
Adenoma, multiple | 1 (2%) | – | 1 (2%) | 1 (2%)
Carcinoma | – | – | 1 (2%) | –
Seminal vesicle | (50) | (50) | (48) | (50)
Adenoma | 1 (2%) | – | – | –
Testes | (50) | (50) | (50) | (50)
Interstitial cell, adenoma | 2 (4%) | 1 (2%) | 2 (4%) | 2 (4%)
Hematopoietic System
Bone marrow | (50) | (50) | (49) | (50)
Hemangiosarcoma | 1 (2%) | – | – | –
Bronchial associated lymphoid tissue | (0) | (1) | (5) | (19)
Lymph node | (12) | (5) | (7) | (5)
Lymph node, bronchial | (42) | (40) | (37) | (35)
Lymph node, mandibular | (46) | (46) | (44) | (45)
Carcinoma, metastatic, Zymbal’s gland | – | 1 (2%) | – | –
Lymph node, mediastinal | (46) | (45) | (50) | (49)
Lymph node, mesenteric | (50) | (50) | (49) | (50)
Hemangioma | – | – | 1 (2%) | –
Hemangiosarcoma | 3 (6%) | 1 (2%) | – | 2 (4%)
Spleen | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Sarcoma | – | – | – | 1 (2%)
Thymus | (40) | (43) | (44) | (46)
Thymoma benign | 1 (3%) | – | 2 (5%) | 1 (2%)
Thymoma malignant | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (6) | (6) | (3) | (4)
Skin | (50) | (50) | (50) | (50)
Basal cell carcinoma | 1 (2%) | – | 1 (2%) | –
Keratoacanthoma | 1 (2%) | – | – | –
Squamous cell papilloma | – | – | 1 (2%) | –
Sebaceous gland, adenoma | – | 1 (2%) | – | –
Subcutaneous tissue, fibroma | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Subcutaneous tissue, fibrosarcoma | 1 (2%) | – | – | –
Subcutaneous tissue, hemangiopericytoma | – | – | – | 1 (2%)
Subcutaneous tissue, hemangiosarcoma | – | – | – | 1 (2%)
Subcutaneous tissue, lipoma | 1 (2%) | – | – | 1 (2%)
Subcutaneous tissue, liposarcoma | – | – | – | 1 (2%)
Subcutaneous tissue, neural crest tumor | – | 1 (2%) | – | –
Subcutaneous tissue, schwannoma malignant | – | 2 (4%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteosarcoma | 1 (2%) | 1 (2%) | – | 2 (4%)
Sarcoma, metastatic, salivary glands | – | – | – | 1 (2%)
Skeletal muscle | (1) | (2) | (1) | (0)
Sarcoma | – | 1 (50%) | 1 (100%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Carcinoma, metastatic, Zymbal’s gland | – | 1 (2%) | – | –
Glioma | 2 (4%) | 1 (2%) | 1 (2%) | –
Granular cell tumor benign | – | 2 (4%) | – | 1 (2%)
Granular cell tumor malignant | – | 1 (2%) | 1 (2%) | –
Meningioma malignant | 1 (2%) | – | – | –
Sarcoma, metastatic, salivary glands | – | – | – | 1 (2%)
Peripheral nerve | (5) | (4) | (6) | (6)
Spinal cord | (5) | (4) | (7) | (6)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Sarcoma, metastatic, salivary glands | – | – | – | 1 (2%)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 1 (2%) | – | 1 (2%) | –
Osteosarcoma, metastatic, bone | – | 1 (2%) | – | 1 (2%)
Osteosarcoma, metastatic, uncertain primary site | – | 1 (2%) | – | –
Sarcoma, metastatic, salivary glands | – | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Sarcoma, metastatic, salivary glands | – | – | – | 1 (2%)
Trachea | (50) | (49) | (50) | (50)
Sarcoma, metastatic, salivary glands | – | – | – | 1 (2%)
Special Senses System
Ear | (0) | (0) | (1) | (0)
Eye | (50) | (50) | (48) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Sarcoma, metastatic, salivary glands | – | – | – | 1 (2%)
Zymbal’s gland | (3) | (2) | (1) | (0)
Carcinoma | 2 (67%) | 2 (100%) | – | –
Urinary System
Kidney | (50) | (50) | (49) | (50)
Lipoma | – | – | – | 1 (2%)
Renal tubule, adenoma | – | 1 (2%) | – | –
Transitional epithelium, papilloma | 1 (2%) | – | – | –
Urinary bladder | (50) | (50) | (48) | (49)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Lymphoma malignant | – | 2 (4%) | 1 (2%) | 1 (2%)
Mesothelioma malignant | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 37 | 36 | 30 | 39
Total primary neoplasms | 62 | 51 | 45 | 60
Total animals with benign neoplasms | 32 | 27 | 24 | 31
Total benign neoplasms | 45 | 34 | 33 | 42
Total animals with malignant neoplasms | 13 | 14 | 9 | 16
Total malignant neoplasms | 15 | 15 | 11 | 18
Total animals with metastatic neoplasms | – | 4 | – | 2
Total metastatic neoplasms | – | 4 | – | 9
Total animals with malignant neoplasms of uncertain primary site | – | 1 | – | –
Total animals with uncertain neoplasms – benign or malignant | 2 | 2 | 1 | –
Total uncertain neoplasms | 2 | 2 | 1 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 4/50 (8%) | 0/48 (0%) | 1/49 (2%) | 5/50 (10%)
Adjusted rate^b^ | 9.1% | 0.0% | 2.2% | 11.5%
Terminal rate^c^ | 2/33 (6%) | 0/32 (0%) | 1/34 (3%) | 4/33 (12%)
First incidence (days) | 612 | –^e^ | 729 (T) | 725
Poly-3 test^d^ | P = 0.118 | P = 0.070N | P = 0.172N | P = 0.492
Adrenal Medulla: Benign or Malignant Pheochromocytoma
Overall rate | 4/50 (8%) | 1/48 (2%) | 1/49 (2%) | 5/50 (10%)
Adjusted rate | 9.1% | 2.4% | 2.2% | 11.5%
Terminal rate | 2/33 (6%) | 1/32 (3%) | 1/34 (3%) | 4/33 (12%)
First incidence (days) | 612 | 729 (T) | 729 (T) | 725
Poly-3 test | P = 0.177 | P = 0.201N | P = 0.172N | P = 0.492
Brain: Benign or Malignant Granular Cell Tumor
Overall rate | 0/50 (0%) | 3/50 (6%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 0.0% | 7.0% | 2.2% | 2.3%
Terminal rate | 0/33 (0%) | 2/34 (6%) | 0/34 (0%) | 1/33 (3%)
First incidence (days) | – | 704 | 684 | 729 (T)
Poly-3 test | P = 0.593N | P = 0.116 | P = 0.511 | P = 0.500
Mesenteric Lymph Node: Hemangiosarcoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate | 6.7% | 2.3% | 0.0% | 4.6%
Terminal rate | 1/33 (3%) | 0/34 (0%) | 0/34 (0%) | 2/33 (6%)
First incidence (days) | 345 | 704 | – | 729 (T)
Poly-3 test | P = 0.642N | P = 0.321N | P = 0.115N | P = 0.515N
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 3/49 (6%) | 2/50 (4%)
Adjusted rate | 0.0% | 0.0% | 6.5% | 4.6%
Terminal rate | 0/33 (0%) | 0/34 (0%) | 1/34 (3%) | 2/33 (6%)
First incidence (days) | – | – | 704 | 729 (T)
Poly-3 test | P = 0.175 | –^f^ | P = 0.129 | P = 0.236
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 16/49 (33%) | 18/50 (36%) | 11/50 (22%) | 17/50 (34%)
Adjusted rate | 35.2% | 40.2% | 23.3% | 37.5%
Terminal rate | 8/32 (25%) | 13/34 (38%) | 6/34 (18%) | 10/33 (30%)
First incidence (days) | 520 | 505 | 620 | 504
Poly-3 test | P = 0.494 | P = 0.395 | P = 0.150N | P = 0.496
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 16/49 (33%) | 18/50 (36%) | 12/50 (24%) | 17/50 (34%)
Adjusted rate | 35.2% | 40.2% | 25.4% | 37.5%
Terminal rate | 8/32 (25%) | 13/34 (38%) | 6/34 (18%) | 10/33 (30%)
First incidence (days) | 520 | 505 | 620 | 504
Poly-3 test | P = 0.501 | P = 0.395 | P = 0.211N | P = 0.496
Prostate Gland: Adenoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 2.3% | 2.3% | 2.2% | 6.9%
Terminal rate | 1/33 (3%) | 1/34 (3%) | 1/34 (3%) | 3/33 (9%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.157 | P = 0.757 | P = 0.749N | P = 0.304
Prostate Gland: Adenoma or Carcinoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 2.3% | 2.3% | 4.3% | 6.9%
Terminal rate | 1/33 (3%) | 1/34 (3%) | 1/34 (3%) | 3/33 (9%)
First incidence (days) | 729 (T) | 729 (T) | 684 | 729 (T)
Poly-3 test | P = 0.187 | P = 0.757 | P = 0.520 | P = 0.304
Thymus: Benign Thymoma
Overall rate | 1/40 (3%) | 0/43 (0%) | 2/44 (5%) | 1/46 (2%)
Adjusted rate | 2.8% | 0.0% | 4.9% | 2.5%
Terminal rate | 1/27 (4%) | 0/27 (0%) | 1/29 (3%) | 1/30 (3%)
First incidence (days) | 729 (T) | – | 722 | 729 (T)
Poly-3 test | P = 0.613 | P = 0.498N | P = 0.545 | P = 0.734N
Thymus: Benign or Malignant Thymoma
Overall rate | 1/40 (3%) | 0/43 (0%) | 2/44 (5%) | 2/46 (4%)
Adjusted rate | 2.8% | 0.0% | 4.9% | 4.9%
Terminal rate | 1/27 (4%) | 0/27 (0%) | 1/29 (3%) | 1/30 (3%)
First incidence (days) | 729 (T) | – | 722 | 457
Poly-3 test | P = 0.329 | P = 0.498N | P = 0.545 | P = 0.548
Thyroid Gland (C-Cell): Adenoma
Overall rate | 7/50 (14%) | 5/50 (10%) | 3/49 (6%) | 5/50 (10%)
Adjusted rate | 16.0% | 11.6% | 6.6% | 11.5%
Terminal rate | 6/33 (18%) | 4/34 (12%) | 2/34 (6%) | 4/33 (12%)
First incidence (days) | 704 | 717 | 704 | 725
Poly-3 test | P = 0.438N | P = 0.390N | P = 0.143N | P = 0.381N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 7/50 (14%) | 5/50 (10%) | 4/49 (8%) | 6/50 (12%)
Adjusted rate | 16.0% | 11.6% | 8.9% | 13.8%
Terminal rate | 6/33 (18%) | 4/34 (12%) | 3/34 (9%) | 5/33 (15%)
First incidence (days) | 704 | 717 | 704 | 725
Poly-3 test | P = 0.579N | P = 0.390N | P = 0.241N | P = 0.503N
All Organs: Hemangiosarcoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 0/50 (0%) | 4/50 (8%)
Adjusted rate | 6.7% | 2.3% | 0.0% | 9.2%
Terminal rate | 1/33 (3%) | 0/34 (0%) | 0/34 (0%) | 4/33 (12%)
First incidence (days) | 345 | 704 | – | 729 (T)
Poly-3 test | P = 0.188 | P = 0.321N | P = 0.115N | P = 0.482
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 4/50 (8%)
Adjusted rate | 6.7% | 2.3% | 2.2% | 9.2%
Terminal rate | 1/33 (3%) | 0/34 (0%) | 0/34 (0%) | 4/33 (12%)
First incidence (days) | 345 | 704 | 722 | 729 (T)
Poly-3 test | P = 0.213 | P = 0.321N | P = 0.297N | P = 0.482
All Organs: Benign Neoplasms
Overall rate | 32/50 (64%) | 27/50 (54%) | 24/50 (48%) | 31/50 (62%)
Adjusted rate | 67.6% | 59.4% | 50.7% | 67.8%
Terminal rate | 21/33 (64%) | 20/34 (59%) | 15/34 (44%) | 22/33 (67%)
First incidence (days) | 520 | 505 | 620 | 504
Poly-3 test | P = 0.351 | P = 0.269N | P = 0.068N | P = 0.577
All Organs: Malignant Neoplasms
Overall rate | 13/50 (26%) | 15/50 (30%) | 9/50 (18%) | 16/50 (32%)
Adjusted rate | 28.3% | 31.5% | 18.7% | 34.6%
Terminal rate | 7/33 (21%) | 7/34 (21%) | 4/34 (12%) | 8/33 (24%)
First incidence (days) | 345 | 286 | 309 | 457
Poly-3 test | P = 0.284 | P = 0.455 | P = 0.197N | P = 0.333
All Organs: Benign or Malignant Neoplasms
Overall rate | 37/50 (74%) | 36/50 (72%) | 30/50 (60%) | 39/50 (78%)
Adjusted rate | 75.3% | 72.8% | 61.2% | 81.0%
Terminal rate | 23/33 (70%) | 22/34 (65%) | 17/34 (50%) | 24/33 (73%)
First incidence (days) | 345 | 286 | 309 | 457
Poly-3 test | P = 0.201 | P = 0.480N | P = 0.098N | P = 0.332

(T) = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, brain, pancreatic islets, pituitary gland, prostate gland, thymus, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Wistar Han Rats in the Two-year Inhalation Study of CIMSTAR 3800^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 17 | 12 | 13 | 15
Natural deaths | – | 4 | 3 | 2
Survivors
Terminal kill | 33 | 34 | 34 | 33
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (48) | (47) | (49)
Inflammation, acute | – | 1 (2%) | – | –
Necrosis | – | 1 (2%) | – | –
Intestine large, colon | (50) | (49) | (47) | (49)
Inflammation, acute | – | 1 (2%) | – | –
Necrosis | – | 1 (2%) | – | –
Intestine large, rectum | (48) | (47) | (47) | (48)
Intestine small, duodenum | (50) | (48) | (47) | (49)
Intestine small, ileum | (50) | (48) | (47) | (49)
Intestine small, jejunum | (50) | (48) | (47) | (49)
Diverticulum | – | 1 (2%) | – | –
Inflammation, chronic | – | – | – | 1 (2%)
Lymphatic, angiectasis | – | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 3 (6%) | 7 (14%) | 8 (16%) | 7 (14%)
Basophilic focus | 11 (22%) | 20 (40%) | 18 (36%) | 18 (36%)
Clear cell focus | 29 (58%) | 26 (52%) | 17 (34%) | 26 (52%)
Congestion | – | 1 (2%) | – | –
Eosinophilic focus | – | – | 1 (2%) | –
Fatty change | – | – | – | 1 (2%)
Inflammation, granulomatous | – | 1 (2%) | – | –
Mixed cell focus | 3 (6%) | – | – | 1 (2%)
Necrosis | 2 (4%) | 3 (6%) | 1 (2%) | 1 (2%)
Bile duct, cyst | 1 (2%) | 1 (2%) | – | –
Bile duct, dilatation | 3 (6%) | 2 (4%) | 2 (4%) | 4 (8%)
Bile duct, hyperplasia | 1 (2%) | 2 (4%) | – | –
Bile duct, inflammation, chronic active | 1 (2%) | – | – | –
Mesentery | (7) | (7) | (1) | (2)
Fat, necrosis | 6 (86%) | 7 (100%) | 1 (100%) | –
Oral mucosa | (1) | (0) | (1) | (0)
Developmental malformation | 1 (100%) | – | 1 (100%) | –
Pancreas | (50) | (50) | (49) | (50)
Atrophy | 1 (2%) | 4 (8%) | 4 (8%) | 5 (10%)
Basophilic focus | 2 (4%) | 4 (8%) | 2 (4%) | 1 (2%)
Inflammation, acute | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Hyperplasia, squamous | 1 (2%) | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | – | – | –
Ulcer | – | 1 (2%) | – | 2 (4%)
Stomach, glandular | (50) | (50) | (49) | (50)
Necrosis | – | – | 1 (2%) | –
Tooth | (0) | (1) | (0) | (1)
Dysplasia | – | – | – | 1 (100%)
Inflammation, chronic active | – | 1 (100%) | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 28 (56%) | 40 (80%) | 32 (64%) | 33 (66%)
Necrosis | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (50)
Accessory adrenal cortical nodule | 1 (2%) | – | – | –
Degeneration, cystic | 2 (4%) | 1 (2%) | 3 (6%) | 2 (4%)
Hyperplasia | 26 (52%) | 25 (50%) | 28 (57%) | 26 (52%)
Hypertrophy | 20 (40%) | 21 (42%) | 14 (29%) | 16 (32%)
Adrenal medulla | (50) | (48) | (49) | (50)
Angiectasis | – | – | – | 1 (2%)
Hyperplasia | 2 (4%) | 1 (2%) | 4 (8%) | 1 (2%)
Islets, pancreatic | (50) | (50) | (49) | (50)
Parathyroid gland | (43) | (43) | (44) | (47)
Hyperplasia | 1 (2%) | – | 1 (2%) | 1 (2%)
Pituitary gland | (49) | (50) | (50) | (50)
Cyst | 1 (2%) | – | – | –
Pars distalis, hyperplasia | 14 (29%) | 21 (42%) | 13 (26%) | 16 (32%)
Pars intermedia, hyperplasia | 3 (6%) | 1 (2%) | 1 (2%) | 4 (8%)
Thyroid gland | (50) | (50) | (49) | (50)
C-cell, hyperplasia | 34 (68%) | 30 (60%) | 30 (61%) | 28 (56%)
Follicular cell, hyperplasia | 5 (10%) | 1 (2%) | 5 (10%) | –
General Body System
Peritoneum | (1) | (0) | (0) | (0)
Genital System
Coagulating gland | (0) | (0) | (0) | (1)
Inflammation, chronic active | – | – | – | 1 (100%)
Epididymis | (50) | (50) | (50) | (50)
Granuloma sperm | 2 (4%) | – | – | –
Preputial gland | (50) | (50) | (50) | (50)
Inflammation, chronic active | 3 (6%) | 5 (10%) | 3 (6%) | 3 (6%)
Duct, ectasia | – | – | – | 1 (2%)
Prostate gland | (50) | (50) | (50) | (50)
Hyperplasia | 12 (24%) | 17 (34%) | 12 (24%) | 11 (22%)
Inflammation, chronic active | 1 (2%) | 2 (4%) | 4 (8%) | 2 (4%)
Seminal vesicle | (50) | (50) | (48) | (50)
Hyperplasia | 1 (2%) | – | – | 1 (2%)
Inflammation, chronic active | – | – | 2 (4%) | 1 (2%)
Testes | (50) | (50) | (50) | (50)
Atrophy | 15 (30%) | 8 (16%) | 5 (10%) | 5 (10%)
Edema | 16 (32%) | 11 (22%) | 18 (36%) | 11 (22%)
Necrosis | 1 (2%) | – | – | –
Artery, inflammation, chronic active | – | 2 (4%) | – | –
Interstitial cell, hyperplasia | – | – | – | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (50) | (49) | (50)
Lymph node | (12) | (5) | (7) | (5)
Axillary, ectasia | – | – | – | 1 (20%)
Axillary, infiltration cellular, plasma cell | 1 (8%) | – | – | –
Iliac, ectasia | 2 (17%) | – | 1 (14%) | 1 (20%)
Iliac, inflammation, chronic active | – | – | 1 (14%) | –
Lumbar, ectasia | 2 (17%) | 2 (40%) | 2 (29%) | –
Lumbar, hemorrhage | 1 (8%) | – | – | –
Lumbar, infiltration cellular, plasma cell | 5 (42%) | 1 (20%) | 2 (29%) | –
Pancreatic, ectasia | 1 (8%) | – | – | –
Pancreatic, inflammation, chronic active | 1 (8%) | – | – | –
Renal, ectasia | – | 2 (40%) | – | 2 (40%)
Lymph node, bronchial | (42) | (40) | (37) | (35)
Ectasia | – | – | – | 1 (3%)
Hyperplasia, lymphohistiocytic | – | – | 10 (27%) | 28 (80%)
Lymph node, mandibular | (46) | (46) | (44) | (45)
Ectasia | 1 (2%) | 2 (4%) | – | –
Hyperplasia, lymphoid | – | 1 (2%) | – | 1 (2%)
Infiltration, cellular, plasma cell | – | 1 (2%) | 1 (2%) | –
Lymph node, mediastinal | (46) | (45) | (50) | (49)
Ectasia | 1 (2%) | – | – | –
Hyperplasia, lymphohistiocytic | – | – | 4 (8%) | 29 (59%)
Lymph node, mesenteric | (50) | (50) | (49) | (50)
Ectasia | 2 (4%) | – | – | –
Hemorrhage | – | – | – | 1 (2%)
Infiltration cellular, plasma cell | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | 1 (2%)
Hematopoietic cell proliferation | 2 (4%) | – | 4 (8%) | 2 (4%)
Inflammation, granulomatous | – | 1 (2%) | – | –
Necrosis | – | – | 1 (2%) | –
Thymus | (40) | (43) | (44) | (46)
Atrophy | 1 (3%) | – | – | –
Cyst | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (6) | (6) | (3) | (4)
Galactocele | 1 (17%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Angiectasis | – | – | – | 1 (2%)
Cyst epithelial inclusion | 1 (2%) | 1 (2%) | – | 1 (2%)
Inflammation, chronic active | 31 (62%) | 23 (46%) | 30 (60%) | 22 (44%)
Thrombosis | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hyperostosis | 1 (2%) | – | – | –
Inflammation, chronic active | – | – | 1 (2%) | –
Skeletal muscle | (1) | (2) | (1) | (0)
Necrosis | – | 1 (50%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | – | – | – | 1 (2%)
Hemorrhage | – | – | 1 (2%) | –
Peripheral nerve | (5) | (4) | (6) | (6)
Spinal cord | (5) | (4) | (7) | (6)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Foreign body | – | – | 1 (2%) | –
Inflammation, acute | – | 1 (2%) | – | –
Inflammation, chronic | – | – | – | 1 (2%)
Inflammation, chronic active | – | 2 (4%) | 2 (4%) | –
Metaplasia, squamous | 1 (2%) | 47 (94%) | 50 (100%) | 50 (100%)
Epiglottis, fibrosis | – | – | – | 1 (2%)
Epiglottis, ulcer | – | – | – | 1 (2%)
Lung | (50) | (50) | (50) | (50)
Foreign body | 1 (2%) | – | – | –
Hemorrhage | 1 (2%) | – | – | –
Inflammation, lymphohistiocytic | 6 (12%) | 14 (28%) | 41 (82%) | 47 (94%)
Inflammation, acute | – | 2 (4%) | – | –
Metaplasia, squamous | – | 1 (2%) | – | –
Alveolar epithelium, hyperplasia | 4 (8%) | 6 (12%) | 11 (22%) | 13 (26%)
Bronchus-associated lymphoid tissue, hyperplasia, lymphohistiocytic | – | 1 (2%) | 5 (10%) | 19 (38%)
Nose | (50) | (50) | (50) | (50)
Foreign body | – | – | 1 (2%) | 1 (2%)
Inflammation, acute | – | 1 (2%) | 1 (2%) | 1 (2%)
Inflammation, chronic active | 4 (8%) | 1 (2%) | 1 (2%) | –
Glands, olfactory epithelium, hyperplasia | 1 (2%) | 39 (78%) | 47 (94%) | 50 (100%)
Goblet cell, hyperplasia | – | 20 (40%) | 25 (50%) | 34 (68%)
Olfactory epithelium, accumulation, hyaline droplet | 19 (38%) | 50 (100%) | 50 (100%) | 50 (100%)
Respiratory epithelium, accumulation, hyaline droplet | – | 17 (34%) | 25 (50%) | 29 (58%)
Trachea | (50) | (49) | (50) | (50)
Inflammation, acute | – | 1 (2%) | – | –
Special Senses System
Ear | (0) | (0) | (1) | (0)
Eye | (50) | (50) | (48) | (50)
Cataract | 2 (4%) | 3 (6%) | 1 (2%) | –
Cornea, inflammation, chronic active | – | 1 (2%) | – | 1 (2%)
Retina, atrophy | 2 (4%) | 3 (6%) | 2 (4%) | 1 (2%)
Harderian gland | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | – | –
Hyperplasia | 17 (34%) | 7 (14%) | 12 (24%) | 6 (12%)
Hypertrophy | 2 (4%) | 3 (6%) | – | –
Zymbal’s gland | (3) | (2) | (1) | (0)
Urinary System
Kidney | (50) | (50) | (49) | (50)
Cyst | 4 (8%) | 1 (2%) | 3 (6%) | –
Hydronephrosis | – | 1 (2%) | 2 (4%) | –
Infarct | – | – | – | 1 (2%)
Inflammation, suppurative | – | 3 (6%) | 2 (4%) | 4 (8%)
Nephropathy | 43 (86%) | 38 (76%) | 38 (78%) | 38 (76%)
Renal tubule, hyperplasia | – | – | – | 3 (6%)
Transitional epithelium, hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | –
Urinary bladder | (50) | (50) | (48) | (49)
Calculus gross observation | – | 1 (2%) | – | –
Inflammation, chronic active | – | 1 (2%) | – | 1 (2%)
Transitional epithelium, hyperplasia | – | 1 (2%) | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.