# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  S.A. Thakur, Ph.D., Co-Study Scientist
  C.R. Blystone, Ph.D., Co-Study Scientist
  P.M. Foster, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A. Nyska, D.V.M., Co-Study Pathologist
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.E. Brix, D.V.M., Ph.D., Co-Study Pathologist
- Conducted pathology review
  N. Allison, D.V.M.
  R.R. Maronpot, D.V.M.
  R.R. Moore, D.V.M., Ph.D.
  A.R. Pandiri, Ph.D.
- Battelle Columbus Operations, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  D.M. Sells, D.V.M., Ph.D.
  A.J. Skowronek, D.V.M., Ph.D.
  D.Y. Vasconcelos, D.V.M., Ph.D.
- Pathology Associates International, A Charles River Company, Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Groups for 2-year rats (July 17, 2012) and 2-year mice (April 26, 2012)
  J.S. Hoane, D.V.M.
- Bridge Global Pharmaceutical Services, Inc.
  Provided SMVCE analysis
  B.J.T. Muir, Ph.D., Principal Investigator
  B. Atkinson, M.S.
  Y. Wang, M.S.