# References

1 Katiyar SK Mukhtar HTea antioxidants in cancer chemoprevention. J Cell Biochem Suppl. 1997; 27:59-67.
2 Balentine DA Wiseman SA Bouwens LCM The chemistry of tea flavonoids. Crit Rev Food Sci Nutr. 1997;37(8):693–704. 10.1080/10408399709527797 9447270
3 Graham HN Green tea composition, consumption, and polyphenol chemistry. Prev Med. 1992; (21). 10.1016/0091-7435(92)90041-F
4 Saito ST Gosmann G Pungartnik C Brendel M Green tea extract-patents and diversity of uses. Recent Pat Food Nutr Agric. 2009;1(3):203–215. 10.2174/2212798410901030203 20653541
5 Vuong QV Golding JB Nguyen M Roach PD Extraction and isolation of catechins from tea. J Sep Sci. 2010;33(21):3415–3428. 10.1002/jssc.201000438 21049524
6 Manning J Roberts JC Analysis of catechin content of commercial green tea products. J Herb Pharmacother. 2003;3(3):19–32. 10.1080/J157v03n03_03 15277054
7 Sarma DN Barrett ML Chavez ML Gardiner P Ko R Mahady GB Marles RJ Pellicore LS Giancaspro GI Low Dog T Safety of green tea extracts : a systematic review by the US Pharmacopeia. Drug Saf. 2008;31(6):469–484. 10.2165/00002018-200831060-00003 18484782
8 Lindstrom A Ooyen C Lynch ME Blumenthal M Herb supplement sales increase 5.5% in 2012. HerbalGram. 2013;99:60–65.
9 Naito Y Yoshikawa T Green tea and heart health. J Cardiovasc Pharmacol. 2009;54(5):385–390. 10.1097/FJC.0b013e3181b6e7a1 19668087
10 Weinreb O Amit T Mandel S Youdim MBH Neuroprotective molecular mechanisms of (-)-epigallocatechin-3-gallate: a reflective outcome of its antioxidant, iron chelating and neuritogenic properties. Genes Nutr. 2009;4(4):283–296. 10.1007/s12263-009-0143-4 19756809
11 Yang CS Wang X Green tea and cancer prevention. Nutr Cancer. 2010;62(7):931–937. 10.1080/01635581.2010.509536 20924968
12 Shanafelt TD Call TG Zent CS Leis JF LaPlant B Bowen DA Roos M Laumann K Ghosh AK Lesnick C Phase 2 trial of daily, oral Polyphenon E in patients with asymptomatic, Rai stage 0 to II chronic lymphocytic leukemia. Cancer. 2013;119(2):363–370. 10.1002/cncr.27719 22760587
13 Pisters KMW Newman RA Coldman B Shin DM Khuri FR Hong WK Glisson BS Lee JS Phase I trial of oral green tea extract in adult patients with solid tumors. J Clin Oncol. 2001;19(6):1830–1838. 10.1200/JCO.2001.19.6.1830 11251015
14 Tsao AS Liu D Martin J Tang XM Lee JJ El-Naggar AK Wistuba I Culotta KS Mao L Gillenwater A Phase II randomized, placebo-controlled trial of green tea extract in patients with high-risk oral premalignant lesions. Cancer Prev Res (Phila). 2009;2(11):931–941. 10.1158/1940-6207.CAPR-09-0121 19892663
15 Bogdanski P Suliburska J Szulinska M Stepien M Pupek-Musialik D Jablecka A Green tea extract reduces blood pressure, inflammatory biomarkers, and oxidative stress and improves parameters associated with insulin resistance in obese, hypertensive patients. Nutr Res. 2012;32(6):421–427. 10.1016/j.nutres.2012.05.007 22749178
16 Nguyen MM Ahmann FR Nagle RB Hsu CH Tangrea JA Parnes HL Sokoloff MH Gretzer MB Chow HHS Randomized, double-blind, placebo-controlled trial of polyphenon E in prostate cancer patients before prostatectomy: evaluation of potential chemopreventive activities. Cancer Prev Res (Phila). 2012;5(2):290–298. 10.1158/1940-6207.CAPR-11-0306 22044694
17 Suliburska J Bogdanski P Szulinska M Stepien M Pupek-Musialik D Jablecka A Effects of green tea supplementation on elements, total antioxidants, lipids, and glucose values in the serum of obese patients. Biol Trace Elem Res. 2012;149(3):315–322. 10.1007/s12011-012-9448-z 22581111
18 Code of Federal Regulations (CFR). 21:Part 182.
19 Stockfleth E Meyer T The use of sinecatechins (polyphenon E) ointment for treatment of external genital warts. Expert Opin Biol Ther. 2012;12(6):783–793. 10.1517/14712598.2012.676036 22506983
20 Suganuma M Okabe S Oniyama M Tada Y Ito H Fujiki H Wide distribution of [3H](-)-epigallocatechin gallate, a cancer preventive tea polyphenol, in mouse tissue. Carcinogenesis. 1998;19(10):1771–1776. 10.1093/carcin/19.10.1771 9806157
21 Chen L Lee MJ Li H Yang CS Absorption, distribution, elimination of tea polyphenols in rats. Drug Metab Dispos. 1997;25(9):1045–1050. 9311619
22 Lambert JD Lee MJ Lu H Meng X Hong JJ Seril DN Sturgill MG Yang CS Epigallocatechin-3-gallate is absorbed but extensively glucuronidated following oral administration to mice. J Nutr. 2003;133(12):4172–4177. 10.1093/jn/133.12.4172 14652367
23 Record IR Lane JM Simulated intestinal digestion of green and black teas. Food Chem. 2001;73:481–486.10.1016/S0308-8146(01)00131-5
24 Green RJ Murphy AS Schulz B Watkins BA Ferruzzi MG Common tea formulations modulate in vitro digestive recovery of green tea catechins. Mol Nutr Food Res. 2007;51(9):1152–1162. 10.1002/mnfr.200700086 17688297
25 Vaidyanathan JB Walle T Transport and metabolism of the tea flavonoid (-)-epicatechin by the human intestinal cell line Caco-2. Pharm Res. 2001;18(10):1420–1425. 10.1023/A:1012200805593 11697467
26 Chow HH Hakim IA Vining DR Crowell JA Ranger-Moore J Chew WM Celaya CA Rodney SR Hara Y Alberts DS Effects of dosing condition on the oral bioavailability of green tea catechins after single-dose administration of Polyphenon E in healthy individuals. Clin Cancer Res. 2005;11(12):4627–4633. 10.1158/1078-0432.CCR-04-2549 15958649
27 Kim S Lee MJ Hong J Li C Smith TJ Yang GY Seril DN Yang CS Plasma and tissue levels of tea catechins in rats and mice during chronic consumption of green tea polyphenols. Nutr Cancer. 2000;37(1):41–48. 10.1207/S15327914NC3701_5 10965518
28 Chu KO Wang CC Chu CY Chan KP Rogers MS Choy KW Pang CP Pharmacokinetic studies of green tea catechins in maternal plasma and fetuses in rats. J Pharm Sci. 2006;95(6):1372–1381. 10.1002/jps.20594 16625654
29 Lin LC Wang MN Tseng TY Sung JS Tsai TH Pharmacokinetics of (-)-epigallocatechin-3-gallate in conscious and freely moving rats and its brain regional distribution. J Agric Food Chem. 2007;55(4):1517–1524. 10.1021/jf062816a 17256961
30 Wu L Zhang QL Zhang XY Lv C Li J Yuan Y Yin FX Pharmacokinetics and blood-brain barrier penetration of (+)-catechin and (-)-epicatechin in rats by microdialysis sampling coupled to high-performance liquid chromatography with chemiluminescence detection. J Agric Food Chem. 2012;60(37):9377–9383. 10.1021/jf301787f 22953747
31 Chu KO Wang CC Chu CY Choy KW Pang CP Rogers MS Uptake and distribution of catechins in fetal organs following in utero exposure in rats. Hum Reprod. 2007;22(1):280–287. 10.1093/humrep/del353 16959805
32 Swezey RR Aldridge DE LeValley SE Crowell JA Hara Y Green CE Absorption, tissue distribution and elimination of 4-[(3)h]-epigallocatechin gallate in beagle dogs. Int J Toxicol. 2003;22(3):187–193. 10.1080/10915810305101 12851151
33 Kapetanovic IM Crowell JA Krishnaraj R Zakharov A Lindeblad M Lyubimov A Exposure and toxicity of green tea polyphenols in fasted and non-fasted dogs. Toxicology. 2009;260(1-3):28–36. 10.1016/j.tox.2009.03.007 19464566
34 Feng WY Metabolism of green tea catechins: an overview. Curr Drug Metab. 2006;7(7):755–809. 10.2174/138920006778520552 17073579
35 Sang S Lambert JD Hong J Tian S Lee MJ Stark RE Ho CT Yang CS Synthesis and structure identification of thiol conjugates of (-)-epigallocatechin gallate and their urinary levels in mice. Chem Res Toxicol. 2005;18(11):1762–1769. 10.1021/tx050151l 16300386
36 Sang S Lee MJ Yang I Buckley B Yang CS Human urinary metabolite profile of tea polyphenols analyzed by liquid chromatography/electrospray ionization tandem mass spectrometry with data-dependent acquisition. Rapid Commun Mass Spectrom. 2008;22(10):1567–1578. 10.1002/rcm.3546 18433082
37 Selma MV Espín JC Tomás-Barberán FA Interaction between phenolics and gut microbiota: role in human health. J Agric Food Chem. 2009;57(15):6485–6501. 10.1021/jf902107d 19580283
38 Okushio K, Suzuki M, Matsumoto N, Nanjo F, Hara Y. Identification of (–)-epicatechin metabolites and their metabolic fate in the rat. Drug Metab Dispos. 1999; 27:309-316. 9929521
39 Okushio K Suzuki M Matsumoto N Nanjo F Hara Y Methylation of tea catechins by rat liver homogenates. Biosci Biotechnol Biochem. 1999;63(2):430–432. 10.1271/bbb.63.430 10192923
40 Meng X Sang S Zhu N Lu H Sheng S Lee MJ Ho CT Yang CS Identification and characterization of methylated and ring-fission metabolites of tea catechins formed in humans, mice, and rats. Chem Res Toxicol. 2002;15(8):1042–1050. 10.1021/tx010184a 12184788
41 Lu H Meng X Li C Sang S Patten C Sheng S Hong J Bai N Winnik B Ho CT Glucuronides of tea catechins: enzymology of biosynthesis and biological activities. Drug Metab Dispos. 2003;31(4):452–461. 10.1124/dmd.31.4.452 12642472
42 Lu H Meng X Yang CS Enzymology of methylation of tea catechins and inhibition of catechol-O-methyltransferase by (-)-epigallocatechin gallate. Drug Metab Dispos. 2003;31(5):572–579. 10.1124/dmd.31.5.572 12695345
43 Jodoin J Demeule M Béliveau R Inhibition of the multidrug resistance P-glycoprotein activity by green tea polyphenols. Biochim Biophys Acta. 2002;1542(1-3):149–159. 10.1016/S0167-4889(01)00175-6 11853888
44 Qian F Wei D Zhang Q Yang S Modulation of P-glycoprotein function and reversal of multidrug resistance by (-)-epigallocatechin gallate in human cancer cells. Biomed Pharmacother. 2005;59(3):64–69. 10.1016/j.biopha.2005.01.002 15795098
45 Farabegoli F Papi A Bartolini G Ostan R Orlandi M (-)-Epigallocatechin-3-gallate downregulates Pg-P and BCRP in a tamoxifen resistant MCF-7 cell line. Phytomedicine. 2010;17(5):356–362. 10.1016/j.phymed.2010.01.001 20149610
46 Nishikawa M Ariyoshi N Kotani A Ishi I Nakamura H Nakasa H Ida M Nakamura H Kimura N Kimura M Effects of continuous ingestion of green tea or grape seed extracts on the pharmacokinetics of midazolam. Drug Metab Pharmacokin. 2004; 19:280-289. 10.2133/dmpk.19.280
47 Chung JH Choi DH Choi JS Effects of oral epigallocatechin gallate on the oral pharmacokinetics of verapamil in rats. Biopharm Drug Disp. 2009; 30:90-93. 10.1002/bdd.644
48 Shin SC Choi JS Effects of epigallocatechin gallate on the oral bioavailability and pharmacokinetics of tamoxifen and its main metabolite, 4-hydroxytamoxifen, in rats. Anticancer Drugs. 2009;20(7):584–588. 10.1097/CAD.0b013e32832d6834 19491656
49 Yang CS, Chen L, Lee MJ, Balentine D, Kuo MC, Schantz SP. Blood and urine levels of tea catechins after ingestion of different amounts of green tea by human volunteers. Cancer Epidemiol Biomarkers Prev. 1998; 7:351-354. 9568793
50 Ullmann U Haller J Decourt JP Girault N Girault J Richard-Caudron AS Pineau B Weber P A single ascending dose study of epigallocatechin gallate in healthy volunteers. J Int Med Res. 2003;31(2):88–101. 10.1177/147323000303100205 12760312
51 Van Amelsvoort JM Van Hof KH Mathot JN Mulder TP Wiersma A Tijburg LB Plasma concentrations of individual tea catechins after a single oral dose in humans. Xenobiotica. 2001;31(12):891–901. 10.1080/00498250110079149 11780763
52 Lee MJ, Maliakal P, Chen L, Meng X, Bondoc FY, Prabhu S, Lambert G, Mohr S, Yang CS. Pharmacokinetics of tea catechins after ingestion of green tea and (−)-epigallocatechin-3-gallate by humans: Formation of different metabolites and individual variability. Cancer Epidemiol Biomarkers Prev. 2002; 11:1025-1032. 12376503
53 Nagai M Conney AH Zhu BT Strong inhibitory effects of common tea catechins and bioflavonoids on the O-methylation of catechol estrogens catalyzed by human liver cytosolic catechol-O-methyltransferase. Drug Metab Dispos. 2004;32(5):497–504. 10.1124/dmd.32.5.497 15100171
54 Mohamed MF Tseng T Frye RF Inhibitory effects of commonly used herbal extracts on UGT1A1 enzyme activity. Xenobiotica. 2010;40(10):663–669. 10.3109/00498254.2010.505669 20666626
55 Mohamed MEF Frye RF Inhibitory effects of commonly used herbal extracts on UDP-glucuronosyltransferase 1A4, 1A6, and 1A9 enzyme activities. Drug Metab Dispos. 2011;39(9):1522–1528. 10.1124/dmd.111.039602 21632963
56 Isbrucker RA Edwards JA Wolz E Davidovich A Bausch J Safety studies on epigallocatechin gallate (EGCG) preparations. Part 2: dermal, acute and short-term toxicity studies. Food Chem Toxicol. 2006;44(5):636–650. 10.1016/j.fct.2005.11.003 16387402
57 Takami S Imai T Hasumura M Cho YM Onose J Hirose M Evaluation of toxicity of green tea catechins with 90-day dietary administration to F344 rats. Food Chem Toxicol. 2008;46(6):2224–2229. 10.1016/j.fct.2008.02.023 18400353
58 Lambert JD Kennett MJ Sang S Reuhl KR Ju J Yang CS Hepatotoxicity of high oral dose (-)-epigallocatechin-3-gallate in mice. Food Chem Toxicol. 2010;48(1):409–416. 10.1016/j.fct.2009.10.030 19883714
59 Chandra AK De N Goitrogenic/antithyroidal potential of green tea extract in relation to catechin in rats. Food Chem Toxicol. 2010;48(8-9):2304–2311. 10.1016/j.fct.2010.05.064 20561943
60 Yoshida M Takahashi M Inoue K Nakae D Nishikawa A Lack of chronic toxicity and carcinogenicity of dietary administrated catechin mixture in Wistar Hannover GALAS rats. J Toxicol Sci. 2011;36(3):297–311. 10.2131/jts.36.297 21628958
61 Mazzanti G Menniti-Ippolito F Moro PA Cassetti F Raschetti R Santuccio C Mastrangelo S Hepatotoxicity from green tea: a review of the literature and two unpublished cases. Eur J Clin Pharmacol. 2009;65(4):331–341. 10.1007/s00228-008-0610-7 19198822
62 Laurie SA Miller VA Grant SC Kris MG Ng KKPhase I study of green tea extract in patients with advanced lung cancer. Chemother Pharmacol. 2006; 55:33-38. 10.1007/s00280-004-0859-1
63 Crew KD Brown P Greenlee H Bevers TB Arun B Hudis C McArthur HL Chang J Rimawi M Vornik L Phase IB randomized, double-blinded, placebo-controlled, dose escalation study of polyphenon E in women with hormone receptor-negative breast cancer. Cancer Prev Res (Phila). 2012;5(9):1144–1154. 10.1158/1940-6207.CAPR-12-0117 22827973
64 Isbrucker RA Edwards JA Wolz E Davidovich A Bausch J Safety studies on epigallocatechin gallate (EGCG) preparations. Part 3: teratogenicity and reproductive toxicity studies in rats. Food Chem Toxicol. 2006;44(5):651–661. 10.1016/j.fct.2005.11.002 16410036
65 Morita O Knapp JF Tamaki Y Stump DG Moore JS Nemec MD Effects of green tea catechin on embryo/fetal development in rats. Food Chem Toxicol. 2009;47(6):1296–1303. 10.1016/j.fct.2009.03.005 19285533
66 Park D Jeon JH Shin S Joo SS Kang DH Moon SH Jang MJ Cho YM Kim JW Ji HJ Green tea extract increases cyclophosphamide-induced teratogenesis by modulating the expression of cytochrome P-450 mRNA. Reprod Toxicol. 2009;27(1):79–84. 10.1016/j.reprotox.2008.11.058 19103281
67 Logsdon AL Herring BJ Lockard JE Miller BM Kim H Hood RD Bailey MM Exposure to green tea extract alters the incidence of specific cyclophosphamide-induced malformations. Birth Defects Res B Dev Reprod Toxicol. 2012;95(3):231–237. 10.1002/bdrb.21011 22447743
68 Stratton SP Bangert JL Alberts DS Dorr RT Dermal toxicity of topical (-)epigallocatechin-3-gallate in BALB/c and SKH1 mice. Cancer Lett. 2000;158(1):47–52. 10.1016/S0304-3835(00)00498-5 10940508
69 Haqqi TM Anthony DD Gupta S Ahmad N Lee MS Kumar GK Mukhtar H Prevention of collagen-induced arthritis in mice by a polyphenolic fraction from green tea. Proc Natl Acad Sci USA. 1999;96(8):4524–4529. 10.1073/pnas.96.8.4524 10200295
70 Varilek GW Yang F Lee EY deVilliers WJS Zhong J Oz HS Westberry KF McClain CJ Green tea polyphenol extract attenuates inflammation in interleukin-2-deficient mice, a model of autoimmunity. J Nutr. 2001;131(7):2034–2039. 10.1093/jn/131.7.2034 11435526
71 Hsu SD Dickinson DP Qin H Borke J Ogbureke KUE Winger JN Camba AM Bollag WB Stöppler HJ Sharawy MM Green tea polyphenols reduce autoimmune symptoms in a murine model for human Sjogren’s syndrome and protect human salivary acinar cells from TNF-α-induced cytotoxicity. Autoimmunity. 2007;40(2):138–147. 10.1080/08916930601167343 17364504
72 Shirai T Sato A Chida K Hayakawa H Akiyama J Iwata M Taniguchi M Reshad K Hara Y Epigallocatechin gallate-induced histamine release in patients with green tea-induced asthma. Ann Allergy Asthma Immunol. 1997;79(1):65–69. 10.1016/S1081-1206(10)63087-6 9236503
73 Shirai T Reshad K Yoshitomi A Chida K Nakamura H Taniguchi M Green tea-induced asthma: relationship between immunological reactivity, specific and non-specific bronchial respon-siveness. Clin Exp Allergy. 2003;33:1251–1255.10.1046/j.1365-2222.2003.01744.x
74 Hirose M Hoshiya T Akagi K Takahashi S Hara Y Ito N Effects of green tea catechins in a rat multi-organ carcinogenesis model. Carcinogenesis. 1993;14(8):1549–1553. 10.1093/carcin/14.8.1549 8353840
75 Nagao M Takahashi Y Yamanaka H Sugimura T Mutagens in coffee and tea. Mutat Res. 1979;68(2):101–106. 10.1016/0165-1218(79)90137-X 390384
76 Alejandre-Durán E Alonso-Moraga A Pueyo C Implication of active oxygen species in the direct-acting mutagenicity of tea. Mutat Res. 1987;188(4):251–257. 10.1016/0165-1218(87)90001-2 3302694
77 Mortelmans K Haworth S Lawlor T Speck W Tainer B Zeiger E Salmonella mutagenicity tests: II. Results from the testing of 270 chemicals. Environ Mutagen. 1986;8 Suppl 7:1–119. 10.1002/em.2860080802 3516675
78 Uyeta M Taue S Mazaki M Mutagenicity of hydrolysates of tea infusions. Mutat Res. 1981;88(3):233–240. 10.1016/0165-1218(81)90035-5 7019686
79 Tewes FJ Koo LC Meisgen TJ Rylander R Lung cancer risk and mutagenicity of tea. Environ Res. 1990;52(1):23–33. 10.1016/S0013-9351(05)80148-3 2351126
80 Ogura R Ikeda N Yuki K Morita O Saigo K Blackstock C Nishiyama N Kasamatsu T Genotoxicity studies on green tea catechin. Food Chem Toxicol. 2008;46(6):2190–2200. 10.1016/j.fct.2008.02.016 18381228
81 Chang PY Mirsalis J Riccio ES Bakke JP Lee PS Shimon J Phillips S Fairchild D Hara Y Crowell JA Genotoxicity and toxicity of the potential cancer-preventive agent polyphenon E. Environ Mol Mutagen. 2003;41(1):43–54. 10.1002/em.10129 12552591
82 Brown JP Dietrich PS Mutagenicity of plant flavonols in the Salmonella/mammalian microsome test: activation of flavonol glycosides by mixed glycosidases from rat cecal bacteria and other sources. Mutat Res. 1979;66(3):223–240. 10.1016/0165-1218(79)90083-1 375081
83 Spencer JPE Metabolism of tea flavonoids in the gastrointestinal tract. J Nutr. 2003;133(10):3255S–3261S. 10.1093/jn/133.10.3255S 14519823
84 Elbling L Weiss RM Teufelhofer O Uhl M Knasmueller S Schulte-Hermann R Berger W Micksche M Green tea extract and (-)-epigallocatechin-3-gallate, the major tea catechin, exert oxidant but lack antioxidant activities. FASEB J. 2005;19(7):807–809. 10.1096/fj.04-2915fje 15738004
85 Imanishi H Sasaki YF Ohta T Watanabe M Kato T Shirasu Y Tea tannin components modify the induction of sister-chromatid exchanges and chromosome aberrations in mutagen-treated cultured mammalian cells and mice. Mutat Res. 1991;259(1):79–87. 10.1016/0165-1218(91)90111-X 1899132
86 Lorenz M Cellular targets for the beneficial actions of tea polyphenols. Am J Clin Nutr. 2013;98(6) Suppl:1642S–1650S. 10.3945/ajcn.113.058230 24172299
87 Isbrucker RA Bausch J Edwards JA Wolz E Safety studies on epigallocatechin gallate (EGCG) preparations. Part 1: genotoxicity. Food Chem Toxicol. 2006;44(5):626–635. 10.1016/j.fct.2005.07.005 16364532
88 Ullmann U Haller J Decourt JD Girault J Spitzer V Weber P Plasma-kinetic characteristics of purified and isolated green tea catechin epigallocatechin gallate (EGCG) after 10 days repeated dosing in healthy volunteers. Int J Vitam Nutr Res. 2004;74(4):269–278. 10.1024/0300-9831.74.4.269 15580809
89 Yuquan L Takeshita T Morimoto K Effects of (-)-epigallocatechin gallate (EGCG) on DNA strand breaks as evaluated by single-cell gel electrophoresis (SCG) in human lymphocytes. Environ Health Prev Med. 2001;5(4):150–154. 10.1007/BF02918291 21432404
90 Kanadzu M Lu Y Morimoto K Dual function of (—)-epigallocatechin gallate (EGCG) in healthy human lymphocytes. Cancer Lett. 2006;241(2):250–255. 10.1016/j.canlet.2005.10.021 16303244
91 Hayatsu H Inada N Kakutani T Arimoto S Negishi T Mori K Okuda T Sakata I Suppression of genotoxicity of carcinogens by (-)-epigallocatechin gallate. Prev Med. 1992;21(3):370–376. 10.1016/0091-7435(92)90044-I 1614998
92 Gupta S Saha B Giri AK Comparative antimutagenic and anticlastogenic effects of green tea and black tea: a review. Mutat Res. 2002;512(1):37–65. 10.1016/S1383-5742(02)00024-8 12220589
93 Kuroda Y Hara Y Antimutagenic and anticarcinogenic activity of tea polyphenols. Mutat Res. 1999;436(1):69–97. 10.1016/S1383-5742(98)00019-2 9878691
94 Zeiger E What is needed for an acceptable antimutagenicity manuscript? Mutat Res. 2007;626(1-2):1–3. 10.1016/j.mrgentox.2006.10.011 17141555
95 Sander LC Bedner M Tims MC Yen JH Duewer DL Porter B Christopher SJ Day RD Long SE Molloy JL Development and certification of green tea-containing standard reference materials. Anal Bioanal Chem. 2012;402(1):473–487. 10.1007/s00216-011-5472-7 22127575
96 Seeram NP Henning SM Niu Y Lee R Scheuller HS Heber D Catechin and caffeine content of green tea dietary supplements and correlation with antioxidant capacity. J Agric Food Chem. 2006;54(5):1599–1603. 10.1021/jf052857r 16506807
97 Henning SM Fajardo-Lira C Lee HW Youssefian AA Go VL Heber D Catechin content of 18 teas and a green tea extract supplement correlates with the antioxidant capacity. Nutr Cancer. 2003;45(2):226–235. 10.1207/S15327914NC4502_13 12881018
98 Cabrera C Giménez R López MC Determination of tea components with antioxidant activity. J Agric Food Chem. 2003;51(15):4427–4435. 10.1021/jf0300801 12848521
99 King-Herbert A Thayer K NTP workshop: animal models for the NTP rodent cancer bioassay: stocks and strains—should we switch? Toxicol Pathol. 2006;34(6):802–805. 10.1080/01926230600935938 17162538
100 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. 10.1177/019262338201000210 28094716
101 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies In: Weisburger HA, E.K. M, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyes Publications; 1985. p. 345-357.
102 Boorman GA Morgan KT Uriah LC Nose, larynx, and trachea. In: Boorman GA Eustis SL Elwell MR Montgomery CA Mackenzie WFeditors. Pathology of the Fischer Rat. San Diego (CA): Academic Press; 1990. p. 315–337.
103 McConnell EE, Solleveld HA, Swenberg JA, Boorman GA. Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI. 1986; 76:283-289. 3456066
104 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958;53:457–481.10.1080/01621459.1958.10501452
105 Cox DR Regression models and life-tables. J R Stat Soc [Ser A]. 1972;B34:187–220.
106 Tarone RE Tests for trend in life table analysis. Biometrika. 1975;62:679–682.10.1093/biomet/62.3.679
107 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44(2):417–431. 10.2307/2531856 3390507
108 Portier CJ Bailer AJ Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989;12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
109 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology. London: Chapman and Hall; 1997. p.
110 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46:4372-4378. 3731095
111 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;49(3):793–801. 10.2307/2532200 8241374
112 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. JNCI. 1979; 62:957-974. 285297
113 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50:1096–1121.10.1080/01621459.1955.10501294
114 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. 10.2307/2528930 5547548
115 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. 10.2307/2556164 5037867
116 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
117 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. 10.2307/2531254 3719054
118 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6:241–252.10.1080/00401706.1964.10490181
119 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41:133–145.10.1093/biomet/41.1-2.133
120 Dixon WJ Massey FJ Jr Introduction to Statistical Analysis. New York: McGraw Hill Book Company, Inc.; 1957.10.2307/2332898
121 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987;43(1):225–234. 10.2307/2531963 3567307
122 Haseman JK Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992;26:191–200.10.1177/009286159202600210
123 Haseman JK Data analysis: statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995;21(1):52–59, discussion 81–86. 10.1006/rtph.1995.1009 7784636
124 Code of Federal Regulations (CFR). 21:Part 58.
125 Schmid W The micronucleus test. Mutat Res. 1975;31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
126 Heddle JA Hite M Kirkhart B Mavournin K MacGregor JT Newell GW Salamone MF The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983;123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
127 Miller JA Miller EC Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH Watson JD Winsten JAeditors. Origins of Human Cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. p. 605–627.
128 Straus DS. Somatic mutation, cellular dif-ferentiation, and cancer causation. JNCI. 1981; 67:233-241. 7021938
129 Crawford BD Perspectives on the somatic mutation model of carcinogenesis. Princeton (NJ): Princeton Scientific Publishing Co., Inc.; 1985.
130 Ashby J Tennant RW Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991;257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
131 Tennant RW Margolin BH Shelby MD Zeiger E Haseman JK Spalding J Caspary W Resnick M Stasiewicz S Anderson B Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987;236(4804):933–941. 10.1126/science.3554512 3554512
132 Zeiger E Haseman JK Shelby MD Margolin BH Tennant RW Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990;16 Suppl 18:1–14. 10.1002/em.2850160502 2091921
133 Shelby MD Erexson GL Hook GJ Tice RR Evaluation of a three-exposure mouse bone marrow micronucleus protocol: results with 49 chemicals. Environ Mol Mutagen. 1993;21(2):160–179. 10.1002/em.2850210210 8444144
134 Shelby MD Witt KL Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995;25(4):302–313. 10.1002/em.2850250407 7607185
135 Witt KL Knapton A Wehr CM Hook GJ Mirsalis J Shelby MD MacGregor JT Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ Mol Mutagen. 2000; 36:163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
136 Johnson WD Morrissey RL Crowell JA McCormick DL Subchronic oral toxicity of green tea polyphenols in rats and dogs. Toxicol Sci. 1999;48(1) Suppl.:57–58. [Abstr.].
137 Kao YH Hiipakka RA Liao S Modulation of endocrine systems and food intake by green tea epigallocatechin gallate. Endocrinology. 2000;141(3):980–987. 10.1210/endo.141.3.7368 10698173
138 Monteiro R Assunção M Andrade JP Neves D Calhau C Azevedo I Chronic green tea consumption decreases body mass, induces aromatase expression, and changes proliferation and apoptosis in adult male rat adipose tissue. J Nutr. 2008;138(11):2156–2163. 10.1093/jn/138.11.2156 18936213
139 Wu D Wang J The ability of green tea to alleviate autoimmune diseases: fact or fiction? Expert Rev Clin Immunol. 2011;7(6):711–713. 10.1586/eci.11.67 22014009
140 Yang TTC Koo MWL Chinese green tea lowers cholesterol level through an increase in fecal lipid excretion. Life Sci. 2000;66(5):411–423. 10.1016/S0024-3205(99)00607-4 10670829
141 Chan PC Ramot Y Malarkey DE Blackshear P Kissling GE Travlos G Nyska A Fourteen-week toxicity study of green tea extract in rats and mice. Toxicol Pathol. 2010;38(7):1070–1084. 10.1177/0192623310382437 20884815
142 Chung KT Wong TY Wei CI Huang YW Lin Y Tannins and human health: a review. Crit Rev Food Sci Nutr. 1998;38(6):421–464. 10.1080/10408699891274273 9759559
143 Price ML Hagerman AE Butler LG Tannin content of cowpeas, chickpeas, pigeon peas, and mung beans. J Agric Food Chem. 1980;28(2):459–461. 10.1021/jf60228a047 7391382
144 Dahl AR Hadley WM Nasal cavity enzymes involved in xenobiotic metabolism: effects on the toxicity of inhalants. Crit Rev Toxicol. 1991;21(5):345–372. 10.3109/10408449109019571 1741949
145 Reed CJ Drug metabolism in the nasal cavity: relevance to toxicology. Drug Metab Rev. 1993;25(1-2):173–205. 10.3109/03602539308993975 8449146
146 Lock EA Harpur ES Toxicology of sensory systems: a perspective. Hum Exp Toxicol. 1992;11(6):442–448. 10.1177/096032719201100602 1361131
147 Damsch S Eichenbaum G Looszova A Lammens L Feyen B Van den Bulck K Knight E Kelley M Tonelli A Unexpected nasal changes in rats related to reflux after gavage dosing. Toxicol Pathol. 2011; 39:337 347. 10.1177/0192623310388430
148 Damsch S Eichenbaum G Tonelli A Lammens L Van den Bulck K Feyen B Vandenberghe J Megens A Knight E Kelley M Gavage-related reflux in rats: identification, pathogenesis, and toxicological implications (review). Toxicol Pathol. 2011;39(2):348–360. 10.1177/0192623310388431 21422261
149 Boyd EM Bereczky K Godi I The acute toxicity of tannic acid administered intra-gastrically. Can Med Assoc J. 1965;92:1291–1297.
150 Dollahite JW, Camp BJ. Calcium hydroxide–an antidote for tannic acid poisoning in rabbits. Am J Vet Res. 1962; 23:1271-1272. 14028468
151 Gloro R Hourmand-Ollivier I Mosquet B Mosquet L Rousselot P Salamé E Piquet MA Dao T Fulminant hepatitis during self-medication with hydroalcoholic extract of green tea. Eur J Gastroenterol Hepatol. 2005;17(10):1135–1137. 10.1097/00042737-200510000-00021 16148563
152 Patel SS Beer S Kearney DL Phillips G Carter BA Green tea extract: a potential cause of acute liver failure. World J Gastroenterol. 2013;19(31):5174–5177. 10.3748/wjg.v19.i31.5174 23964154
153 Goodin MG Bray BJ Rosengren RJ Sex- and strain-dependent effects of epigallocatechin gallate (EGCG) and epicatechin gallate (ECG) in the mouse. Food Chem Toxicol. 2006;44(9):1496–1504. 10.1016/j.fct.2006.04.012 16762473
154 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992;19 Suppl 21:2–141. 10.1002/em.2850190603 1541260
155 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990;14(3):513–522. 10.1016/0272-0590(90)90255-I 2111256