# Conclusions

Under the conditions of these 2-year gavage studies, there was no evidence of carcinogenic activity^a^ of green tea extract in male or female Wistar Han rats administered 100, 300, or 1,000 mg/kg. There was no evidence of carcinogenic activity of green tea extract in male or female B6C3F1/N mice administered 30, 100, or 300 mg/kg.

a See Explanation of Levels of Evidence of Carcinogenic Activity. See summary of the peer review panel comments and the public discussion on this Technical Report in Appendix L.

Administration of green tea extract resulted in increased incidences of nonneoplastic lesions of the liver, glandular stomach, small intestine (duodenum, ileum, and jejunum), nose, lung, heart, and spleen in male and female rats; bone marrow of female rats; the nose, mandibular lymph node, and bone marrow of male and female mice; and the liver of male mice.