# Discussion

Green tea extract is the purported active ingredient of many weight loss and nutritional supplements. Also, green tea extract, or components thereof, are currently being investigated in multiple human clinical trials as a potential treatment for various cancers, hypercholesterolemia, diabetes, and cardiovascular diseases. Despite widespread use, the potential adverse effects of repeated chronic consumption of green tea extract supplements, which contain constituent levels higher than the traditional green tea beverage, have not been adequately investigated. Hence, green tea extract was tested by NTP to characterize its potential subchronic and chronic toxicity and carcinogenicity. NTP conducted 3-month toxicology studies of green tea extract in F344/NTac rats and B6C3F1/N mice and 2-year toxicology and carcinogenicity studies in Wistar Han rats and B6C3F1/N mice. A gavage route of administration was selected to mimic human consumption of supplements. A 3-month interim evaluation was conducted during the 2-year rat study to compare high dose effects (1,000 mg/kg) between F344/NTac and Wistar Han rats.

Prior to the toxicity evaluation, green tea extract lots were characterized by NTP. A number of green tea extract formulations with varying concentrations of active ingredient are available as over-the-counter products in grocery stores and pharmacies in the United States. Comparative studies have been performed on a few of the commercially available products to determine the catechin polyphenol and caffeine content of different preparations^6,96-98^ and results demonstrated a wide variation in concentrations of catechins and caffeine in different green tea extract products. In addition, the measured catechin polyphenol and caffeine content in many products did not match their corresponding label claims. Caffeine was found to be present in most of the products but only a few products made label claims about the quantities of caffeine present.^6,96^ For the current studies, NTP conducted a chemical content analysis on four commercially available products and selected a representative green tea extract. Selection was based upon concentrations of EGCG, lack of adulteration, similarity with other products on the market, and availability in bulk quantity. The proportion of catechin polyphenols in NTP’s test article was similar to that in Standard Reference Material 3255 identified by the National Institute of Standards and Technology.^95^

Doses for the 3-month studies in rats and mice were selected based on a 3-month study conducted by the National Cancer Institute (NCI) using 1,000 mg/kg of green tea catechin polyphenols as the highest dose in Harlan Sprague-Dawley rats.^136^ The abstract for that study described increased treatment-related deaths in the 1,000 mg/kg group, dose-related suppression of body weight gains, and reduced spleen and thymus weights. Intestinal dilation was noted in many of the early death and terminally killed animals. NTP selected a top dose of 1,000 mg/kg for the current 3-month studies because it was not known if F344/NTac rats and B6C3F1/N mice were more or less sensitive to green tea extract administration. Additionally, because the majority of botanical extracts are not standardized, there was a high probability that substantial variability in concentrations of catechin polyphenols would exist between the two test green tea extracts used by the NCI and NTP.

In the current 3-month F344/NTac rat study, there were no treatment-related adverse effects on survival. However, administration of 250 mg/kg or greater was associated with significant decreases in body weights (5% to 14%) in male and female rats. Histologic lesions associated with green tea extract administration occurred in the liver (females only), nose, lymph nodes (males only), and thymus of rats and the incidences of these lesions increased in a dose-dependent manner. Because administration of 1,000 mg/kg had no effect on survival and the reductions in body weights and the histopathologic lesions were not considered to be dose limiting, a high dose of 1,000 mg/kg was selected for the 2-year studies in Wistar Han rats. Consistently, Wistar Han rats administered 1,000 mg/kg and evaluated at 3 months displayed little or no reductions in body weight. Mice appeared to be more sensitive in the 3-month study with regard to effects on survival following green tea extract administration, because significant mortality was observed in males and females administered 1,000 mg/kg. The treatment-related decreases in final mean body weights of males and females administered 250 mg/kg or greater ranged from 12% to 24%. Treatment-related lesions were observed in the liver, nose, lymph nodes, spleen (females only), and thymus in mice. In male mice, significant increases in the incidences of various nonneoplastic lesions of the nose were observed in the 250 mg/kg or greater groups. Based on these observations, 300 mg/kg was selected as the high dose for 2-year studies in B6C3F1/N mice.

In the 2-year Wistar Han rat study, survival of 1,000 mg/kg males and females was significantly less than survival of the vehicle control groups. No signs of overt toxicity were observed in the rats except decreased body weights in male rats. The increase in mortality in 1,000 mg/kg female rats did not correlate with decreases in body weight. The increased deaths in green tea extract treated rats could be ascribed to gastrointestinal toxicity. Macroscopic analysis of the gastrointestinal tract showed dose-related increased incidences of gray to black, focal to diffuse discoloration of the mucosa and wall of the stomach and small intestine. Previous studies of green tea extract toxicity in Harlan Sprague-Dawley rats (fed) and beagle dogs (fasted) demonstrated similar gross histopathologic changes in the gastrointestinal tract and unexpected mortality.^33,136^ The increased mortality in rats could also partly be related to dose-dependent increases in nasal lesions in male and female rats. At 2 years, a spectrum of inflammatory and degenerative lesions in the nose was observed in all dosed groups of rats.

Decreased body weight gain after green tea extract consumption has been previously demonstrated in both animals and humans.^58,137-139^ The mechanisms of dose-dependent decreases in body weight in the 3-month and 2-year rat and mouse studies are not known, and the decreases might be attributed to decreased feed consumption and inhibition of intestinal nutrient absorption.^57,140,141^ Green tea extract is rich in catechin polyphenols, which are also classified as condensed tannins. Studies in experimental animals have associated consumption of feed rich in condensed tannins to decreased feed intake, protein digestibility, and growth rate.^142^ Condensed tannins have been shown to inhibit numerous digestive enzymes such as cellulose, pectinase, amylase, lipase, proteolytic enzymes, and β-galactosidase in vitro. It has also been reported that dietary tannins form complexes with dietary protein and reduce the digestibility and absorption of proteins.^142,143^

In the current 3-month and 2-year studies, numerous histopathologic lesions occurred in the nose of F344/NTac rats, Wistar Han rats, and B6C3F1/N mice. In the 3-month studies, green tea extract administration significantly increased the incidences of inflammation (female F344/NTac rats only), hyperplasia of the Bowman’s gland underlying the olfactory epithelium (male and female F344/NTac rats only), nerve atrophy and atrophy of the olfactory epithelium, metaplasia and pigmentation (male and female F344/NTac rats only) of the olfactory epithelium, and necrosis of the olfactory epithelium (female B6C3F1/N mice only). Similar histopathologic changes of the nose were also observed in male and female Wistar Han rats at 3 months, but to a lesser extent than in F344/NTac rats.

In the 2-year studies in Wistar Han rats and B6C3F1/N mice, the most pronounced response was observed in the nose. Treatment with green tea extract produced a spectrum of inflammatory, degenerative, and proliferative lesions of the olfactory epithelium, nasopharyngeal duct, and respiratory epithelium in rats and mice. Significant and progressive increases in the incidences of inflammation, atrophy of the olfactory epithelium, nerve atrophy, metaplasia of the olfactory epithelium, and necrosis (rats only) occurred in both rats and mice. A treatment-related increase in the incidences of suppurative inflammation of the nasopharyngeal duct was noted in male and female rats. In addition, dose-dependent increases in excessive growth of turbinate bone (hyperostosis) and deformity were observed in Level III of the nose of dosed groups of rats while turbinate atrophy was observed in most 100 and 300 mg/kg male and female mice. Another distinct finding was the significantly increased occurrences of foreign body in the nose of male and female mice and female rats in the 2-year studies. In the 2-year mouse study, the nasal lesions were observed even in the low dose group (30 mg/kg). Inflammatory responses were also observed in the lung and epicardium of the heart in male and female rats during the 2-year study.

The nasal toxicity observed following oral exposure to green tea extract may be related to direct systemic toxicity of green tea extract or its metabolites. A significant amount of metabolizing enzyme activity is known to occur in the nasal epithelia in many species.^144,145^ Some of the active metabolizing enzymes present in nasal epithelium include CYP 450, glutathione-S-transferase, carboxylesterase, aldehyde dehydrogenase and flavin monooxygenases.^146^ Green tea catechins are known to undergo rapid and extensive metabolic transformations. Therefore, one of the potential mechanisms underlying the unexpected nasal toxicity observed may be the metabolic activation of green tea extract components. Another potential mechanism of the pathogenesis of nasal toxicity could be the retrograde aspiration of green tea extract or stomach acids into the nasal cavity. Articles published in the literature have described the characteristic histopathologic changes indicative of gavage-related reflux of irritant compounds.^147^ In the current 2-year studies, increased lesion incidences were observed in the posterior nose levels (Level II and Level III) and the presence of foreign bodies (which may have been the test article or feed material) were evident in a significant number of rats and mice in the highest dosed groups. These observations have been described as typical of gavage-related reflux and subsequent aspiration of irritant test material.^147,148^ Lesions observed in the lung and heart may represent an extension of the inflammatory process secondary to aspiration of test material.

Another important target organ system for green tea extract was found to be the gastrointestinal tract in rats. At 2 years, dose-dependent increases in the incidences of gray to black focal to diffuse discoloration were observed macroscopically in the stomach mucosa and small intestine of rats. These gross changes coincided with significant dose-dependent increases in the incidences of mucosa necrosis of the glandular stomach and all segments of the small intestine in males and females. These lesions throughout the gastrointestinal tract were primarily observed in the 1,000 mg/kg groups and correlated with the low survival observed in these groups. Microscopic evaluation of the necrotic tissue showed evidence of congestion and hemorrhage in the stomach and small intestine of a few rats. The green tea extract-induced gastrointestinal toxicity was consistent with previously published studies in animals and humans.^33,63^ In humans, severe rectal bleeding was reported in one female patient with a previous history of gastrointestinal bleeding during a Phase IB clinical trial of green tea extract conducted by NCI.^63^

Although the exact causes and mechanisms of observed gastrointestinal injury in the rats are not completely understood, injury could be attributed to administration of high amounts of condensed tannins or catechin polyphenols in the test compound. Previous studies have demonstrated that exposure to high amounts of tannins could cause gastroenteritis and intestinal wall congestion in rats^149^ and hemorrhagic gastroenteritis in rabbits.^150^ In contrast to the rats, no evidence of gastrointestinal injury was noted in the 2-year study in mice. The lack of gastrointestinal toxicity in mice may be attributed to the relatively lower doses used in the 2-year mouse study compared to the 2-year rat study.

The gavage route of administration may have contributed to observed toxicity (e.g., gastrointestinal toxicity and effects on survival) in rats. When a catechin mixture was administered in feed (0.02%, 0.3%, 1%, or 3%) in a 2-year exposure scenario, only effects on body weight and relative liver weights with centrilobular hypertrophy were noted.^60^ The high dose of 3% in the feed resulted in doses of 1,265.8 and 1,539.8 mg/kg per day (respectively) in male and female rats, higher than the 1,000 mg/kg dose used in the current study, suggesting that the co-administration of green tea catechins with food reduces the potential for chronic toxicity.

Case reports describe occasional cases of hepatotoxicity and liver failure following green tea extract use in humans.^7,61,63,151,152^ The potential hepatotoxicity leading to liver failure is a major safety concern in using green tea extract products.^7^ At 3 months in the NTP studies, histopathologic changes were noted in the liver of female F344/NTac and Wistar Han rats and in male and female B6C3F1/N mice in the 1,000 mg/kg groups. In female F344/NTac and Wistar Han rats at3 months, the liver lesions included inflammation, minimal bile duct hyperplasia, oval cell hyperplasia, hepatocyte hypertrophy, periportal hypertrophy, minimal to mild mitosis, and/or hepatocyte necrosis. Supportive evidence from clinical chemistry analyses showed significant increases in bile salt concentrations and alanine aminotransferase activities in the serum of the same F344/NTac rats at 3 months. Clinical chemistry endpoints were not measured in the Wistar Han rats at 3 months. Based on the incidences of hepatic necrosis, the mice showed relatively greater levels of hepatic toxicity than the rats following 3 months of dosing. Similarly, reports in the literature have found mice to be more sensitive to green tea extract-induced hepatic toxicity.^58^ These differences could be related to the greater bioavailability of EGCG in mice (26%) than in rats (1.6%).^21,22^

In the 2-year Wistar Han rat study, the incidences of hepatic necrosis were significantly increased only in the 1,000 mg/kg males and females, where decreases in survival were observed. Increased incidences of inflammation and hematopoietic cell proliferation were noted in 300 mg/kg male mice in the 2-year study. No pathological changes in the liver of female mice were related to green tea administration in the 2-year study. No obvious species differences in toxicity were noted in the 2-year studies.

There were gender differences in the sensitivity to induced hepatic toxicity in F344/NTac and Wistar Han rats exposed to green tea extract in the current studies. At 3 months, only a few female F344/NTac rats in the 1,000 mg/kg group developed hepatic necrosis and inflammation. At 2 years, although both male and female Wistar Han rats had increased incidences of hepatic necrosis, the incidences were higher in females (52%) than in males (26%) in the 1,000 mg/kg group. These findings are corroborated by reports in the literature that females appear to be more susceptible to EGCG and green tea extract-induced hepatotoxicity in animals as well as humans.^61,153^

In the 3-month and 2-year studies, effects of green tea extract administration were also observed in lymphoid organs such as the lymph nodes, spleen, and thymus. Significant decreases in spleen weights (male rats) and thymus weights (male and female rats and mice) were observed in the 3-month studies. Corresponding increased incidences of thymus atrophy were observed microscopically in male and female rats and mice in the 1,000 mg/kg groups. Other histopathologic changes in lymphoid organs in mice administered green tea extract for 3 months included atrophy of the mandibular lymph node (male and female mice) and lymphoid atrophy of the spleen (female mice) in the 1,000 mg/kg groups. In addition, significant dose-related increases in the incidences of bone marrow hyperplasia were observed in female rats and male and female mice in the 2-year study. These changes may have been in response to the effects that occurred in non-lymphoid organs, e.g., nose, and thus secondary alterations in response to green tea administration.

The NTP in vivo micronucleus test results with green tea extract were negative in mice and are similar to observations from several other in vivo genotoxicity tests of green tea extract or EGCG under a variety of exposure conditions (e.g., dietary, gavage, injection, single versus multiple exposures) and with different preparations of green tea extracts.^80,81,85,87^ The lack of genotoxic effects from exposure to green tea extract in vivo is consistent with the overall lack of carcinogenic activity in the 2-year bioassay.

In summary, the current 2-year studies of green tea extract identified liver, nose, and gastrointestinal tract (rats only) as the major targets for toxicity in Wistar Han rats and B6C3F1/N mice. This is the first report describing green tea extract-induced nasal lesions in rats and mice. Nasal toxicity associated with the administration of green tea extract for 2 years occurred in all dosed groups of rats and mice, even in the 30 mg/kg groups of mice. The observed nasal toxicity could be related to systemic exposure to green tea extract or its metabolites. However, the pattern of nasal changes observed suggests that gavage-related reflux of green tea extract or stomach contents could also be a potential inducer of nasal toxicity in rats and mice. At 2 years, significant necrosis was also noted in the gastrointestinal tract of 1,000 mg/kg male and female rats. Increased incidences of hepatic necrosis were noted in the 3-month studies of F344/N/Tac rats and B6C3F1/N mice and in the 2-year study in Wistar Han rats. Female rats appeared to be more susceptible to the liver toxicity of green tea extract in the 3-month and 2-year studies. The findings of liver and gastrointestinal toxicities correlate with reported incidences of hepatic necrosis and rectal bleeding in humans. The current studies indicate that green tea extract has the potential to cause hepatic and gastrointestinal toxicity when administered for prolonged periods in rats and mice.