# Results

## Three-month Study in F344/NTac Rats

One 125 mg/kg female died during week 7. All other rats survived to the end of the study (Table 3). Final mean body weights and mean body weight gains of males and females administered 250 mg/kg or greater were significantly less than those of the vehicle controls (Table 3 and Figure 4). Animals in the 1,000 mg/kg groups exhibited increased activity for the first 3 weeks of the study.

Table 3 Survival and Body Weights of F344/NTac Rats in the Three-month Gavage Study of Green Tea Extract^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 88 ± 2 | 340 ± 4 | 252 ± 4
62.5 | 10/10 | 86 ± 2 | 330 ± 4 | 244 ± 4 | 97
125 | 10/10 | 88 ± 2 | 330 ± 4 | 242 ± 3 | 97
250 | 10/10 | 87 ± 2 | 318 ± 4** | 231 ± 3** | 94
500 | 10/10 | 87 ± 2 | 302 ± 5** | 215 ± 5** | 89
1,000 | 10/10 | 87 ± 2 | 293 ± 4** | 207 ± 4** | 86
Female
0 | 10/10 | 81 ± 2 | 188 ± 2 | 108 ± 3
62.5 | 10/10 | 81 ± 2 | 184 ± 3 | 103 ± 3 | 98
125 | 9/10^c^ | 82 ± 2 | 184 ± 3 | 101 ± 3 | 98
250 | 10/10 | 80 ± 2 | 176 ± 2* | 97 ± 2* | 93
500 | 10/10 | 80 ± 2 | 179 ± 4* | 99 ± 3* | 95
1,000 | 10/10 | 81 ± 1 | 176 ± 3** | 94 ± 3** | 93

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Week of death: 7.

Figure 4

Growth Curves for F344/NTac Rats Administered Green Tea Extract by Gavage for Three Months

The hematology and clinical chemistry data for rats are presented in Table F-1. On day 4, the hematology findings demonstrated a minimal (approximately 5%), transient increase in the circulating erythron (evidenced by increases in hematocrit values, hemoglobin concentrations, and erythrocyte counts) in the 500 mg/kg females and the 1,000 mg/kg males and females. This erythron increase was consistent with a transient, physiologic, hemoconcentration-type response that resolved by day 23.

On days 4 and 23, small increases in alanine amino-transferase activity occurred in the 500 and 1,000 mg/kg males and females; the change resolved by week 14. Because sorbitol dehydrogenase activity, another marker of hepatocellular injury, was not affected at these time points, the transient increases in alanine aminotransferase activity were considered to be related to altered liver metabolism. At week 14, serum concentrations of total bile salts, a marker of hepatic function/injury and/or cholestasis, were increased approximately fivefold in the 1,000 mg/kg groups. Serum alkaline phosphatase activity (another marker of cholestasis), however, was not increased at week 14. Because serum alkaline phosphatase activity was not increased and bile salt concentration can also be affected by hepatic injury or altered function, it appeared the increases in bile salt concentration were not related to a cholestatic event. Interestingly, animal #113, a 1,000 mg/kg female that had an exceptionally high individual bile salt concentration (280 μmol/L) also had an exceptionally high serum alanine aminotransferase activity (7,780 IU/L). Considered together, these two values suggest this animal had treatment-related hepatocellular injury. At week 14, serum total protein and albumin (females only) concentrations were decreased in males and females administered 250 mg/kg or greater.

The absolute lung weights in all dosed groups of males were significantly decreased compared to those of the vehicle control group (up to 20.6% decrease in the 1,000 mg/kg group) (Table G-1). The absolute spleen weights were significantly decreased in all dosed groups of males, with an approximately 25% decrease at 1,000 mg/kg. The relative spleen weight of 1,000 mg/kg males was also significantly decreased (12.7%) when compared to that of the vehicle control group. The absolute testis weight of 1,000 mg/kg males was significantly decreased (6.9%). The absolute thymus weights were significantly decreased in 250 mg/kg and greater males, with a 36.5% decrease in the 1,000 mg/kg group. The relative thymus weight of the 1,000 mg/kg males was significantly decreased (26.2%). In females, the absolute thymus weights were significantly decreased in 500 and 1,000 mg/kg groups, by 17% and 15%, respectively; relative thymus weights were also significantly decreased in 500 and 1,000 mg/kg females, by 12% and 9.5%, respectively. There was an increase in the incidence of seminiferous tubule degeneration of the testes in the 1,000 mg/kg males when compared to the vehicle control group, although the increase was not significant by a pairwise comparison. There were significant increases in the incidences of atrophy of the thymus in 1,000 mg/kg males and females when compared to the vehicle control groups. Other tissues with organ weight changes had no correlating histopathologic changes. Although the absolute liver weight decreased in males, the decreases paralleled decreases in body weights. Despite histologic changes in the livers of three 1,000 mg/kg females, the liver weights were similar to vehicle controls.

Males administered 1,000 mg/kg exhibited significantly lower cauda epididymis (12%), epididymis (10%), and testis weights (4%) compared to those of the vehicle controls (Table H-1). Total sperm per cauda exhibited a negative trend (14% lower in the 1,000 mg/kg group). Females administered 1,000 mg/kg displayed an increase in estrous cycle length and spent significantly more time in extended diestrus than did the vehicle controls (Table H-2). Thus, under the conditions of these studies, green tea extract administered by oral gavage exhibited the potential to be a reproductive toxicant in male and female F344/NTac rats.

Relevant findings in the liver were limited to three female rats in the 1,000 mg/kg group (Table 4). Lesions included a single case of moderate hepatocyte necrosis characterized by necrotic hepatocytes, hemorrhage, and a mononuclear infiltrate in the centrilobular regions. The nuclei of necrotic hepatocytes frequently had pyknotic and karyorrhectic nuclei and either vacuolated or eosinophilic condensed cytoplasm. The necrosis was associated with mild chronic inflammation. Additional lesions in female rats included minimal bile duct hyperplasia, minimal to mild oval cell hyperplasia, and minimal to mild mitosis reflecting an increased number of hepatocytes with mitotic figures located in the midzonal regions between the periportal and centrilobular areas, as well as mild accumulation of golden brown pigment in Kupffer cells (consistent with ceroid lipofuscin and glycoprotein with special staining). Two female rats, including the one female rat with necrosis, were diagnosed with periportal hypertrophy. The hypertrophic hepatocytes also had karyomegaly.

Table 4 Incidences of Nonneoplastic Lesions of the Liver in Female F344/NTac Rats in the Three-month Gavage Study of Green Tea Extract

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Chronic Inflammation^a^ | 0 | 0 | 0 | 0 | 0 | 1 (2.0)^b^
Mitoses | 0 | 0 | 0 | 0 | 0 | 2 (1.5)
Bile Duct, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 3 (1.0)
Hepatocyte, Necrosis | 0 | 0 | 0 | 0 | 0 | 1 (3.0)
Oval Cell, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 3 (1.7)
Periportal, Hypertrophy | 0 | 0 | 0 | 0 | 0 | 2 (1.5)

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Significantly increased incidences of lesions in the nose were limited to males and females in the 500 and 1,000 mg/kg groups and included inflammation (females); hyperplasia of the glands underlying the olfactory epithelium (Bowman’s glands); nerve atrophy; and atrophy, metaplasia, and pigmentation of the olfactory epithelium (Table 5). Other biologically important lesions, which were not significantly increased, included occasional occurrences of inflammation (males); pigmentation within histiocytes of the lamina propria; degeneration of the nasopharyngeal duct epithelium and inflammation within the nasopharyngeal duct lumen (males); hyperplasia of the basal cells of the olfactory epithelium; olfactory epithelium necrosis (males); and atrophy, squamous metaplasia, hyperplasia, and necrosis of the respiratory epithelium (primarily in males). These isolated lesions most likely represent different manifestations of the same pathologic process within the nose, and they are considered part of the spectrum of changes within the nasal cavity that was related to exposure to green tea extract.

Table 5 Incidences of Nonneoplastic Lesions of the Nose in F344/NTac Rats in the Three-month Gavage Study of Green Tea Extract

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Inflammation^a^ | 2 (1.0)^b^ | 3 (1.0) | 1 (1.0) | 2 (1.0) | 3 (1.3) | 5 (2.0)
Glands, Olfactory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 3 (1.3) | 7** (1.1)
Lamina Propria, Pigmentation, Histiocyte | 0 | 0 | 0 | 0 | 0 | 2 (2.0)
Nasopharyngeal Duct, Degeneration | 0 | 0 | 0 | 0 | 3 (2.0) | 3 (2.0)
Nasopharyngeal Duct, Inflammation | 0 | 0 | 0 | 0 | 2 (1.0) | 3 (2.0)
Nerve, Atrophy | 0 | 0 | 0 | 0 | 5* (1.8) | 10** (1.7)
Olfactory Epithelium, Atrophy | 0 | 0 | 2 (1.0) | 1 (1.0) | 3 (1.0) | 9** (1.1)
Olfactory Epithelium, Hyperplasia, Basal Cell | 0 | 0 | 0 | 0 | 1 (1.0) | 1 (1.0)
Olfactory Epithelium, Metaplasia | 0 | 0 | 1 (1.0) | 0 | 6** (1.5) | 10** (1.0)
Olfactory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 1 (1.0) | 3 (1.7)
Olfactory Epithelium, Pigmentation | 0 | 0 | 0 | 0 | 4* (1.0) | 5* (1.0)
Respiratory Epithelium, Atrophy | 0 | 0 | 0 | 0 | 0 | 1 (2.0)
Respiratory Epithelium, Hyperplasia | 1 (2.0) | 0 | 0 | 0 | 2 (1.0) | 4 (1.0)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 1 (2.0)
Female
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Inflammation | 2 (1.0) | 1 (1.0) | 1 (1.0) | 4 (1.0) | 10** (1.2) | 8* (1.0)
Glands, Olfactory Epithelium, Hyperplasia | 0 | 0 | 0 | 2 (1.0) | 1 (1.0) | 4* (1.0)
Lamina Propria, Pigmentation, Histiocyte | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Nasopharyngeal Duct, Degeneration | 0 | 0 | 0 | 0 | 2 (1.5) | 0
Nerve, Atrophy | 0 | 0 | 0 | 1 (1.0) | 4* (1.0) | 5* (1.8)
Olfactory Epithelium, Atrophy | 0 | 1 (1.0) | 1 (1.0) | 0 | 0 | 7** (1.1)
Olfactory Epithelium, Hyperplasia, Basal Cell | 0 | 0 | 0 | 1 (1.0) | 0 | 0
Olfactory Epithelium, Metaplasia | 0 | 0 | 0 | 0 | 5* (1.2) | 4* (1.0)
Olfactory Epithelium, Pigmentation | 0 | 0 | 0 | 2 (1.0) | 3 (1.0) | 5* (1.0)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 1 (1.0) | 1 (1.0) | 0

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Grading criteria for the nasal lesions were as follows: minimal was characterized by unilateral involvement, mild represented bilateral involvement or unilateral on multiple levels, moderate represented bilateral involvement on more than one level; severe represented involvement of all or almost all of the respective epithelium (e.g., olfactory) present in all levels.

Increases in incidence and/or severity of inflammation were noted in males and females in the 500 and 1,000 mg/kg groups and in the 250 mg/kg females. This change was characterized by largely neutrophilic infiltrates, with lesser numbers of lymphocytes and plasma cells in the lamina propria, migrating through the epithelium and sometimes filling the airways or extending into Bowman’s glands. Inflammation frequently involved the respiratory epithelium of the nasal septum or lateral wall of Levels I and II and the olfactory epithelium in the dorsal or dorsolateral meatus of Levels II and III. In severe instances only among the males treated with 500 or 1,000 mg/kg, the infiltrate was associated with olfactory epithelium necrosis, characterized by sloughing or loss of the olfactory epithelium with pyknosis and karyorrhexis of the nuclei.

Nasopharyngeal duct degeneration was noted at Level III in 500 and 1,000 mg/kg males and in 500 mg/kg females and was often accompanied by inflammation in males. Nasopharyngeal duct degeneration was characterized by decreased goblet cells and transformation of tall columnar ciliated epithelial cells to a more attenuated or cuboidal cell. If present, the inflammatory infiltrate was largely neutrophils with lesser numbers of mononuclear cells.

Hyperplasia of Bowman’s glands located in the olfactory epithelium was diagnosed in 500 and 1,000 mg/kg males and females and in 250 mg/kg females, and the incidences in 1,000 mg/kg males and females were significantly greater than those in the vehicle control groups. Bowman’s gland hyperplasia was characterized by nodular proliferation of cells that occasionally formed an acinus in the lamina propria underlying or continuous with the olfactory epithelium. The finding was mostly in the dorsal meatus or upper portion of the septum in Level II and occasionally in Level III.

Olfactory epithelial atrophy was noted in the 62.5, 125, and 1,000 mg/kg females and in males in the 125 mg/kg or greater groups. Olfactory epithelial atrophy was associated with thinning of the layers of olfactory epithelial cells, especially in the dorsal meatus, compared to vehicle controls. Nerve atrophy was noted in males and females administered 500 or 1,000 mg/kg and in one female administered 250 mg/kg. This change was characterized by the loss of olfactory nerve bundles in the submucosal regions underlying the olfactory epithelium in the dorsal meatus of Level II and dorsal meatus and nasal turbinates of Level III. Nerve atrophy was frequently accompanied by olfactory epithelium metaplasia characterized by the transition of olfactory epithelium to respiratory epithelium. Metaplasia of the olfactory epithelium was present in males in the 125, 500, and 1,000 mg/kg groups and in females in the 500 and 1,000 mg/kg groups.

Basal cell hyperplasia of the olfactory epithelium was diagnosed in one 500 and one 1,000 mg/kg male and one 250 mg/kg female. Basal cell hyperplasia was characterized by a minimal proliferation (two to three cells thick) of basal cells at the margin of the lamina propria and the olfactory epithelium in the dorsal meatus.

Increased incidences, when compared to that in the vehicle controls, of respiratory epithelium hyperplasia were diagnosed in the 500 and 1,000 mg/kg males, and single incidences were seen in females administered 250 or 500 mg/kg. This lesion was characterized by the proliferation of nonciliated cuboidal epithelium more than three cell layers thick in Level I or occasionally Level II involving the nasal septum or lateral wall.

Atrophy and necrosis of the respiratory epithelium were diagnosed in one male in the 1,000 mg/kg group. The presence of golden brown pigment accumulation in the degenerating olfactory epithelium was noted in 500 and 1,000 mg/kg males and in females administered 250 mg/kg or greater, in addition to the sporadic cases of golden brown pigmented histiocytes in the lamina propria in 1,000 mg/kg males and females. Pigmented cells in the nose stained positive for Schmorl’s and PAS but negative for Prussian Blue and Hall’s, suggesting that the pigment was composed of a combination of glycoprotein and lipofuscin.

Squamous metaplasia of the respiratory epithelium was noted in one 1,000 mg/kg male and was characterized by transformation of single-layer tall columnar epithelial cells to well-differentiated keratinized epithelium four to nine layers thick unilaterally in Level II along the ventral portion of the nasal septum.

Atrophy of the mesenteric lymph node was seen in one 1,000 mg/kg female and was characterized by loss of lymphocytes and numerous lymphocytes undergoing apoptosis in the paracortex. The incidences of histiocyte cellular infiltration in the mesenteric lymph node in 125 mg/kg or greater males were significantly increased compared to that in the vehicle control group [vehicle control, 0/10; 62.5 mg/kg, 2/10 (2.0); 125 mg/kg, 6/10 (1.5); 250 mg/kg, 7/10 (1.9); 500 mg/kg, 7/10 (1.7); 1,000 mg/kg, 7/10 (1.7)].

Minimal thymus atrophy was noted in males and females administered 1,000 mg/kg [males: 0/10, 0/10, 0/10, 1/10 (1.0), 0/10, 5/8 (1.0); females: 0/10, 0/10, 0/10, 0/10, 0/10, 6/10 (1.0)]; one 250 mg/kg male also had this lesion. Thymus atrophy was characterized by variable thinning of the cortex due to loss of T cells by apoptosis. Thymus atrophy was considered related to stress.

Degeneration of the seminiferous tubules of the testes was increased in 1,000 mg/kg males compared to the vehicle control males, although this increase was not significant by a pairwise comparison, only with a trend test [3/10 (1.0), 1/10 (1.0), 2/10 (1.0), 3/10 (1.0), 3/10 (1.0), 7/10 (1.0)]. Seminiferous tubule degeneration was characterized by vacuolated or absent germinal epithelial cells, resulting in decreased layers of germinal epithelium. In a few cases, tubules were completely devoid of germinal epithelium, and had only Sertoli cells remaining.

Dose Selection Rationale: All rats survived until the end of the 3-month study. Treatment-related body weight effects and histopathologic lesions of minimal to mild severity were not considered dose limiting. Therefore, green tea extract doses selected for the 2-year gavage study in Wistar Han rats were 100, 300, and 1,000 mg/kg.

## Two-year Study in Wistar Han Rats

### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 6 and in the Kaplan-Meier survival curves (Figure 5). The survival of 1,000 mg/kg males and females was significantly less than that of the vehicle controls. Early mortality may have been related to gastrointestinal lesions, respiratory compromise, or cardiovascular collapse.

Table 6 Survival of Wistar Han Rats in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | 100 mg/kg | 300 mg/kg | 1,000 mg/kg
Male
Animals initially in study | 60 | 50 | 50 | 60
3-month interim evaluation^a^ | 10 | – | – | 10
Accidental deaths^a^ | 0 | 0 | 0 | 2
Moribund | 12 | 7 | 5 | 5
Natural deaths | 3 | 6 | 2 | 19
Animals surviving to study termination | 35 | 37 | 43^b^ | 24
Percent probability of survival at end of study^c^ | 70 | 74 | 86 | 50
Mean survival (days)^d^ | 687 | 695 | 705 | 591
Survival analysis^e^ | P = 0.001 | P = 0.755N | P = 0.085N | P = 0.037
Female
Animals initially in study | 60 | 50 | 50 | 60
3-month interim evaluation^a^ | 10 | – | – | 10
Accidental deaths^a^ | 0 | 0 | 1 | 3
Moribund | 14 | 12 | 17 | 8
Natural deaths | 10 | 10 | 9 | 35
Animals surviving to study termination | 26 | 28 | 23 | 4
Percent probability of survival at end of study | 52 | 56 | 47 | 9
Mean survival (days) | 671 | 646 | 566 | 408
Survival analysis | P < 0.001 | P = 0.910N | P = 0.394 | P < 0.001

^a^ Censored from survival analyses.

^b^ Includes one animal that died during the last week of the study.

^c^ Kaplan-Meier determinations.

^d^ Mean of all deaths (uncensored, censored, and terminal kill); does not include interim evaluation animals.

^e^ The result of the life table trend test^106^ is in the vehicle control column, and the results of the life table pairwise comparisons^105^ with the vehicle controls are in the dosed group columns. A lower mortality in a dose group is indicated by N.

Figure 5

Kaplan-Meier Survival Curves for Wistar Han Rats Administered Green Tea Extract by Gavage for Two Years

### Body Weights, Organ Weights, and Clinical Findings

Mean body weights of 300 and 1,000 mg/kg males were at least 10% less than those of the vehicle control group after weeks 41 and 9 of the study, respectively; mean body weights of dosed groups of female rats were at least 10% less after weeks 65 (100 mg/kg), 61 (300 mg/kg), and 57 (1,000 mg/kg) (Table 7, Table 8, and Figure 6). At the 3-month interim evaluation, body weights in the vehicle control and 1,000 mg/kg groups were similar for both males and females. The relative kidney weight of 1,000 mg/kg males was significantly greater than that of the vehicle control group (Table G-2); this change was not observed in the 3-month study in F344/NTac rats, and there were no histopathologic findings that correlated to this change. The absolute and relative thymus weights of 1,000 mg/kg females were significantly less than those of the vehicle controls (approximately 16%), but this decrease was less than that seen in the 1,000 mg/kg females in the 3-month study in F344/NTac rats. In the interim evaluation animals, there were no histopathologic changes in the thymus to correlate to the decrease in thymus weights, in contrast to the thymic atrophy observed in the 3-month study. No clinical findings related to chemical exposure were observed.

Table 7 Mean Body Weights and Survival of Male Wistar Han Rats in the Two-year Gavage Study of Green Tea Extract

Day | 0 mg/kg | | 100 mg/kg | | | 300 mg/kg | | | 1,000 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 167 | 60 | 169 | 101 | 50 | 167 | 100 | 50 | 167 | 100 | 60
8 | 210 | 60 | 209 | 99 | 50 | 207 | 99 | 50 | 204 | 97 | 60
15 | 251 | 60 | 250 | 99 | 50 | 245 | 98 | 50 | 237 | 95 | 60
22 | 282 | 60 | 281 | 100 | 50 | 272 | 96 | 50 | 263 | 93 | 60
29 | 306 | 60 | 306 | 100 | 50 | 296 | 97 | 50 | 283 | 93 | 60
36 | 327 | 60 | 326 | 100 | 50 | 315 | 96 | 50 | 301 | 92 | 60
43 | 342 | 60 | 341 | 100 | 50 | 330 | 97 | 50 | 314 | 92 | 60
50 | 358 | 60 | 356 | 100 | 50 | 342 | 96 | 50 | 328 | 92 | 60
57 | 368 | 60 | 367 | 100 | 50 | 352 | 96 | 50 | 335 | 91 | 59
64 | 381 | 60 | 379 | 99 | 50 | 362 | 95 | 50 | 341 | 89 | 59
71 | 390 | 60 | 388 | 100 | 50 | 370 | 95 | 50 | 349 | 90 | 59
78 | 399 | 60 | 395 | 99 | 50 | 377 | 95 | 50 | 355 | 89 | 59
85 | 407 | 60 | 402 | 99 | 50 | 381 | 94 | 50 | 360 | 89 | 59
113 | 435 | 50^a^ | 422 | 97 | 50 | 397 | 91 | 50 | 373 | 86 | 47^a^
141 | 460 | 50 | 445 | 97 | 50 | 421 | 92 | 50 | 394 | 86 | 47
169 | 475 | 50 | 458 | 97 | 50 | 433 | 91 | 50 | 397 | 84 | 47
197 | 493 | 50 | 470 | 95 | 50 | 445 | 90 | 50 | 416 | 84 | 46
225 | 504 | 50 | 484 | 96 | 50 | 458 | 91 | 49 | 422 | 84 | 45
253 | 516 | 50 | 493 | 96 | 50 | 467 | 91 | 49 | 430 | 83 | 45
281 | 529 | 50 | 508 | 96 | 50 | 479 | 91 | 49 | 437 | 83 | 45
309 | 542 | 50 | 519 | 96 | 50 | 485 | 90 | 49 | 441 | 82 | 45
337 | 557 | 50 | 530 | 95 | 50 | 491 | 88 | 49 | 446 | 80 | 44
365 | 569 | 50 | 545 | 96 | 49 | 499 | 88 | 49 | 457 | 80 | 41
393 | 577 | 50 | 557 | 97 | 49 | 508 | 88 | 49 | 465 | 81 | 41
421 | 589 | 50 | 561 | 95 | 49 | 508 | 86 | 49 | 471 | 80 | 41
449 | 598 | 50 | 569 | 95 | 49 | 514 | 86 | 49 | 470 | 79 | 41
477 | 605 | 50 | 577 | 95 | 49 | 526 | 87 | 49 | 478 | 79 | 39
505 | 611 | 49 | 583 | 96 | 49 | 534 | 88 | 49 | 482 | 79 | 39
533 | 618 | 45 | 582 | 94 | 48 | 534 | 87 | 49 | 486 | 79 | 37
561 | 620 | 43 | 587 | 95 | 47 | 542 | 87 | 49 | 485 | 78 | 36
589 | 627 | 43 | 591 | 94 | 46 | 547 | 87 | 48 | 483 | 77 | 32
617 | 632 | 42 | 601 | 95 | 44 | 548 | 87 | 46 | 487 | 77 | 29
645 | 625 | 39 | 597 | 96 | 42 | 546 | 87 | 45 | 477 | 76 | 28
673 | 633 | 37 | 593 | 94 | 39 | 550 | 87 | 44 | 482 | 76 | 26
701 | 632 | 36 | 591 | 93 | 38 | 561 | 89 | 43 | 480 | 76 | 24
Mean for Weeks
1–13 | 322 | – | 321 | 100 | – | 309 | 96 | – | 295 | 92 | –
14–52 | 501 | – | 481 | 96 | – | 453 | 90 | – | 417 | 83 | –
53–101 | 610 | – | 580 | 95 | – | 532 | 87 | – | 477 | 78 | –

^a^ Interim evaluation occurred during week 14.

Table 8 Mean Body Weights and Survival of Female Wistar Han Rats in the Two-year Gavage Study of Green Tea Extract

Day | 0 mg/kg | | 100 mg/kg | | | 300 mg/kg | | | 1,000 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 129 | 60 | 129 | 99 | 50 | 129 | 100 | 50 | 130 | 100 | 60
8 | 148 | 60 | 148 | 100 | 50 | 149 | 101 | 49 | 148 | 100 | 59
15 | 166 | 60 | 166 | 100 | 49 | 166 | 100 | 48 | 165 | 99 | 57
22 | 179 | 60 | 179 | 100 | 49 | 177 | 99 | 47 | 176 | 99 | 56
29 | 189 | 60 | 189 | 100 | 49 | 186 | 98 | 47 | 189 | 100 | 56
36 | 198 | 60 | 199 | 100 | 49 | 194 | 98 | 47 | 196 | 99 | 56
43 | 204 | 60 | 206 | 101 | 49 | 202 | 99 | 47 | 205 | 101 | 56
50 | 210 | 60 | 212 | 101 | 49 | 208 | 99 | 47 | 211 | 101 | 56
57 | 214 | 60 | 216 | 101 | 49 | 213 | 100 | 47 | 214 | 100 | 56
64 | 219 | 60 | 220 | 101 | 48 | 217 | 99 | 47 | 220 | 101 | 56
71 | 222 | 60 | 224 | 101 | 48 | 220 | 99 | 47 | 223 | 100 | 56
78 | 225 | 60 | 223 | 99 | 48 | 218 | 97 | 47 | 226 | 100 | 56
85 | 227 | 60 | 226 | 99 | 48 | 222 | 98 | 47 | 227 | 100 | 55
113 | 235 | 50^a^ | 234 | 100 | 48 | 230 | 98 | 45 | 231 | 98 | 42^a^
141 | 242 | 50 | 242 | 100 | 48 | 240 | 99 | 45 | 243 | 100 | 42
169 | 246 | 50 | 243 | 99 | 48 | 242 | 99 | 45 | 245 | 100 | 40
197 | 252 | 50 | 248 | 98 | 48 | 249 | 99 | 45 | 252 | 100 | 38
225 | 258 | 50 | 251 | 97 | 48 | 250 | 97 | 44 | 254 | 99 | 36
253 | 263 | 50 | 255 | 97 | 48 | 252 | 96 | 43 | 258 | 98 | 34
281 | 269 | 50 | 260 | 97 | 48 | 260 | 97 | 42 | 261 | 97 | 33
309 | 276 | 50 | 264 | 96 | 47 | 264 | 96 | 41 | 266 | 97 | 33
337 | 285 | 50 | 270 | 95 | 47 | 269 | 94 | 40 | 267 | 94 | 32
365 | 292 | 49 | 273 | 94 | 47 | 271 | 93 | 39 | 271 | 93 | 32
393 | 298 | 48 | 279 | 94 | 47 | 277 | 93 | 39 | 276 | 93 | 30
421 | 308 | 48 | 283 | 92 | 46 | 281 | 91 | 38 | 276 | 90 | 29
449 | 318 | 48 | 290 | 91 | 45 | 287 | 90 | 38 | 278 | 88 | 25
477 | 326 | 48 | 293 | 90 | 45 | 288 | 88 | 37 | 286 | 88 | 24
505 | 339 | 47 | 297 | 87 | 43 | 288 | 85 | 37 | 285 | 84 | 23
533 | 345 | 46 | 299 | 87 | 41 | 289 | 84 | 34 | 296 | 86 | 17
561 | 354 | 43 | 309 | 87 | 40 | 301 | 85 | 33 | 304 | 86 | 14
589 | 360 | 42 | 312 | 87 | 40 | 309 | 86 | 32 | 292 | 81 | 12
617 | 365 | 40 | 313 | 86 | 39 | 311 | 85 | 31 | 282 | 77 | 8
645 | 366 | 36 | 313 | 86 | 37 | 307 | 84 | 28 | 285 | 78 | 7
673 | 367 | 34 | 320 | 87 | 35 | 313 | 85 | 28 | 277 | 76 | 5
701 | 370 | 28 | 321 | 87 | 31 | 318 | 86 | 25 | 275 | 74 | 5
Mean for Weeks
1–13 | 195 | – | 195 | 100 | – | 192 | 98 | – | 195 | – | 100
14–52 | 258 | – | 252 | 98 | – | 251 | 97 | – | 253 | – | 98
53–101 | 339 | – | 300 | 88 | – | 295 | 87 | – | 283 | – | 83

^a^ Interim evaluation occurred during week 14.

Figure 6

Growth Curves for Wistar Han Rats Administered Green Tea Extract by Gavage for Two Years

## Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms or nonneoplastic lesions of the liver, stomach, small intestine (duodenum, ileum, and jejunum), nose, lung, heart, bone marrow, spleen, pituitary gland, mammary gland, and uterus. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix A for male rats and Appendix B for female rats.

Liver: At the 3-month interim evaluation, one 1,000 mg/kg female had several nonneoplastic changes in the liver, mostly of minimal severity, that were not seen in the vehicle control females (Table 9 and Table B-3).

Table 9 Incidences of Nonneoplastic Lesions of the Liver in Wistar Han Rats in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | 100 mg/kg | 300 mg/kg | 1,000 mg/kg
Male
Two-year Study
Number Examined Microscopically | 50 | 50 | 50 | 50
Necrosis^a^ | 1 (1.0)^b^ | 2 (1.0) | 2 (1.5) | 13** (2.9)
Oval Cell Hyperplasia | 0 | 0 | 0 | 2 (1.5)
Female
Three-month Interim Evaluation
Number Examined Microscopically | 10 | – | – | 10
Inflammation | 0 | – | – | 3 (1.0)
Necrosis | 0 | – | – | 1 (2.0)
Bile Duct Hyperplasia | 0 | – | – | 1 (1.0)
Hepatocyte Hypertrophy | 0 | – | – | 1 (1.0)
Oval Cell Hyperplasia | 0 | – | – | 1 (1.0)
Two-year study
Number Examined Microscopically | 50 | 48 | 49 | 46
Necrosis | 3 (2.7) | 2 (2.0) | 5 (2.6) | 24** (3.3)
Oval Cell Hyperplasia | 1 (1.0) | 2 (1.0) | 3 (1.7) | 16** (1.3)

** Significantly different (P ≤ 0.01) from the vehicle control group by the Poly-3 test.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

These included inflammation, necrosis, bile duct hyperplasia, hepatocyte hypertrophy, and oval cell hyperplasia. Two other animals from the same group had only inflammation. Necrosis was characterized by individual scattered hepatocytes, hypereosinophilia, variable cell body swelling or shrinking, and variable nuclear karyorrhexis/karyolysis. Hypertrophy was characterized by enlargement of the hepatocytes due to an increase of finely granular eosinophilic cytoplasm. Inflammation was composed of mixed inflammatory cell infiltrates including lymphocytes, plasma cells, and neutrophils both in portal regions as well as multifocally scattered throughout the hepatic parenchyma. Oval cell hyperplasia was composed of multifocal proliferations of small cells with scant cytoplasm and ovoid nuclei occasionally forming clusters and linear tracts. The formation of distinct ducts was characteristic of bile duct hyperplasia. The lesions were similar to those observed in three female F344/NTac rats in the 3-month study. There were no differences in liver weights of dosed groups compared to those of the vehicle controls.

At 2 years, the incidences of necrosis and oval cell hyperplasia were generally significantly increased in 1,000 mg/kg males and females (Table 9, Table A-3, and Table B-3).

The liver necrosis was characterized by both necrosis of individual hepatocytes and submassive to massive necrosis of hepatic parenchyma. There was no distinct pattern to the necrosis, though the less severe lesions were predominantly midzonal. Individual cell necrosis was characterized by rounding up and shrinkage of individual hepatocytes with nuclear condensation-pyknosis. In more severe lesions, individual cell necrosis was characterized by swollen, hypereosinophilic hepatocytes with nuclear karyolysis-karyorrhexis; these lesions were associated with congestion, hemorrhage, predominantly neutrophilic cellular infiltrates, and hypertrophy/hyper-plasia of the Kupffer cells. These lesions in the 300 and 1,000 mg/kg males and all dosed groups of females could be distinguished from the liver necrosis diagnosed in vehicle control males and females and 100 mg/kg males by the presence of large numbers of individual necrotic hepatocytes and/or the presence of congestion/hemorrhage. Acute hepatic necrosis may have been related to septic shock or hypoxia rather than direct hepatotoxicity. Oval cell hyperplasia was primarily minimal and was characterized by increased cellularity, primarily within portal areas, with proliferation of small cells with scant cytoplasm and oval-shaped nuclei occasionally forming linear tracts, though not forming ducts.

Gastrointestinal Tract: At 2 years, dose-related increased incidences of gray to black, focal to diffuse discoloration of the mucosa and wall of the stomach and/or variable lengths of the small intestine were observed macroscopically (Figure 10).

In the glandular stomach of 1,000 mg/kg males and 300 and 1,000 mg/kg females, the incidences of mucosa necrosis were significantly greater than the vehicle control incidences (Table 10, Table A-3, and Table B-3). Mucosa necrosis was characterized by a variably thick zone of mucosa with shrunken, hypereosinophilic cytoplasm and nuclear pyknosis, which was accompanied by cell debris, congestion, hemorrhage, fibrin thrombi, and bacterial colonies in older lesions. There were small numbers of treated animals with increased numbers of pigment-laden cells, and occasionally the pigment was darker brown and globular, consistent with hemosiderin and suggestive of prior hemorrhage.

Table 10 Incidences of Mucosa Necrosis of the Gastrointestinal Tract in Wistar Han Rats in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | 100 mg/kg | 300 mg/kg | 1,000 mg/kg
Two-year Study
Male
Stomach, Glandular^a^ | 49 | 50 | 50 | 50
Mucosa, Necrosis^b^ | 0 | 3 (2.0)^c^ | 3 (1.7) | 21** (2.5)
Intestine Small, Duodenum | 50 | 47 | 49 | 48
Mucosa, Necrosis | 0 | 1 (1.0) | 1 (2.0) | 10** (2.4)
Intestine Small, Ileum | 50 | 48 | 49 | 45
Mucosa, Necrosis | 0 | 1 (1.0) | 2 (1.5) | 6** (1.7)
Intestine Small, Jejunum | 49 | 47 | 48 | 46
Mucosa, Necrosis | 0 | 0 | 2 (1.0) | 9** (2.0)
Intestine Small (Duodenum, Ileum, or Jejunum) | 49 | 46 | 48 | 45
Mucosa, Necrosis | 0 | 2 | 4 | 14**
Two-year Study
Female
Stomach, Glandular | 50 | 49 | 49 | 44
Mucosa, Necrosis | 0 | 1 (2.0) | 7** (1.1) | 20** (1.9)
Intestine Small, Duodenum | 47 | 48 | 48 | 39
Mucosa, Necrosis | 0 | 0 | 1 (1.0) | 5** (2.2)
Intestine Small, Ileum | 45 | 46 | 47 | 36
Mucosa, Necrosis | 0 | 0 | 0 | 5** (1.0)
Intestine Small, Jejunum | 45 | 43 | 45 | 40
Mucosa, Necrosis | 0 | 0 | 1 (1.0) | 6** (1.0)
Intestine Small (Duodenum, Ileum, or Jejunum) | 44 | 42 | 44 | 33
Mucosa, Necrosis | 0 | 0 | 2 | 10**

** Significantly different (P ≤ 0.01) from the vehicle control group by the Poly-3 test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked; no average severity grades available for combined small intestine sites.

Dose-related increased incidences of mucosa necrosis were seen in all the segments of the small intestine, and the incidences in 1,000 mg/kg males and females were significantly greater than those in the vehicle control groups (Table 10, Table A-3, and Table B-3). The severity of this lesion generally increased with increasing dose. Mucosa necrosis was characterized by findings that varied from excessive exfoliation of shrunken, hypereosinophilic epithelial cells with pyknotic nuclei at the tips (or lateral aspect) of villi or variable lengths of shriveled intact villous epithelium lacking supporting lamina propria (Figure 11). In addition to changes to the mucosal epithelium, the capillaries of the subjacent lamina propria of affected villi were often markedly dilated and infrequently contained fibrin thrombi. Occasionally remaining villi showed evidence of regeneration characterized by unevenly spaced epithelial cells with variable amounts of cytoplasm and vesicular nuclei. One female in the 100 mg/kg group had hemorrhagic necrosis of the small intestine mucosa. This lesion had a different appearance than mucosa necrosis, in that it was hemorrhagic and involved the entire thickness of the intestinal wall, rather than just the mucosa. Similar lesions were not observed in the interim evaluation animals.

Nose: In 1,000 mg/kg males and females at 3 months, lesions included suppurative and acute inflammation; nerve atrophy; and olfactory epithelium atrophy, respiratory metaplasia, and pigmentation (Table 11, Table A-3, and Table B-3). Other lesions that occurred only in 1,000 mg/kg males were hyperplasia and necrosis of the nasopharyngeal duct epithelium and suppurative inflammation in the nasopharyngeal duct; mineralization in the lamina propria; olfactory epithelium necrosis; and squamous metaplasia of the respiratory epithelium. In 1,000 mg/kg females, additional lesions were degeneration and regeneration of the epithelium of the nasopharyngeal duct, acute inflammation in the nasopharyngeal duct, pigmentation in the lamina propria, and turbinate deformity.

Table 11 Incidences of Nonneoplastic Lesions of the Nose in Wistar Han Rats in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | 100 mg/kg | 300 mg/kg | 1,000 mg/kg
Male
Three-month interim evaluation
Number examined microscopically | 10 | – | – | 10
Inflammation, suppurative^a^ | 0 | – | – | 2 (3.0)^b^
Inflammation, acute | 0 | – | – | 1 (1.0)
Epithelium, nasopharyngeal duct, hyperplasia | 0 | – | – | 1 (3.0)
Epithelium, nasopharyngeal duct, necrosis | 0 | – | – | 1 (2.0)
Lamina propria, mineralization | 0 | – | – | 1 (1.0)
Nasopharyngeal duct, inflammation, suppurative | 0 | – | – | 2 (3.5)
Nerve, atrophy | 0 | – | – | 5* (2.0)
Olfactory epithelium, atrophy | 0 | – | – | 5* (2.0)
Olfactory epithelium, metaplasia, respiratory | 0 | – | – | 3 (1.7)
Olfactory epithelium, necrosis | 0 | – | – | 2 (1.0)
Olfactory epithelium, pigmentation | 0 | – | – | 3 (1.3)
Respiratory epithelium, metaplasia, squamous | 0 | – | – | 2 (1.0)
Two-year study
Number examined microscopically | 50 | 50 | 50 | 50
Inflammation, suppurative | 11 (1.7) | 12 (1.8) | 20 (2.0) | 42** (2.2)
Epithelium, nasopharyngeal duct, degeneration | 0 | 1 (2.0) | 0 | 3 (2.7)
Epithelium, nasopharyngeal duct, hyperplasia | 0 | 0 | 2 (1.0) | 4* (1.5)
Epithelium, nasopharyngeal duct, necrosis | 0 | 0 | 0 | 2 (2.0)
Epithelium, nasopharyngeal duct, regeneration | 0 | 0 | 2 (1.5) | 2 (3.5)
Lamina propria, mineralization | 0 | 33** (1.4) | 34** (1.4) | 44** (1.5)
Lamina propria, pigmentation | 0 | 4 (1.3) | 11** (1.6) | 25** (2.4)
Nasopharyngeal duct, inflammation, suppurative | 0 | 6* (1.5) | 8** (2.0) | 20** (1.9)
Nerve, atrophy | 0 | 33** (1.7) | 44** (2.0) | 44** (2.5)
Olfactory epithelium, atrophy | 1 (1.0) | 38** (1.8) | 41** (2.0) | 41** (2.0)
Olfactory epithelium, hyperplasia, basal cell | 0 | 1 (1.0) | 9** (1.0) | 28** (1.8)
Olfactory epithelium, metaplasia, respiratory | 4 (1.3) | 40** (2.2) | 43** (2.4) | 47** (2.9)
Olfactory epithelium, necrosis | 1 (2.0) | 3 (2.0) | 0 | 12** (2.0)
Olfactory epithelium, pigmentation | 6 (1.7) | 18** (1.6) | 12 (1.3) | 21** (1.5)
Olfactory epithelium, squamous metaplasia | 0 | 0 | 1 (1.0) | 4* (1.3)
Respiratory epithelium, atrophy | 0 | 2 (1.5) | 5* (1.4) | 6** (1.5)
Respiratory epithelium, degeneration | 0 | 0 | 0 | 3 (2.0)
Respiratory epithelium, metaplasia, squamous | 0 | 1 (1.0) | 3 (1.3) | 7** (1.6)
Respiratory epithelium, necrosis | 0 | 0 | 0 | 4* (2.8)
Respiratory epithelium, pigmentation | 2 (1.0) | 6 (1.2) | 7 (1.1) | 7* (1.3)
Turbinate, deformity | 0 | 16** | 22** | 35**
Turbinate, hyperostosis | 0 | 18** (1.5) | 27** (1.9) | 40** (2.2)
Female
Three-month interim evaluation
Number examined microscopically | 10 | – | – | 10
Inflammation, suppurative | 0 | – | – | 1 (2.0)
Inflammation, acute | 0 | – | – | 1 (1.0)
Epithelium, nasopharyngeal duct, degeneration | 0 | – | – | 1 (2.0)
Epithelium, nasopharyngeal duct, regeneration | 0 | – | – | 1 (2.0)
Lamina propria, pigmentation | 0 | – | – | 1 (1.0)
Nasopharyngeal duct, inflammation, acute | 0 | – | – | 1 (1.0)
Nerve, atrophy | 0 | – | – | 1 (1.0)
Olfactory epithelium, atrophy | 0 | – | – | 2 (1.5)
Olfactory epithelium, metaplasia, respiratory | 1 (1.0) | – | – | 4 (1.0)
Olfactory epithelium, pigmentation | 0 | – | – | 4* (1.0)
Turbinate, deformity | 0 | – | – | 1
Two-year study
Number examined microscopically | 49 | 49 | 50 | 49
Foreign body | 3 | 2 | 4 | 8**
Inflammation, suppurative | 5 (1.2) | 3 (2.0) | 17** (1.5) | 35** (2.1)
Epithelium, nasopharyngeal duct, degeneration | 0 | 0 | 1 (3.0) | 3* (2.7)
Epithelium, nasopharyngeal duct, hyperplasia | 0 | 1 (1.0) | 4* (1.0) | 1 (2.0)
Epithelium, nasopharyngeal duct, necrosis | 0 | 1 (1.0) | 2 (3.5) | 7** (3.0)
Epithelium, nasopharyngeal duct, regeneration | 0 | 0 | 0 | 8** (3.1)
Lamina propria, mineralization | 3 (1.0) | 23** (1.1) | 30** (1.4) | 22** (1.5)
Lamina propria, pigmentation | 1 (1.0) | 0 | 6* (1.2) | 14** (2.0)
Nasopharyngeal duct, inflammation, suppurative | 0 | 2 (1.0) | 5* (1.2) | 15** (2.3)
Nerve, atrophy | 0 | 38** (1.6) | 41** (2.1) | 38** (2.3)
Olfactory epithelium, atrophy | 2 (1.5) | 35** (1.6) | 42** (1.7) | 34** (1.8)
Olfactory epithelium, hyperplasia, basal cell | 0 | 0 | 8** (1.1) | 20** (1.7)
Olfactory epithelium, metaplasia, respiratory | 1 (1.0) | 42** (2.1) | 43** (2.7) | 36** (3.0)
Olfactory epithelium, necrosis | 0 | 3 (1.7) | 1 (2.0) | 18** (1.8)
Olfactory epithelium, pigmentation | 0 | 11** (1.0) | 7** (1.3) | 5** (1.2)
Olfactory epithelium, squamous metaplasia | 0 | 2 (1.0) | 1 (1.0) | 5** (1.4)
Respiratory epithelium, atrophy | 0 | 8** (1.5) | 9** (1.7) | 3* (1.0)
Respiratory epithelium, metaplasia, squamous | 1 (1.0) | 1 (1.0) | 1 (1.0) | 4* (1.5)
Respiratory epithelium, necrosis | 0 | 1 (2.0) | 2 (1.5) | 17** (2.4)
Respiratory epithelium, pigmentation | 0 | 1 (1.0) | 5* (1.2) | 5** (1.0)
Respiratory epithelium, regeneration | 0 | 0 | 0 | 2 (2.0)
Turbinate, deformity | 0 | 6* | 20** | 15**
Turbinate, hyperostosis | 0 | 18** (1.3) | 32** (1.7) | 36** (2.2)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test (interim evaluation) or the Poly-3 test (2-year study).

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Suppurative inflammation was predominantly characterized by accumulation of neutrophils within the nasal lumen. Acute inflammation was characterized by small accumulations of neutrophils within the epithelium with no appreciable luminal exudate. Epithelial hyperplasia in the nasopharyngeal duct was characterized by increased height and nuclear layers within the epithelium often with epithelial infoldings/invaginations. Necrosis of the nasopharyngeal duct epithelium was characterized by hypereosinophilia and cell swelling, and often there were large sections of sloughed necrotic epithelium. Acute or suppurative inflammation of the nasopharyngeal duct were characterized by small accumulations of intraepithelial neutrophils or accumulation of neutrophils within the lumen, respectively. Regeneration of the nasopharyngeal duct epithelium was characterized by multiple layers of undifferentiated cells that lacked cilia. Degeneration of the nasopharyngeal duct epithelium was characterized by lack of goblet cells and ciliated brush border in the affected tissue. Lamina propria mineralization was characterized by focal accumulation of pale, basophilic, poorly laminated material within the basal lamina of both respiratory and olfactory epithelium and was similar to that seen at 2 years. Atrophy of the olfactory epithelium was characterized by thinning of the epithelial layers. Respiratory metaplasia of the olfactory epithelium was characterized by the replacement of the olfactory epithelium with respiratory epithelium often accompanied by loss of the underlying Bowman’s glands. Nerve atrophy was always associated with atrophy of the olfactory epithelium, though not all animals with epithelial atrophy had corresponding atrophy of the underlying nerve bundles. Necrosis of the olfactory epithelium was characterized by hypereosinophilia and cell swelling and often there were large sections of sloughed necrotic epithelium. Pigmentation of the olfactory epithelium, nasopharyngeal duct epithelium, or lamina propria was characterized by the presence of round cells, likely macrophages, with abundant intracytoplasmic golden brown pigmented material. Squamous metaplasia of the respiratory epithelium was characterized by replacement of small sections of normal resident respiratory epithelium by a multilayer epithelium that appeared to have extensive intracellular connections, a flattened luminal layer, and evidence, though typically minimal, of keratin production. Deformity of the turbinates was characterized by a wide spectrum of abnormally shaped turbinates and fusion of turbinates to the nasal septum, nasal wall, or each other.

The lesions in the nose of the 1,000 mg/kg Wistar Han rats were similar in character to those observed in the 3-month study in F344/NTac rats, although the incidences of the lesions were slightly lower in the Wistar Han rats.

At 2 years, numerous nasal lesions were increased in incidence in dosed males and/or females, relative to the vehicle controls (Table 11, Table A-3, and Table B-3). Lesions in the nasal lumen included increased incidences of suppurative inflammation in male and female rats and foreign material in female rats. Suppurative inflammation was characterized by accumulations of, predominantly, neutrophils within the lumen of the nasal passages. The inflammatory infiltrate in general was most prominent in Level III (the most posterior level) of the nose, though in more severely affected animals, the neutrophilic exudate extended into Level II and occasionally Level I (the most rostral level). Rarely, there was an inflammatory exudate in Level I without inflammation with the more posterior levels, and in these animals, the inflammation was almost always associated with the presence of foreign material. In addition to the luminal exudate, there were variable numbers of neutrophils undergoing transepithelial migration and present in the underlying submucosal stroma. Some animals also had infiltrates of lymphocytes and plasma cells within the subepithelial stroma. The presence of foreign bodies within the nasal lumen consisted most often of pieces of plant material or hair shafts and occasionally other small refractile pieces of unidentifiable material. Typically, the foreign material was associated with a neutrophilrich luminal exudate.

Increased incidences of lesions of the nasopharyngeal duct of dosed groups included degeneration, hyperplasia, necrosis, and regeneration of the epithelium and suppurative inflammation within the duct itself. Necrosis was characterized by hypereosinophilia and cell swelling and often there were large sections of sloughed necrotic epithelium. Hyperplasia was characterized by increased height and nuclear layers within the epithelium often with epithelial infoldings or invaginations. Degeneration was characterized by epithelium that exhibited evidence of damage (e.g., cellular vacuolation and/or swelling) but was not to the point of necrosis. Regeneration was comparable to the aspect of this lesion seen in the respiratory epithelium. Suppurative inflammation in the nasopharyngeal duct was characterized by exudation of neutrophils within the nasopharyngeal duct lumen (Figure 12).

Changes within the lamina propria of dosed rats consisted of pigmentation and mineralization. Pigmentation was characterized by variably sized clusters of histiocytes with abundant intracytoplasmic accumulation of golden to greenish brown pigmented material that were located in the lamina propria generally associated with regions of bony proliferation/remodeling. Mineralization was associated with the basement membrane of both olfactory and respiratory epithelium, most commonly at Level III, but occasionally in Level II as well. Larger foci consisted of pale irregular laminated material. Enlarged deposits of the mineralized material usually protruded into the lamina propria, but occasionally projected outward into the epithelium and rarely protruded into the nasal lumen.

Lesions that increased in incidence in the olfactory epithelium of dosed rats included atrophy, necrosis, basal cell hyperplasia, respiratory and squamous metaplasia, and pigmentation. The olfactory epithelial lesions primarily were seen in Level III, but also affected the dorsal portion of Level II. Atrophy of the nerves underlying the olfactory epithelium was also significantly increased in all dosed groups of male and female rats at the 2-year evaluation.

Olfactory epithelium atrophy was characterized by focal to focally extensive regions of decreased numbers and disorganization of the nuclear layers and loss of the luminal eosinophilic border. Nerve atrophy was always associated with atrophy of the olfactory epithelium, though not all animals with epithelial atrophy had corresponding atrophy of the underlying nerve bundles. Olfactory epithelium necrosis was characterized by a segment or cluster of epithelial cells that were shrunken and hypereosinophilic with karyorrhexis and/or nuclear pyknosis. Olfactory basal cell hyperplasia was characterized by increased cell size and cell number of the basal cells of the olfactory epithelium, generally two to three cell layers in thickness, with the occasional formation of gland-like structures and occasionally extending down ducts into the underlying Bowman’s glands. This lesion was not limited to the dorsal meatus as described in the 3-month F344/NTac rat study, but instead was often present in any/all remaining olfactory epithelium in affected animals. Metaplasia was characterized by partial to complete loss and replacement of the olfactory epithelium predominantly by respiratory epithelium and rarely by squamous epithelium. Occasionally, the metaplastic respiratory epithelium formed gland-like invaginations into the underlying stroma. The stroma underlying the affected olfactory epithelium was altered in that there was a loss of Bowman’s glands and atrophy of the olfactory nerve bundles. Pigmentation of the olfactory epithelium was characterized by variable numbers of cells within the olfactory epithelium with abundant intracytoplasmic accumulation of golden brown pigmented material. These cells were most often present in regions of the epithelium that had atrophied or had evidence of prior damage and repair.

Significantly increased incidences of lesions in the respiratory epithelium included atrophy, necrosis, squamous metaplasia, and pigmentation. Degeneration of the respiratory epithelium was increased in the 1,000 mg/kg males, and regeneration of the respiratory epithelium was increased in the 1,000 mg/kg females, but neither of these increases was significant. The respiratory epithelium lesions were predominantly noted in Level III of the nose, with less severe lesions occasionally present in Level II and few lesions present in Level I. Atrophy of the respiratory epithelium was characterized by flattening of the respiratory epithelium to a low cuboidal epithelium instead of the normal tall columnar epithelium. Degeneration of the respiratory epithelium was characterized by epithelium exhibiting evidence of damage (e.g., cellular vacuolation and swelling) but was not to the point of necrosis. Necrosis was characterized by hypereosinophilia and swelling of the respiratory epithelium and often there were large sections of affected epithelium sloughing off of an underlying basal epithelial layer. Regeneration was characterized by the presence of multiple layers of undifferentiated cells that lacked cilia in a region normally occupied by respiratory epithelium. Squamous metaplasia was characterized by the presence of regions in which the normal ciliated columnar epithelium had been replaced by squamous epithelium. Pigmentation was characterized by variable numbers of cells within the respiratory epithelium with abundant intracytoplasmic accumulation of golden brown pigmented material.

Changes involving the turbinates consisted of hyperostosis and deformity, which are considered to reflect postinflammation bony remodeling. These turbinate changes were most commonly seen in and most severe in Level III of the nose. These lesions were characterized by increased bony deposition (hyperostosis) and malformation (Figure 13). Occasional fusion of turbinates to the nasal septum and to each other was noted.

Lung: Compared to the vehicle controls at 2 years, the incidences of suppurative inflammation were significantly increased in 1,000 mg/kg males and females [males: vehicle control, 0/50; 100 mg/kg, 1/50 (2.0); 300 mg/kg, 3/50 (3.7); 1,000 mg/kg, 10/50 (3.7); females: 1/50 (2.0), 3/49 (2.0), 2/50 (3.5), 9/48 (3.4); Table A-3 and Table B-3]; the severity was increased at 300 and 1,000 mg/kg. Suppurative inflammation of moderate to marked severity was characterized by acute accumulation of massive numbers of neutrophils and fibrin within alveolar spaces and bronchial and bronchiolar lumens. These lesions often were focally extensive over large portions of the affected lung lobes. There was occasionally necrosis of alveolar septa and bronchial and bronchiolar epithelium and focal or multifocal hemorrhage. The findings were considered consistent with aspiration pneumonia, though no foreign material was evident within the examined sections.

Heart: Epicardium inflammation was seen at 2 years in 300 and 1,000 mg/kg males [vehicle control, 0/50; 100 mg/kg, 0/50; 300 mg/kg, 1/50 (1.0); 1,000 mg/kg, 5/50 (2.2); Table A-3] and in all dosed groups of females [0/50, 2/48 (2.0), 2/50 (2.0), 4/48 (1.5); Table B-3]; the incidences at 1,000 mg/kg were significantly greater than the vehicle control incidences. A single incidence of pericardium inflammation of marked severity was seen in a 1,000 mg/kg male. Inflammation of the pericardium or epicardium occasionally extended into the underlying heart and was an extension of the inflammatory process in the lungs. Three incidences of mild myocardium necrosis occurred in the 1,000 mg/kg males. Myocardial necrosis was diagnosed when there were multiple cardiomyocytes that were swollen and hypereosinophilic with a loss of cellular and nuclear detail. These cells often had an associated predominantly neutrophilic inflammatory infiltrate. This lesion was distinguished from cardiomyopathy due to the presence of multiple cardiomyocytes in the same acute stage of cellular death.

Bone Marrow: Incidences of bone marrow hyperplasia were significantly increased in all dosed groups of females at 2 years [6/50 (1.7), 14/50 (2.1), 16/50 (2.4), 13/50 (2.5); Table B-3]. The hyperplastic bone marrow was predominantly composed of immature cells of granulocyte lineage.

Spleen: The incidences of lymphoid depletion at 2 years were significantly increased in the 1,000 mg/kg males and all dosed groups of females [males: 1/50 (2.0), 2/50 (2.0), 1/50 (1.0), 13/50 (2.2); females: 0/50, 7/49 (1.7), 5/48 (1.8), 17/43 (1.7); Table A-3 and Table B-3]. Lymphoid depletion consisted of a decrease in white pulp (periarteriolar, follicular, or multizonal) compared to that in the vehicle control rats.

Other Organs: Uterine endometrial adenocarcinoma was observed in all dosed groups of females in the original evaluation (3/50, 9/50, 5/50, 4/50; Table B-1 and Table B-2); there was no statistically significant difference between the groups. A longitudinal evaluation of the residual uterine tissue revealed numerous uterine neoplasms in all groups, as well as occurrences of atypical hyperplasia (Table B-4). When the incidences of uterine neoplasms from the original evaluation and the longitudinal evaluation were combined, there was not considered to be an effect due to green tea extract exposure.

## Mice

### Three-month Study

Six males and four females administered 1,000 mg/kg died before the end of the study (Table 12). Early deaths were due to liver necrosis. Final mean body weights and mean body weight gains of males administered 250 mg/kg or greater and females administered 125 mg/kg or greater were significantly less than those of the vehicle controls (Table 12 and Figure 7). Clinical findings included lethargy, abnormal breathing, and ataxia in early death females and ruffled fur in two surviving 1,000 mg/kg males.

Table 12 Survival and Body Weights of Mice in the Three-month Gavage Study of Green Tea Extract^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 24.4 ± 0.3 | 40.7 ± 1.0 | 16.3 ± 0.9 | –
62.5 | 10/10 | 24.2 ± 0.4 | 38.5 ± 1.1 | 14.3 ± 1.0 | 95
125 | 10/10 | 24.1 ± 0.3 | 39.4 ± 1.0 | 15.3 ± 0.9 | 97
250 | 10/10 | 24.3 ± 0.4 | 35.4 ± 0.9** | 11.1 ± 0.8** | 87
500 | 10/10 | 24.3 ± 0.3 | 34.1 ± 0.9** | 9.8 ± 0.8** | 84
1,000 | 4/10^c^ | 24.2 ± 0.3 | 30.8 ± 0.9** | 6.3 ± 0.6** | 76
Female
0 | 10/10 | 18.7 ± 0.2 | 30.4 ± 0.6 | 11.7 ± 0.6 | –
62.5 | 10/10 | 18.9 ± 0.3 | 32.9 ± 1.1 | 14.0 ± 0.9 | 92
125 | 10/10 | 18.3 ± 0.2 | 26.6 ± 0.7** | 8.3 ± 0.6** | 88
250 | 10/10 | 18.6 ± 0.2 | 26.8 ± 0.7** | 8.2 ± 0.6** | 88
500 | 10/10 | 18.6 ± 0.2 | 24.3 ± 0.4** | 5.7 ± 0.5** | 80
1,000 | 6/10^d^ | 18.3 ± 0.2 | 26.2 ± 0.3** | 7.6 ± 0.2** | 86

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Weeks of deaths: 1, 1, 1, 1, 1, 8.

^d^ Weeks of deaths: 1, 1, 10, 11.

Figure 7

Growth Curves for Mice Administered Green Tea Extract by Gavage for Three Months

No changes in the hematology data for mice were considered attributable to the administration of green tea extract (Table F-2).

The absolute thymus weight of 1,000 mg/kg males was significantly less by approximately 35% and those of 500 and 1,000 mg/kg females were significantly less (up to 23%) than those of the vehicle control groups (Table G-3). The changes in the thymus weights were most likely due to stress. Other statistically significant changes in organ weights were not considered biologically significant or were considered related to changes in body weight.

Males administered 500 mg/kg exhibited a significantly decreased spermatid per testis count (11%) compared to vehicle controls (Table H-3). Females administered 500 mg/kg spent significantly more time in extended diestrus than did the vehicle controls (Table H-4). Thus, under the conditions of these studies, green tea extract administered by oral gavage exhibited the potential to be a reproductive toxicant in male and female B6C3F1/N mice.

In the liver, increased incidences of centrilobular necrosis, glycogen depletion, pigmentation, mitosis, karyomegaly, and chronic inflammation (females) occurred in the 1,000 mg/kg groups of male and female mice (Table 13). Increased incidences of glycogen depletion in 250 and 500 mg/kg males and females and centrilobular necrosis in 125 mg/kg males were also observed. The liver necrosis in severely affected animals was characterized by a centrilobular to panlobular necrosis and hemorrhage. In the livers with minimal to mild necrosis, there were more individualized hepatocytes undergoing necrosis with minimal to no inflammation. If inflammatory cells were present, they were usually macrophages, lymphocytes, and plasma cells. Hepatocytes were characterized by pyknotic, condensed nuclei and shrunken eosinophilic cytoplasm. Chronic inflammation consisted of infiltration of mononuclear cells in the areas of hepatocellular necrosis. Mitosis was characterized by the presence of hepatocytes with mitotic figures in the intervening region between the centrilobular and periportal regions. Accumulation of golden brown cytoplasmic pigment was present in the Kupffer cells. Special stains were not performed on mouse liver sections. However, a similar pigment was found in the rat livers as a treatment-related effect. Minimal karyomegaly was diagnosed when 10 to 50 enlarged nuclei were observed per section. Diagnosis was not made if there was significant concurrent hepatocyte damage or cell swelling due to necrosis or fatty change. The karoymegalic hepatocytes occurred in mice having minimal levels of necrosis, and were located in the midzonal regions between centrilobular and periportal areas. The nuclei were 2.5 to 3 times normal size and had clumped chromatin or intranuclear vacuoles, which most likely represented invagination of the nuclear membrane. Rare hepatocytes with three nuclei were also present.

Table 13 Incidences of Selected Nonneoplastic Lesions in Mice in the Three-month Gavage Study of Green Tea Extract

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
Liver^a^ | 10 | 10 | 10 | 10 | 10 | 10
Depletion Glycogen^b^ | 2 (1.0)^c^ | 0 | 2 (1.5) | 8* (1.5) | 10** (1.7) | 4 (2.5)
Karyomegaly | 0 | 0 | 0 | 0 | 0 | 2 (1.0)
Mitosis | 0 | 0 | 0 | 0 | 0 | 3 (1.3)
Pigmentation | 0 | 0 | 0 | 0 | 0 | 2 (1.0)
Centrilobular Necrosis | 0 | 0 | 2 (1.0) | 0 | 0 | 8** (3.1)
Nose | 10 | 10 | 10 | 10 | 10 | 10
Inflammation | 0 | 0 | 1 (3.0) | 0 | 1 (2.0) | 1 (2.0)
Glands, Olfactory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 3 (1.3)
Nerve, Atrophy | 0 | 0 | 0 | 5* (1.2) | 7** (1.1) | 5* (1.8)
Olfactory Epithelium, Atrophy | 0 | 1 (1.0) | 0 | 4* (1.3) | 4* (1.8) | 4* (1.3)
Olfactory Epithelium, Hyperplasia, Basal Cell | 0 | 0 | 0 | 0 | 0 | 3 (2.3)
Olfactory Epithelium, Metaplasia | 0 | 0 | 0 | 5* (1.0) | 5* (1.2) | 5* (2.2)
Olfactory Epithelium, Necrosis | 0 | 0 | 1 (3.0) | 0 | 1 (3.0) | 3 (1.7)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 3 (1.0)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 0 | 0 | 1 (2.0)
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 1 (4.0) | 1 (2.0)
Lymph Node, Mesenteric | 10 | 10 | 10 | 10 | 10 | 10
Atrophy | 4 (1.0) | 0* | 0* | 0* | 2 (1.0) | 8 (1.4)
Lymph Node, Mandibular | 10 | 10 | 10 | 10 | 10 | 10
Atrophy | 1 (1.0) | 0 | 0 | 0 | 2 (1.0) | 7** (1.9)
Thymus | 10 | 10 | 10 | 10 | 10 | 10
Atrophy | 0 | 0 | 0 | 0 | 0 | 6** (3.3)
Intestine, Large, Colon | 10 | 0 | 0 | 0 | 10 | 10
Peyer’s Patch, Atrophy | 0 | – | – | – | 0 | 1 (1.0)
Intestine, Small, Ileum | 10 | 0 | 0 | 0 | 10 | 10
Peyer’s Patch, Atrophy | 0 | – | – | – | 0 | 2 (2.0)
Female
Liver | 10 | 10 | 10 | 10 | 10 | 10
Depletion Glycogen | 0 | 0 | 0 | 1 (1.0) | 4* (1.5) | 7** (2.1)
Inflammation, Chronic | 0 | 0 | 0 | 0 | 0 | 3 (2.0)
Karyomegaly | 0 | 0 | 0 | 0 | 0 | 5* (1.0)
Mitosis | 0 | 0 | 0 | 0 | 0 | 2 (2.0)
Pigmentation | 0 | 0 | 0 | 0 | 0 | 2 (1.0)
Centrilobular Necrosis | 0 | 0 | 0 | 0 | 0 | 7** (2.4)
Nose | 10 | 10 | 10 | 10 | 10 | 10
Inflammation | 0 | 1 (2.0) | 1 (2.0) | 0 | 0 | 1 (1.0)
Glands, Olfactory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Nasopharyngeal Duct, Degeneration | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Nerve, Atrophy | 0 | 0 | 1 (1.0) | 1 (1.0) | 7** (1.3) | 5* (1.4)
Olfactory Epithelium, Atrophy | 0 | 0 | 1 (2.0) | 0 | 4* (1.0) | 4* (1.8)
Olfactory Epithelium, Hyperplasia, Basal Cell | 0 | 0 | 0 | 0 | 0 | 1 (2.0)
Olfactory Epithelium, Metaplasia | 0 | 0 | 1 (1.0) | 1 (1.0) | 7** (1.6) | 6** (1.3)
Olfactory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 1 (1.0) | 4* (1.5)
Respiratory Epithelium, Hyaline Droplet | 0 | 0 | 0 | 1 (2.0) | 4* (1.8) | 0
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 2 (2.0)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 1 (3.0)
Spleen | 10 | 10 | 10 | 10 | 10 | 10
Atrophy, Lymphoid | 0 | 0 | 0 | 1 (1.0) | 4* (1.0) | 4* (2.8)
Lymph Node, Mesenteric | 10 | 10 | 10 | 10 | 10 | 9
Atrophy | 2 (1.0) | 0 | 0 | 0 | 2 (1.5) | 3 (2.3)
Lymph Node, Mandibular | 10 | 10 | 10 | 10 | 10 | 10
Atrophy | 0 | 0 | 0 | 2 (1.0) | 2 (1.5) | 4* (2.0)
Thymus | 10 | 10 | 10 | 10 | 10 | 10
Atrophy | 0 | 0 | 0 | 0 | 0 | 4* (3.3)
Intestine, Large, Cecum | 10 | 0 | 0 | 0 | 0 | 10
Peyer’s Patch, Atrophy | 0 | – | – | – | – | 1 (1.0)
Intestine, Small, Ileum | 10 | 0 | 0 | 0 | 0 | 10
Peyer’s Patch, Atrophy | 0 | – | – | – | – | 2 (2.5)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Significant increases in the incidences of lesions of the nose occurred in the 500 and 1,000 mg/kg groups of male and female mice and included nerve atrophy and atrophy, metaplasia, and necrosis (1,000 mg/kg females) of the olfactory epithelium (Table 13). Incidences of nerve atrophy and olfactory epithelium atrophy and metaplasia were also significantly increased in 250 mg/kg males. The incidence of hyaline droplet accumulation of the respiratory epithelium was significantly increased in 500 mg/kg females. Other biologically important lesions that were not significantly increased included inflammation; hyperplasia of the glands of the olfactory epithelium; degeneration of the nasopharyngeal duct (females); basal cell hyperplasia and necrosis (males) of the olfactory epithelium; and hyperplasia, squamous metaplasia, and necrosis of the respiratory epithelium. Several of these lesions that lacked statistical significance in the 3-month study were significantly increased in incidence in the 2-year study. These varying lesions are most likely all part of a spectrum of changes associated with the same pathologic process.

Lesions of the olfactory epithelium were focal to locally extensive and frequently bilateral and/or involved multiple levels (Levels II and III). Olfactory epithelium atrophy was associated with thinning of the layers of olfactory epithelial cells, especially in the dorsal meatus, compared to vehicle controls. Nerve atrophy was noted by the loss of olfactory nerve bundles in the submucosal regions underlying the olfactory epithelium in the dorsal meatus of Level II and nasal turbinates of Level III. Atrophy was most notable in the dorsal and dorsolateral meatus. Nerve atrophy was frequently accompanied by olfactory epithelium metaplasia characterized by the transition of olfactory epithelium to respiratory epithelium.

Olfactory epithelium necrosis was characterized by loss of olfactory sensory epithelial cells or pyknosis and karyorrhexis of olfactory epithelial nuclei with infiltrates of neutrophils and lesser numbers of lymphocytes and plasma cells.

Basal cell hyperplasia of the olfactory epithelium was sporadically seen in 1,000 mg/kg males and females and was located in the dorsal meatus of Levels II and III. There were increased numbers of basal cells and instead of a single layer of basophilic nuclei, nuclei were frequently piled up or crowded and extended up into the olfactory cells. Occasionally, hyperplastic cuboidal cells extended to the Bowman’s glands and appeared as nodular proliferations of cells underlying the olfactory epithelium. The proliferating basal cells frequently obscured the lumen of the Bowman’s glands.

Inflammation in the nose was an infrequent finding in mice compared to rats. Inflammation was characterized by the presence of infiltrates of neutrophils with lesser numbers of lymphocytes and plasma cells in the lamina propria of the respiratory epithelium in various locations but most frequently along the septum or lateral walls and dorsal meatus (Level I) and in some cases the lamina propria of the olfactory epithelium (Levels II and III). Occasionally this mixed cellular infiltrate would extend into the overlying epithelium (either respiratory or olfactory, depending on the location).

The nasopharyngeal duct located at Level III was degenerated in one 1,000 mg/kg female. This lesion was characterized by loss of goblet cells and occasionally the attenuation of the typical tall columnar epithelium.

Squamous metaplasia of the respiratory epithelium in Levels I and II of the nasal cavity was characterized by transformation of the columnar cuboidal ciliated respiratory epithelium to well-differentiated stratified squamous epithelium intermittently along the lateral wall and a portion of nasal septum and dorsolateral meatus. This lesion occurred in association with respiratory epithelium hyperplasia, which was characterized by the proliferation of nonciliated cuboidal epithelium that affected extensive areas of the respiratory epithelium at Levels I and II along the nasal septum and lateral walls of the nasal cavity. Respiratory epithelium necrosis was characterized by loss of respiratory epithelial cells, or pyknosis and karyorrhexis of respiratory epithelial nuclei, and sloughing of necrotic cells admixed with infiltrates of degenerative and viable neutrophils and lesser numbers of lymphocytes and plasma cells and cell debris.

Evidence of lymphoid tissue atrophy was seen in the spleen (females), lymph nodes (mesenteric and mandibular), thymus, and intestine (Peyer’s patches) (Table 13). These lesions may represent direct toxicity, but it is likely they are evidence of an indirect effect, such as stress.

In the spleen, dose-related increased incidences and severities of lymphoid atrophy were noted in 250 mg/kg or greater females (Table 13). Atrophy in the spleen was characterized by loss of B cell lymphocytes in the germinal centers and follicles and loss of T cell lymphocytes in the periarteriolar lymphoid sheath region.

Increased incidences of mesenteric lymphoid atrophy occurred in 1,000 mg/kg males and females, with the males being more frequently affected, and increased incidences of mandibular lymphoid atrophy occurred in 500 and 1,000 mg/kg males and 250 mg/kg or greater females (Table 13). The severity of these lesions generally increased with increasing dose. In the mesenteric lymph node, atrophy of the T lymphocytes in the paracortex and B cells of the follicles was characterized by loss of lymphocytes and apoptosis of lymphocytes. Apoptotic lymphocytes had condensed nuclear chromatin and cytoplasm, pyknosis, and karyorrhexis. In the mandibular lymph node, atrophy of the T lymphocytes in the paracortex and B cells of the follicles was characterized by loss of lymphocytes, lymphocytes with condensed and fragmented nuclear chromatin (pyknosis and karyorrhexis), and shrunken cells with condensed cytoplasm.

Mild to marked thymic atrophy occurred in 1,000 mg/kg males and females (Table 13). Atrophy was characterized by variable thinning of the cortex due to loss of T cells by apoptosis.

Sporadic cases of minimal to moderate atrophy of the Peyer’s patches were seen in the ileum and cecum or colon of 1,000 mg/kg males and females (Table 13). This lesion was characterized by lymphoid depletion and apoptosis of, largely, B lymphocytes residing in the follicle and occasional T lymphocytes in the perifollicular areas.

Dose Selection Rationale: Significant decreases in survival were observed in the 1,000 mg/kg mice. Treatment-related decreases in body weight gain in the 500 mg/kg groups were considered dose limiting. Therefore, the green tea extract doses selected for the 2-year gavage study in mice were 30, 100, and 300 mg/kg.

## Two-year Study

### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 14 and in the Kaplan-Meier survival curves (Figure 8). Survival of dosed groups was similar to that of the vehicle control groups.

Table 14 Survival of Mice in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | | 30 mg/kg | 100 mg/kg | 300 mg/kg
Male
Animals initially in study | 50 | | 50 | 50 | 50
Accidental deaths^a^ | 0 | | 0 | 0 | 2
Moribund | 6 | | 8 | 7 | 10
Natural deaths | 11 | | 6 | 10 | 1
Animals surviving to study termination | 33 | | 36 | 33^b^ | 37
Percent probability of survival at end of study^c^ | 66 | | 72 | 66 | 77
Mean survival (days)^d^ | 694 | | 702 | 705 | 699
Survival analysis^e^ | P = 0.325N | | P = 0.657N | P = 1.000 | P = 0.296N
Female
Animals initially in study | 50 | | 50 | 50 | 50
Accidental deaths^a^ | 3 | | 6 | 1 | 0
Moribund | 10 | | 2 | 2 | 6
Natural deaths | 3 | | 9 | 3 | 5
Animals surviving to study termination | 34 | | 33^f^ | 44 | 39
Percent probability of survival at end of study | 72 | | 75 | 90 | 78
Mean survival (days) | 665 | | 620 | 701 | 680
Survival analysis | P = 0.808N | | P = 1.000 | P = 0.061N | P = 0.779N

^a^ Censored from survival analyses.

^b^ Includes one animal that died during the last week of the study (censored from survival analysis).

^c^ Kaplan-Meier determinations.

^d^ Mean of all deaths (uncensored, censored, and terminal kill).

^e^ The result of the life table trend test^106^ is in the vehicle control column, and the results of the life table pairwise comparisons^105^ with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dose group is indicated by N.

^f^ Includes one animal that died during the last week of the study (not censored from survival analysis).

Figure 8

Kaplan-Meier Survival Curves for Mice Administered Green Tea Extract by Gavage for Two Years

### Body Weights and Clinical Findings

Mean body weights of 100 and 300 mg/kg males were at least 10% less than those of the vehicle control group after weeks 89 and 65, respectively, and mean body weights of 100 and 300 mg/kg females were at least 10% less after weeks 25 and 17, respectively (Figure 9; Table 15 and Table 16). There were no clinical findings related to green tea extract administration.

Figure 9

Growth Curves for Mice Administered Green Tea Extract by Gavage for Two Years

Table 15 Mean Body Weights and Survival of Male Mice in the Two-year Gavage Study of Green Tea Extract

Day | 0 mg/kg | | 30 mg/kg | | | | 100 mg/kg | | | 300 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 22.1 | 50 | 22.2 | 101 | 50 | | 22.1 | 100 | 50 | 22.2 | 101 | 50
8 | 23.1 | 50 | 23.0 | 100 | 50 | | 22.8 | 99 | 50 | 23.1 | 100 | 50
15 | 24.0 | 50 | 24.0 | 100 | 50 | | 23.8 | 99 | 50 | 23.9 | 100 | 50
22 | 25.5 | 50 | 25.7 | 101 | 50 | | 25.5 | 100 | 50 | 25.5 | 100 | 50
29 | 26.3 | 50 | 26.5 | 101 | 50 | | 26.1 | 100 | 50 | 26.2 | 100 | 50
36 | 27.2 | 50 | 27.5 | 101 | 50 | | 27.1 | 100 | 50 | 27.2 | 100 | 50
43 | 28.5 | 50 | 28.6 | 101 | 50 | | 28.2 | 99 | 50 | 28.3 | 99 | 50
50 | 29.8 | 50 | 29.7 | 100 | 50 | | 29.4 | 99 | 50 | 29.5 | 99 | 50
57 | 31.3 | 50 | 31.3 | 100 | 50 | | 30.7 | 98 | 50 | 30.4 | 97 | 50
64 | 32.4 | 50 | 32.7 | 101 | 50 | | 32.0 | 99 | 50 | 31.5 | 97 | 50
71 | 33.1 | 50 | 33.2 | 100 | 50 | | 32.3 | 97 | 50 | 32.3 | 98 | 50
78 | 34.6 | 50 | 34.7 | 100 | 50 | | 33.7 | 98 | 50 | 33.3 | 96 | 50
85 | 35.3 | 50 | 35.6 | 101 | 50 | | 34.5 | 98 | 50 | 34.2 | 97 | 50
113 | 39.9 | 50 | 40.1 | 100 | 50 | | 38.6 | 97 | 50 | 37.0 | 93 | 50
141 | 42.5 | 50 | 43.2 | 101 | 50 | | 41.3 | 97 | 50 | 39.3 | 93 | 50
169 | 45.1 | 50 | 45.1 | 100 | 50 | | 43.1 | 96 | 50 | 40.9 | 91 | 50
197 | 46.3 | 50 | 46.4 | 100 | 50 | | 42.6 | 92 | 50 | 41.0 | 89 | 50
225 | 47.5 | 50 | 47.9 | 101 | 50 | | 46.0 | 97 | 50 | 44.0 | 93 | 50
253 | 48.9 | 50 | 49.0 | 100 | 50 | | 46.5 | 95 | 50 | 44.4 | 91 | 50
281 | 49.7 | 50 | 49.3 | 99 | 50 | | 47.1 | 95 | 50 | 44.8 | 90 | 50
309 | 50.6 | 50 | 50.1 | 99 | 50 | | 47.6 | 94 | 50 | 45.5 | 90 | 50
337 | 50.8 | 49 | 50.6 | 100 | 50 | | 48.7 | 96 | 50 | 46.6 | 92 | 50
365 | 51.3 | 49 | 51.6 | 101 | 50 | | 49.5 | 97 | 50 | 48.2 | 94 | 50
393 | 51.8 | 49 | 51.5 | 99 | 50 | | 49.8 | 96 | 50 | 47.8 | 92 | 50
421 | 51.7 | 49 | 51.4 | 99 | 50 | | 50.3 | 97 | 50 | 48.7 | 94 | 50
449 | 51.4 | 49 | 51.3 | 100 | 50 | | 50.4 | 98 | 50 | 48.4 | 94 | 48
477 | 52.1 | 49 | 52.1 | 100 | 49 | | 50.0 | 96 | 50 | 45.5 | 87 | 47
505 | 52.1 | 49 | 52.2 | 100 | 49 | | 49.5 | 95 | 50 | 45.3 | 87 | 47
533 | 52.0 | 49 | 51.9 | 100 | 48 | | 50.4 | 97 | 49 | 44.2 | 85 | 47
561 | 51.9 | 47 | 51.5 | 99 | 47 | | 50.0 | 96 | 48 | 42.1 | 81 | 47
589 | 52.0 | 46 | 51.0 | 98 | 47 | | 50.3 | 97 | 48 | 40.7 | 78 | 47
617 | 52.6 | 41 | 51.6 | 98 | 44 | | 48.1 | 91 | 48 | 38.7 | 74 | 46
645 | 52.0 | 39 | 51.2 | 98 | 42 | | 45.3 | 87 | 45 | 34.6 | 67 | 44
673 | 52.1 | 38 | 50.0 | 96 | 41 | | 43.8 | 84 | 43 | 33.9 | 65 | 41
701 | 51.5 | 38 | 49.5 | 96 | 39 | | 43.4 | 84 | 35 | 34.4 | 67 | 38
Mean for Weeks
1–13 | 28.7 | – | 28.8 | 100 | – | | 28.3 | 99 | – | 28.3 | 99 | –
14–52 | 46.8 | – | 46.9 | 100 | – | | 44.6 | 95 | – | 42.6 | 91 | –
53–101 | 51.9 | – | 51.3 | 99 | – | | 48.5 | 93 | – | 42.5 | 82 | –

Table 16 Mean Body Weights and Survival of Female Mice in the Two-year Gavage Study of Green Tea Extract

Day | 0 mg/kg | | 30 mg/kg | | | 100 mg/kg | | | 300 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 17.8 | 50 | 17.8 | 100 | 50 | 17.7 | 100 | 50 | 17.7 | 99 | 50
8 | 18.0 | 47 | 17.8 | 99 | 46 | 18.0 | 100 | 49 | 18.2 | 101 | 48
15 | 18.9 | 47 | 18.8 | 99 | 46 | 18.9 | 100 | 49 | 19.0 | 100 | 48
22 | 20.1 | 47 | 19.6 | 98 | 45 | 19.7 | 98 | 49 | 20.0 | 100 | 48
29 | 20.7 | 47 | 20.5 | 99 | 44 | 20.3 | 98 | 49 | 20.3 | 98 | 48
36 | 21.4 | 47 | 21.0 | 99 | 44 | 20.9 | 98 | 49 | 21.1 | 99 | 48
43 | 22.2 | 47 | 22.5 | 101 | 44 | 21.8 | 98 | 49 | 22.0 | 99 | 48
50 | 23.6 | 47 | 23.3 | 99 | 44 | 22.9 | 97 | 49 | 22.8 | 97 | 48
57 | 23.6 | 47 | 23.7 | 101 | 44 | 23.6 | 100 | 49 | 23.4 | 99 | 48
64 | 25.3 | 47 | 24.9 | 99 | 44 | 24.5 | 97 | 49 | 23.9 | 95 | 48
71 | 26.0 | 47 | 26.0 | 100 | 44 | 25.2 | 97 | 49 | 25.3 | 98 | 48
78 | 27.2 | 47 | 26.9 | 99 | 44 | 26.2 | 96 | 49 | 26.0 | 95 | 48
85 | 28.5 | 47 | 27.7 | 98 | 44 | 27.0 | 95 | 49 | 26.2 | 92 | 48
113 | 31.5 | 47 | 30.8 | 98 | 44 | 30.1 | 96 | 49 | 28.5 | 91 | 48
141 | 35.7 | 47 | 34.5 | 97 | 44 | 33.5 | 94 | 49 | 31.9 | 89 | 48
169 | 37.7 | 47 | 33.4 | 89 | 44 | 35.1 | 93 | 49 | 33.2 | 88 | 48
197 | 41.5 | 47 | 38.7 | 93 | 44 | 37.1 | 89 | 49 | 35.8 | 86 | 48
225 | 44.0 | 47 | 41.1 | 93 | 44 | 39.5 | 90 | 49 | 37.5 | 85 | 48
253 | 47.5 | 47 | 44.1 | 93 | 44 | 41.1 | 86 | 49 | 38.4 | 81 | 48
281 | 49.7 | 47 | 46.2 | 93 | 44 | 43.0 | 86 | 49 | 39.7 | 80 | 48
309 | 52.5 | 47 | 49.1 | 94 | 44 | 45.4 | 87 | 49 | 42.1 | 80 | 48
337 | 54.9 | 47 | 51.5 | 94 | 44 | 47.3 | 86 | 49 | 42.6 | 78 | 48
365 | 57.2 | 47 | 54.1 | 95 | 44 | 50.5 | 88 | 49 | 47.0 | 82 | 48
393 | 57.8 | 46 | 56.0 | 97 | 43 | 52.0 | 90 | 48 | 47.5 | 82 | 48
421 | 58.8 | 46 | 56.9 | 97 | 43 | 53.0 | 90 | 48 | 46.4 | 79 | 48
449 | 59.1 | 46 | 57.0 | 97 | 43 | 53.2 | 90 | 48 | 46.2 | 78 | 48
477 | 60.2 | 46 | 57.8 | 96 | 43 | 50.2 | 84 | 48 | 42.9 | 71 | 48
505 | 61.3 | 46 | 58.7 | 96 | 43 | 50.7 | 83 | 48 | 42.9 | 70 | 47
533 | 61.5 | 46 | 60.1 | 98 | 42 | 51.3 | 83 | 48 | 44.7 | 73 | 46
561 | 60.7 | 46 | 58.6 | 97 | 42 | 49.4 | 81 | 48 | 43.2 | 71 | 46
589 | 61.8 | 45 | 59.4 | 96 | 41 | 49.3 | 80 | 47 | 43.5 | 70 | 45
617 | 62.9 | 43 | 59.1 | 94 | 41 | 48.0 | 76 | 47 | 43.3 | 69 | 43
645 | 61.6 | 43 | 58.3 | 95 | 38 | 44.9 | 73 | 46 | 42.0 | 68 | 43
673 | 60.6 | 41 | 56.5 | 93 | 37 | 40.3 | 67 | 46 | 41.4 | 68 | 42
701 | 59.7 | 39 | 56.0 | 94 | 36 | 37.7 | 63 | 45 | 39.0 | 65 | 42
Mean for Weeks
1–13 | 22.6 | – | 22.3 | 99 | – | 22.1 | 98 | – | 22.0 | 97 | –
14–52 | 43.9 | – | 41.0 | 93 | – | 39.1 | 89 | – | 36.6 | 83 | –
53–101 | 60.2 | – | 57.6 | 96 | – | 48.5 | 81 | – | 43.8 | 73 | –

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the nose, lung, bone marrow, mandibular lymph node, liver, adrenal gland, and pancreatic islets. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix C for male mice and Appendix D for female mice.

Nose: The incidences of suppurative inflammation and foreign body (except 30 mg/kg females) in all dosed groups of mice were significantly greater than the vehicle control group incidences (Table 17, Table C-3, and Table D-3). Increased incidences of lumen pigmentation occurred in all dosed groups, and the increases were significant in 30 and 300 mg/kg females. The incidences of hyperostosis, septum perforation, and turbinate atrophy were significantly increased in 100 and 300 mg/kg mice. The severity of these lesions generally increased with increasing dose.

Table 17 Incidences of Nonneoplastic Lesions of the Nose in Mice in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | 30 mg/kg | 100 mg/kg | 300 mg/kg
Male
Number Examined Microscopically | 50 | 49 | 50 | 50
Foreign Body^a^ | 1 | 10** | 16** | 25**
Hyperostosis | 0 | 0 | 28** (1.5)^b^ | 46** (1.6)
Inflammation, Suppurative | 14 (1.0) | 40** (1.3) | 49** (2.6) | 48** (2.8)
Lumen, Pigmentation | 0 | 3 (1.0) | 4 (1.3) | 2 (1.5)
Nasopharyngeal Duct, Degeneration | 0 | 0 | 4 (1.0) | 9** (1.3)
Nasopharyngeal Duct, Inflammation | 0 | 1 (1.0) | 2 (1.5) | 4 (1.3)
Nasopharyngeal Duct, Metaplasia, Squamous | 0 | 0 | 0 | 1 (2.0)
Nerve, Atrophy | 0 | 26** (1.5) | 49** (2.9) | 50** (3.5)
Olfactory Epithelium, Atrophy | 4 (1.5) | 24** (1.3) | 28** (1.6) | 3 (1.0)
Olfactory Epithelium, Fibrosis | 0 | 4 (1.3) | 37** (1.8) | 43** (2.8)
Olfactory Epithelium, Metaplasia, Respiratory | 11 (1.1) | 45** (1.5) | 49** (3.2) | 49** (4.0)
Olfactory Epithelium, Necrosis | 0 | 2 (1.0) | 1 (2.0) | 0
Respiratory Epithelium, Hyperplasia | 5 (1.4) | 20** (1.4) | 10 (1.3) | 19** (1.4)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 14** (1.3) | 39** (1.6) | 46** (2.3)
Respiratory Epithelium, Necrosis | 0 | 7** (1.0) | 16** (1.3) | 27** (1.7)
Septum, Perforation | 1 | 0 | 26** | 37**
Turbinate, Atrophy | 0 | 0 | 41** (1.3) | 50** (2.8)
Female
Number Examined Microscopically | 48 | 48 | 50 | 50
Foreign Body | 4 | 8 | 13* | 17**
Hyperostosis | 0 | 0 | 21** (1.1) | 48** (2.1)
Inflammation, Suppurative | 4 (1.0) | 24** (1.0) | 44** (2.8) | 47** (2.4)
Lumen, Pigmentation | 0 | 19** (1.0) | 3 (1.0) | 16** (1.7)
Nasopharyngeal Duct, Degeneration | 0 | 0 | 2 (1.0) | 4 (1.8)
Nasopharyngeal Duct, Inflammation | 0 | 0 | 1 (2.0) | 3 (1.0)
Nerve, Atrophy | 0 | 13** (1.2) | 47** (3.4) | 48** (3.5)
Olfactory Epithelium, Atrophy | 0 | 18** (1.6) | 26** (1.8) | 17** (2.2)
Olfactory Epithelium, Fibrosis | 0 | 1 (1.0) | 39** (1.8) | 43** (2.2)
Olfactory Epithelium, Metaplasia, Respiratory | 2 (1.0) | 36** (1.7) | 49** (3.4) | 48** (3.7)
Olfactory Epithelium, Necrosis | 0 | 2 (1.5) | 1 (1.0) | 0
Respiratory Epithelium, Hyperplasia | 1 (1.0) | 1 (1.0) | 22** (1.1) | 15** (1.3)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 8** (1.0) | 42** (2.0) | 42** (1.9)
Respiratory Epithelium, Necrosis | 0 | 4 (1.5) | 28** (1.3) | 32** (1.5)
Septum, Perforation | 0 | 0 | 38** | 42**
Turbinate, Atrophy | 0 | 0 | 40** (1.2) | 48** (2.7)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Inflammation of the nasal cavity was characterized by accumulations of primarily neutrophils within the nasal lumen. In addition, variable numbers of neutrophils were undergoing transepithelial migration, and neutrophils were present in the underlying submucosal stroma (Figure 14). The foreign body material ranged from large pieces of plant material to hair shafts and other small refractile pieces of unidentifiable material. The foreign bodies were typically surrounded by neutrophils. Acellular greenish-brown debris was also present within the lumen of the nasal cavity in some animals (Figure 15). A small number of animals had a similar pigmented material accumulated in intraluminal macrophages. Hyperostosis was variably characterized by deposition of woven and lamellar bone within the nasal septum and along the ventral surface of the flat bones lining the dorsal portion of the nasal cavity, primarily in Level III, but occasionally extending to Level II. Some animals with expanded nasal septa had enlarged and irregularly shaped bone marrow spaces within the bony deposits. Perforation of the septum in Level I consisted of a discontinuation of the septum separating the right and left nasal passages. Turbinate atrophy varied from thinned and/or slightly blunted nasoturbinates and maxilloturbinates of Levels I and II to pronounced blunting and fusion of the turbinates in Levels I and II and the ethmo-turbinates of Level III (Figure 16 and Figure 17).

Nasopharyngeal duct degeneration and inflammation occurred in 100 and 300 mg/kg mice, and inflammation was seen in one 30 mg/kg male (Table 17, Table C-3, and Table D-3). The increased incidence of degeneration in 300 mg/kg males was significant. One 300 mg/kg male had squamous metaplasia of the nasopharyngeal duct. Degeneration of the nasopharyngeal duct was characterized by cell swelling and vacuolation of the respiratory epithelium lining the duct. The inflammation and squamous metaplasia were similar to those previously described.

In the olfactory epithelium, incidences of atrophy in 30 and 100 mg/kg males and all dosed groups of females, respiratory metaplasia in all dosed groups, and fibrosis in 100 and 300 mg/kg males and females were significantly increased (Table 17, Table C-3, and Table D-3). The incidences of nerve atrophy were also significantly increased in all dosed groups. Necrosis occurred in a few mice administered 30 or 100 mg/kg. The lower incidence of olfactory epithelium atrophy in the high dose groups of males and females, when compared to the low and middle dose groups, may reflect a progression of some of the lesions past the point of atrophy and into fibrosis. Similarly, the few occurrences of necrosis of the olfactory epithelium probably represent that this lesion was fairly early on in the process and was followed by atrophy, and subsequently fibrosis. Atrophy of the olfactory epithelium was seen in Level III and in the dorsal portion of Level II, and was associated with subsequent atrophy of the related olfactory nerve bundles. Olfactory epithelium atrophy ranged from focally extensive lesions of decreased number and disorganization of the nuclear layers and loss of the lumenal eosinophilic border to extensive thinning and cellular loss of the olfactory epithelium. When becoming metaplastic, the olfactory epithelium was replaced by respiratory epithelium. In some animals with respiratory metaplasia of the olfactory epithelium, there were variable numbers of invaginations of the respiratory epithelium resembling glands within the subepithelial stroma. When fibrosis was present, the stroma underlying the affected olfactory epithelium was altered in that there was a loss of Bowman’s glands, atrophy of the nerve bundles, and occasionally deposition of fibrous connective tissue. In some animals, generally those with more severe inflammation, the epithelium replacing the olfactory epithelium was composed of one or multiple layers of flattened squamoid epithelium that was most consistent with recently damaged/lost epithelium undergoing reepithelialization. Necrosis of the olfactory epithelium was characterized by the presence of a segment or cluster of epithelial cells that were shrunken and hypereosinophilic with karyorrhexis and/or nuclear pyknosis with or without cell loss.

In the respiratory epithelium, the incidences of necrosis in all dosed groups except 30 mg/kg females, squamous metaplasia in all dosed groups, and hyperplasia in 30 and 300 mg/kg males and 100 and 300 mg/kg females were significantly greater than the vehicle control incidences (Table 17, Table C-3, and Table D-3). In males, the severity of squamous metaplasia and necrosis increased with increasing dose. Necrosis of the respiratory epithelium was characterized by hypereosinophilia and cell swelling, and often there were large sections of affected epithelium sloughing off of an underlying basal epithelial layer. Squamous metaplasia of the respiratory epithelium was characterized by replacement of the ciliated columnar epithelium by flattened squamous epithelium of variable thickness. This change was located most commonly at the tips of the nasoturbinates and along the lateral wall of Level I, and less often Level II. Respiratory epithelium hyperplasia was characterized by increased numbers of cells piled up in multiple layers or forming folds and invaginations into the underlying lamina propria and was most often observed on the tips of nasal turbinates and along the nasal septum and lateral walls of Levels I and II.

Lung: Increased incidences and severities of inflammation occurred in 100 and 300 mg/kg males; occurrences of the lesion were also recorded in the 30 and 100 mg/kg females [males: 1/50 (1.0), 0/50, 6/50 (4.0), 5/50 (3.2); females: 0/50, 1/49 (4.0), 2/50 (3.0), 0/50; Table C-3 and Table D-3]. Inflammation was characterized primarily by massive infiltrates of neutrophils within alveolar spaces and extending into bronchioles and occasional bronchi. The lesions often were focally extensive over large portions of the affected lung lobes. There were small numbers of alveolar macrophages, and frequently there were large numbers of intracellular and extracellular bacteria admixed with the neutrophils.

Bone Marrow: The incidences of hyperplasia were increased in all dosed groups of males and females, and the increases were significant in all but the 30 mg/kg females (Table 18, Table C-3, and Table D-3). Hyperplasia was characterized by an increase in the myeloid cell population.

Table 18 Incidences of Selected Nonneoplastic Lesions in Mice in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | 30 mg/kg | 100 mg/kg | 300 mg/kg
Male
Bone Marrow^a^ | 50 | 50 | 50 | 50
Hyperplasia^b^ | 5 (1.2)^c^ | 42** (1.6) | 38** (1.6) | 46** (1.5)
Mandibular Lymph Node | 50 | 50 | 50 | 50
Hyperplasia, Lymphoid | 0 | 1 (1.0) | 31** (2.2) | 37** (2.1)
Infiltration Cellular, Plasma Cell | 1 (1.0) | 1 (1.0) | 24** (1.3) | 41** (1.6)
Female
Bone Marrow | 50 | 50 | 50 | 50
Hyperplasia | 6 (2.2) | 11 (1.9) | 41** (2.4) | 34** (1.9)
Mandibular Lymph Node | 50 | 48 | 49 | 48
Hyperplasia, Lymphoid | 0 | 1 (2.0) | 8** (1.4) | 12** (1.4)
Infiltration Cellular, Plasma Cell | 0 | 0 | 31** (1.3) | 18** (1.3)

** Significantly different (P ≤ 0.01) from the vehicle control group by the Poly-3 test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Mandibular Lymph Node: The incidences of lymphoid hyperplasia and plasma cell infiltration were significantly increased in 100 and 300 mg/kg males and females (Table 18, Table C-3, and Table D-3). Plasma cell infiltration was characterized by increased plasma cells within the medullary cords. Lymphoid hyperplasia was characterized by expanded follicles and lymphocyte proliferation in paracortical regions.

Liver: The incidences of hepatocellular adenoma (males: vehicle control, 35/50; 30 mg/kg, 29/50; 100 mg/kg, 25/50; 300 mg/kg, 16/50; females: 12/50, 9/50, 3/50, 0/50) in 100 and 300 mg/kg males and females and hepatocellular adenoma or carcinoma (combined) (males: 40/50, 39/50, 35/50, 21/50; females: 14/50, 15/50, 7/50, 1/50) in 300 mg/kg males and 100 and 300 mg/kg females were significantly less than those in the vehicle control groups (Table C-1, Table C-2, Table D-1, and Table D-2). The incidences of multiple hepatocellular adenoma were also significantly decreased in 100 and 300 mg/kg mice (males: 16/50, 15/50, 6/50, 2/50; females: 5/50, 1/50, 0/50, 0/50). Three 30 mg/kg males had hepatocholangiocarcinoma; this incidence was within the NTP historical control range for all routes of administration (range 0%–8%).

The incidences of clear cell foci were significantly decreased in 100 and 300 mg/kg males (24/50, 17/50, 6/50, 1/50) and the incidences of eosinophilic foci were significantly decreased in 300 mg/kg males and 100 and 300 mg/kg females (males: 24/50, 27/50, 22/50, 13/50; females: 23/50, 14/50, 8/50, 3/50; Table C-3 and Table D-3). The incidences of hematopoietic cell proliferation [vehicle control, 2/50 (1.0); 30 mg/kg, 2/50 (1.5); 100 mg/kg, 6/50 (1.2); 300 mg/kg, 10/50 (1.0)] and inflammation [4/50 (1.0), 1/50 (3.0), 5/50, (2.8), 12/50 (1.2)] were significantly increased in 300 mg/kg males. Hematopoietic cell proliferation was composed of multiple small clusters of hematopoietic precursor cells scattered throughout the hepatic parenchyma. The precursor cells were predominantly of granulocytic origin. The hematopoietic cell proliferation seen in the liver was likely similar to the bone marrow hyperplasia and was a response to the continued inflammatory process occurring in the nasal cavities of the mice. Inflammation consisted of a variably mixed infiltrate of neutrophils and macrophages, with or without lymphocytes or plasma cells and was often associated with one or two individual necrotic hepatocytes.

Other Organs: The incidences of adrenal cortical hypertrophy were decreased in 100 and 300 mg/kg males [10/49 (1.4), 8/50 (1.3), 1/50 (2.0), 2/50 (1.5); Table C-3]. The incidence of pancreatic islet hyperplasia was significantly decreased in 300 mg/kg males [22/50 (1.8), 18/50 (1.5), 19/50 (1.4), 1/50 (1.0); Table C-3). Islet cell hyperplasia was characterized by an increase in the size of the pancreatic islets due to an increased number of normal looking islet cells. Affected islets did not compress the adjacent exocrine pancreatic tissue. In general, multiple islets were affected in each animal. Gastrointestinal tract lesions, similar to those observed in the 2-year study in rats, were not observed in mice.

## Genetic Toxicology

Green tea extract (50 to 2,000 µg/plate), from the same lot that was tested in the 3-month and 2-year studies, was mutagenic in Salmonella typhimurium strains TA98 and TA100 in the presence of induced rat liver S9; no mutagenicity was observed in these strains without S9, or in the Escherichia coli strain WP2 uvrA/pKM101 (10 to 1,000 µg/plate), with or without S9 (Table E-1).

In vivo, no increases in the frequencies of micronucleated normochromatic erythrocytes were seen in peripheral blood of male or female B6C3F1/N mice administered green tea extract (62.5 to 1,000 mg/kg per day) for 3 months by gavage; no significant changes were observed in the percentage of polychromatic erythrocytes among total erythrocytes in the blood of either males or females, suggesting that green tea extract did not induce bone marrow toxicity (Table E-2).

Figure 10

Macroscopic Aspect of the Mucosa in the Duodenum of a Male Wistar Han Rat Administered 1,000 mg/kg Green Tea Extract by Gavage for Two Years

Note the black discoloration.

Figure 11

Necrosis of the Mucosa in the Duodenum of a Male Wistar Han Rat Administered 1,000 mg/kg Green Tea Extract by Gavage for Two Years (H&E)

Note the hypereosinophilic aspect (arrows) of the epithelial cells located at the tips of villi or for variable lengths along the villi. The hypereosinophilic aspect is due to pyknotic necrosis of the cells associated with the presence of fibrin thrombi within the lamina propria.

Figure 12

Suppurative Inflammation (Arrows) in the Nasopharyngeal Duct of a Male Wistar Han Rat Administered 1,000 mg/kg Green Tea Extract by Gavage for Two Years (H&E)

Figure 13

Increased Bony Deposition (Hyperostosis) and Deformity in the Nasal Turbinate of a Male Wistar Han Rat Administered 1,000 mg/kg Green Tea Extract by Gavage for Two Years (H&E)

Note the thickening of the nasal turbinates (small arrows) with occasional fusion of turbinates to each other (large arrows).

Figure 14

Section of the Nose, Level III, from a Female B6C3F1/N Mouse Administered 300 mg/kg Green Tea Extract by Gavage for Two Years (H&E)

Note the suppurative inflammation within the lumen (arrows). The inflammation also involved the underlying mucosa.

Figure 15

Section of the Nose, Level II, from a Female B6C3F1/N Mouse Administered 300 mg/kg Green Tea Extract by Gavage for Two Years (H&E)

Note the greenish brown material within the lumen (arrow), thought to be the test compound.

Figure 16

Section of the Nose, Level III, from a Vehicle Control Male B6C3F1/N Mouse in the Two-ear Gavage Study of Green Tea Extract (H&E)

Figure 17

Section of the Nose, Level III, from a Male B6C3F1/N Mouse Administered 100 mg/kg Green Tea Extract by Gavage for Two Years (H&E)

Note the blunted atrophic turbinates (arrows) compared to the normal turbinates in Figure 16.