# Materials and Methods

## Procurement and Characterization of Green Tea Extract

Prior to selecting the test article, NTP investigated the composition of four lots of green tea extract from three suppliers. The total catechins determined in the four lots ranged from 62.7% to 83.5% and were in agreement with the total catechin polyphenols reported by the suppliers (72.3% to 83.7%). The epigallocatechin gallate (EGCG) in three of the four lots ranged from 44% to 51%, while in the fourth lot it was 15%. The lot selected for testing was based upon concentration of EGCG, similarity to other products examined by NTP, and availability in bulk quantity.

Green tea extract (ethanol:water extraction of the leaf) was obtained from Amax NutraSource, Inc. (Eugene, OR), in one lot (GTE50-A0302031114) that was used in the 3-month and 2-year studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle Columbus Operations (Columbus, OH) and by the study laboratory at Battelle Columbus Operations (Appendix I). Reports on analyses performed in support of the green tea extract studies are on file at the National Institute of Environmental Health Sciences.

Lot GTE50-A0302031114 of the chemical, a light-brown powder, was identified as green tea extract using infrared spectroscopy. The moisture content of lot GTE50-A0302031114 was determined using weight loss on drying and by Karl Fischer titration. The purity of the test article was determined using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection. Components of the purity profile were identified by comparing the retention times from a chromatogram of lot GTE50-A0302031114 to a chromatogram of a solution containing nine potential green tea extract components; these components were quantified by standard addition using authentic standards. HPLC with mass spectrometry (MS) detection was used to confirm the identity of these components.

For lot GTE50-A0302031114, weight loss on drying conducted at two laboratories indicated 4.77% and 5.8% water. Karl Fischer titration conducted at one laboratory indicated 6% to 11.6% water and similar analyses conducted at a second laboratory indicated 3% to 4% water; the latter values were consistent with the 3.32% water indicated in the manufacturer’s Certificate of Analysis. HPLC/UV indicated eight components with areas greater than or equal to 1% of the total peak area. Six of these peaks were tentatively identified by matching retention times as epicatechin, catechin gallate, caffeine, epigallocatechin gallate, gallocatechin gallate, and epicatechin gallate. The total area of the major polyphenol peaks represented approximately 84.8% of the total peak area; caffeine constituted 12.27% of the total area, and the remainder was two unidentified components. Nine components of the test article HPLC purity profile, including some below 1%, were identified and quantified by standard addition using the same chromatography system; these components were gallocatechin, epigallocatechin, catechin, epicatechin, catechin gallate, caffeine, epigallocatechin gallate, gallocatechin gallate, and epicatechin gallate. HPLC/MS confirmed the identity of eight of the nine components; epigallocatechin was not identified due to the concentration being below the detection limit in the test article sample. The weight percentage contents of EGCG, epicatechin gallate, epigallocatechin, epicatechin, and caffeine were determined to be 48.4%, 12.8%, 2.26%, 2.83%, and 4.99%, respectively (Table 1); these values were comparable to those listed in the manufacturer’s Certificate of Analysis (53.11%, 13.7%, 2.88%, 3.97%, and 5.42%, respectively). Other catechin polyphenols that were quantified included gallocatechin, catechin, catechin gallate, and gallocatechin gallate, and the weight percentage contents were determined to be 0.52%, 0.51%, 0.45%, and 4.6%, respectively. Taken together, these data indicate that lot GTE50-A0302031114 of the test material was green tea extract.

Table 1 Percent by Weight of Various Components Measured in Green Tea Preparations

Class Identified Chemical Components | NIST Standard Reference Material (3255)^a^ (%) | NTP Test Article (% gram of extract)^b^ | Henning et al. (2003)^c^ | Manning and Roberts (2003)^d^ | Seeram et al. (2006)^e^ | Cabrera et al. (2003)^f^
Catechin polyphenols
Epigallocatechin gallate (EGCG) | 42.2 | 48.4 | 28.5 | 1.08–8.80 | 3.80–44.4 | 7.3–10.4
Epicatechin gallate (ECG) | 10.0 | 12.8 | 7.20 | 0.48–3.93 | 1.10–18.6 | 0.8–2.1
Epigallocatechin (EGC) | 8.18 | 2.26 | 2.17 | 1.42–6.80 | 0.50–9.00 | 2.4–4.5
Epicatechin (EC) | 4.7 | 2.83 | 1.97 | 0.13–1.37 | 0.80–5.60 | 0.8–2.1
Gallocatechin (GC) | 2.2 | 0.52 | NA | NA | NA | NA
Catechin (C) | 0.9 | 0.51 | 1.34 | 0.04–0.50 | NA | NA
Gallocatechin gallate (GCG) | 3.9 | 4.6 | 15.1 | 0.08–1.09 | NA | NA
Methylxanthines
Caffeine | 3.7 | 4.9 | 1.63 | 1.28–4.05 | 1.10–17.4 | 2.6–3.8
Theobromine | 0.08 | NM | NA | NA | NA | NA
Theophylline | 0.008 | NM | NA | NA | NA | NA
Polyphenol
Gallic acid | 0.32 | NM | 2.74 | NA | NA | 0.0–0.2
Amino acid
Theanine | 0.03 | NM | NA | NA | NA | NA

NA = not available, NM = not measured.

^a^ Sander et al.^95^

^b^ Values are from products containing green tea extract alone.^6,96^

^c^ Henning et al.^97^ evaluated one green tea extract preparation, data originally expressed as mg per g powder.

^d^ Manning and Roberts^6^ evaluated four green tea encapsulated extracts, data originally expressed as mg per g of capsule.

^e^ Seeram et al.^96^ evaluated various supplements, dietary supplements with only green tea botanicals provided here (% by tablet weight as reported).

^f^ Cabrera et al.^98^ evaluated six green tea leaf preparations, data originally expressed as mg per g of tea leaf.

Stability studies of the bulk chemical were performed by the analytical chemistry laboratory using HPLC/UV. These studies indicated that green tea extract was stable as a bulk chemical for at least 14 days when stored in sealed amber glass containers at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature in sealed amber glass containers.

Periodic reanalyses of the bulk chemical were performed by the study laboratory during the 3-month and 2-year studies using HPLC/UV, and no degradation of the bulk chemical was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing green tea extract with deionized water to give the required concentrations (Table I-2). The dose formulations were stored at room temperature in sealed clear glass bottles, enclosed in amber plastic bags for up to 8 (3-month studies) or 22 (2-year studies) days.

The analytical chemistry laboratory performed a gavageability study of the 200 mg/mL dose formulation using a 25-gauge needle and stability studies of the 6.25 mg/mL dose formulation using HPLC/UV. Gavageability was confirmed and stability was confirmed for at least 42 days for dose formulations stored in sealed amber glass bottles at room temperature and for at least 3 hours under simulated animal room conditions.

The study laboratory performed gavageability studies of the 100 and 200 mg/mL dose formulations using 20- and 18-gauge ball-tipped, stainless steel needles, respectively; in addition, homogeneity studies of the 6.25, 12.5, 100, and 200 mg/mL dose formulations and stability studies of the 6.25, 25, and 200 mg/mL dose formulations were performed using HPLC/UV. Gavageability and homogeneity were confirmed. Stability was confirmed for at least 22 days for dose formulations prepared with sterile water, bottles, caps, and stir bars; formulations were stored at room temperature in clear bottles, but the bottles were placed in amber plastic bags to protect them from light.

Periodic analyses of the dose formulations of green tea extract by measuring EGCG concentrations were conducted by the study laboratory using HPLC/UV. During the 3-month studies, the dose formulations were analyzed three times; all 18 dose formulations were within 10% of the target concentrations (Table I-3). Animal room samples of these dose formulations were also analyzed; all 15 for rats and 14 of 15 for mice were within 10% of the target concentrations. During the 2-year studies, the dose formulations were analyzed approximately every two to three months; animal room samples were also analyzed (Table I-4). Of the dose formulations analyzed, all 63 for rats and all 33 for mice were within 10% of the target concentrations; all 12 animal room samples for rats and 12 of 13 for mice were within 10% of the target concentrations.

### Animal Source

Male and female F344/NTac rats were obtained from the commercial colony at Taconic Farms, Inc. (Germantown, NY). B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc., for the 3-month studies. Male and female Wistar Han [Crl:WI(Han)] rats were obtained from Charles River Laboratories (Raleigh, NC) and male and female B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc., for use in the 2-year studies. The rationale for change of rat strain from F344/N to F344/NTac was a programmatic decision. For many years NTP used the inbred F344/N rat for its toxicity and carcinogenicity studies. Over a period of time, the F344/N rat exhibited sporadic seizures and idiopathic chylothorax and consistently high rates of mononuclear cell leukemia and testicular neoplasia. Because of these issues in the F344/N rat and NTP’s desire to find a more fecund rat model that could be used in both reproductive and carcinogenesis studies for comparative purposes, a change in the rat model was explored. Following a workshop in 2005, the F344 rat from the Taconic commercial colony (F344/NTac) was used for a few NTP studies to allow NTP time to evaluate different rat models between 2005 and 2006.^99^ The Wistar Han rat, an outbred rat stock, was then selected because it was projected to have a long lifespan, resistance to disease, large litter size, and low neonatal mortality.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to green tea extract and to determine the appropriate doses to be used in the 2-year studies.

On receipt, the rats were 3 to 4 weeks old and the mice were 4 to 5 weeks old. Animals were quarantined for 11 or 12 (rats) or 13 or 14 (mice) days; the rats were 5 to 6 weeks old and the mice were 6 to 7 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix K). All tests results were negative.

Initial doses for the current studies were selected based on a 3-month study in Harlan Sprague-Dawley rats conducted by the National Cancer Institute (NCI). The abstract from that study described increased treatment-related deaths in the high dose group (1,000 mg/kg) administered green tea polyphenols. For the current study, 1,000 mg/kg was chosen as the top dose because it was not known if F344/NTac rats and B6C3F1/N mice were more or less sensitive to green tea extract administration. Also, the green tea extract used in the NCI study was different than that used by NTP for the current study. Hence, there was a possibility of substantial variability in the content of catechin polyphenols in the two extracts and the expected biological response to the two extracts.

Groups of 10 male and 10 female core study rats and mice were administered 0, 62.5, 125, 250, 500, or 1,000 mg green tea extract/kg body weight, in deionized water by gavage 5 days per week for 14 weeks. Vehicle control animals were administered the deionized water vehicle alone; dosing volumes were 5 mL/kg for rats and 10 mL/kg for mice. Groups of 10 male and 10 female clinical pathology study rats were administered the same doses by gavage for 23 days. Feed and water were available ad libitum. Rats and mice were housed individually (male mice) or five per cage. Clinical findings and body weights were recorded initially, weekly, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 2.

Table 2 Experimental Design and Materials and Methods in the Gavage Studies of Green Tea Extract

Three-month Studies | Two-year Studies
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)
Strain and Species
F344/NTac rats B6C3F1/N mice | Wistar Han [Crl:WI(Han)] rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Rats: Charles River Laboratories (Raleigh, NC)
| Mice: Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 11 (males) or 12 (females) days Mice: 13 (females) or 14 (males) days | Rats: 16 (males) or 17 (females) days Mice: 11 (females) or 12 (males) days
Average Age When Studies Began
Rats: 5 to 6 weeks | Rats: 6 to 7 weeks
Mice: 6 to 7 weeks | Mice: 5 to 6 weeks
Date of First Dose
Rats: April 17, 2006 (males) April 18, 2006 (females) Mice: April 19, 2006 (females) April 20, 2006 (males) | Rats: July 18, 2007 (males) July 19, 2007 (females) Mice: July 9, 2007 (females) July 10, 2007 (males)
Duration of Dosing
5 days/week for 14 weeks | 5 days/week for 104 (male rats) or 105 weeks
Date of Last Dose
Rats: July 17, 2006 (core males) July 18, 2006 (core females) May 9, 2006 (clinical pathology study males) May 10, 2006 (clinical pathology study females) Mice: July 19, 2006 (females) July 20, 2006 (males) | Rats: October 16, 2007 (interim evaluation males) October 17, 2007 (interim evaluation females) July 14, 2009 (core study males) July 16, 2009 (core study females) Mice: July 7, 2009 (females) July 9, 2009 (males)
Necropsy Dates
Rats: July 18, 2006 (males) July 19, 2006 (females) Mice: July 20, 2006 (females) July 21, 2006 (males) | Rats: October 17, 2007 (interim evaluation males) October 18, 2007 (interim evaluation females) July 13-15, 2009 (core males) July 16-17, 2009 (core females) Mice: July 6-8, 2009 (females) July 8-10, 2009 (males)
Average Age at Necropsy
Rats: 18 to 19 weeks Mice: 19 to 20 weeks | Rats: 19 to 20 weeks (interim evaluation) 110 to 111 weeks (core study) Mice: 109 to 111 weeks
Size of Study Groups
10 males and 10 females | Core study rats and mice: 50 males and 50 females Interim evaluation rats: 10 males and 10 females (0 and 1,000 mg/kg)
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 3-month studies
Animals per Cage
Rats: 5 Mice: 1 (males) or 5 (females) | Rats: 3 (males) or 5 (females) Mice: 1 (males) or 5 (females)
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 wafer diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least weekly | Same as 3-month studies
Water
Tap water (Columbus municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as 3-month studies
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed once weekly (male mice) or twice weekly | Same as 3-month studies
Bedding
Irradiated Sani-Chips^®^ hardwood chips (P.J. Murphy Forest Products Corp., Montville, NJ), changed once weekly (male mice) or twice weekly | Same as 3-month studies
Rack Filters
Spun bonded polyester (Snow Filtration Co., Cincinnati, OH), changed every 2 weeks | Same as 3-month studies
Racks
Stainless steel drawer type (Lab Products, Inc., Seaford, DE), changed and sanitized every 2 weeks | Same as 3-month studies
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as 3-month studies
Doses
0, 62.5, 125, 250, 500, or 1,000 mg/kg in sterile water [dosing volume 5 mL/kg (rats) or 10 mL/kg (mice)] | Rats: 0, 100, 300, or 1,000 mg/kg in sterile water (dosing volume 5 mL/kg) Mice: 0, 30, 100, or 300 mg/kg in sterile water (dosing volume 10 mL/kg)
Type and Frequency of Observation
Observed twice daily; core study animals were weighed and clinical findings were recorded initially, weekly thereafter, and at the end of the studies. | Observed twice daily; animals were weighed initially, weekly for 13 weeks, monthly thereafter, and at terminal kill; clinical findings for core study animals were recorded week 5, monthly thereafter, and at the end of the studies.
Method of Kill
Carbon dioxide asphyxiation | Same as 3-month studies
Necropsy
Necropsies were performed on all core study rats and mice. Organs weighed were heart, right kidney, liver, lung, spleen, right testis, and thymus. | Necropsies were performed on all rats and mice. The heart, right kidney, liver, lung, right testis, and thymus of interim evaluation rats were weighed.
Clinical Pathology
Blood was collected from the retroorbital plexus of clinical pathology study rats on days 4 and 23 and from the retroorbital plexus (rats) or sinus (mice) of core study rats and mice at the end of the studies for hematology and clinical chemistry (rats only). Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile salts. | None
Histopathology
Complete histopathology was performed on all core study vehicle control rats and mice, 1,000 mg/kg rats and mice, and 500 mg/kg male mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. In addition, the heart (mice), liver, lymph nodes, nose, spleen (mice), and thymus were examined to a no-effect level in the remaining groups. | Complete histopathology was performed on all rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus.
Sperm Motility and Vaginal Cytology
At the end of the studies, spermatid and sperm samples were collected from male rats in the 0, 250, 500, and 1,000 mg/kg groups and male mice in the 0, 125, 250, and 500 mg/kg groups. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 16 consecutive days prior to the end of the studies from female rats in the 0, 250, 500, and 1,000 mg/kg groups and female mice in the 0, 125, 250, and 500 mg/kg groups. The proportion of regularly cycling females, estrous cycle length, and probability of extended or skipped estrous cycle stages were evaluated. | None

Blood was collected from the retroorbital plexus of clinical pathology study male and female rats on days 4 and 23 and from the retroorbital plexus (rats) or sinus (mice) of all core study rats and mice at the end of the 3-month studies for hematology and clinical chemistry (rats only) analyses. Animals were anesthetized with a carbon dioxide/oxygen mixture and bled in a random order. Blood was collected into tubes containing EDTA for hematology or into serum separator tubes for clinical chemistry. Hematology parameters were analyzed using the Advia 120 (Bayer Diagnostics Division, Tarrytown, NY). Clinical chemistry parameters were analyzed using the Hitachi 911 (Roche, Indianapolis, IN). The parameters measured are listed in Table 2.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats in the 0, 250, 500, and 1,000 mg/kg groups and mice in the 0, 125, 250, and 500 mg/kg groups. The parameters evaluated are listed in Table 2. For 16 consecutive days prior to scheduled terminal kill, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study animals. The heart, right kidney, liver, lung, spleen, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. In addition, special stains (Schmorl’s, PAS, Hall’s Bile, and Prussian Blue) were used to determine the type of pigment that occurred in Kupffer cells in the liver of female rats and in histiocytes in the nose of male and female rats. Complete histopathologic examinations were performed by the study laboratory pathologist on all vehicle control and 1,000 mg/kg rats and mice and 500 mg/kg male mice; the heart (mice), liver, lymph nodes, nose, spleen (mice), and thymus were examined to a no-effect level in the remaining groups. Table 2 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^100^ and Boorman et al.^101^

## Two-year Studies

### Study Design

Groups of 60 male and 60 female rats were administered 0 or 1,000 mg green tea extract/kg body weight and groups of 50 male and 50 female rats were administered 100 or 300 mg/kg in deionized water by gavage, 5 days per week for up to 105 weeks. Groups of 50 male and 50 female mice were administered 0, 30, 100, or 300 mg/kg for 105 weeks. Vehicle control animals were administered the sterile water vehicle alone. Ten male and 10 female rats randomly selected from the vehicle control and 1,000 mg/kg groups were evaluated at 3 months to compare the results to the 3-month study in F344/NTac rats. Dosing volumes were 5 mL/kg for rats and 10 mL/kg for mice.

Rats and mice were quarantined for 16 or 17 (rats) or 11 or 12 (mice) days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats were 6 to 7 weeks old and mice 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix K). All test results were negative.

Rats were housed three (males) or five (core study and interim evaluation females) per cage and mice were housed individually (males) or five (females) per cage. Feed and water were available ad libitum. Further details of animal maintenance are given in Table 2. Information on feed composition and contaminants is provided in Appendix J.

### Clinical Examinations and Pathology

All animals were observed twice daily. Body weights of rats and mice were recorded on study day 1, weekly for the first 13 weeks, every 4 weeks thereafter, and at terminal kill. Clinical findings for core study animals were recorded during study week 5, every 4 weeks thereafter, and at study termination.

Complete necropsies and microscopic examinations were performed on all rats and mice. At the 3-month interim evaluation in rats, the heart, right kidney, liver, lung, right testis, and thymus were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin [except, initially, eyes were placed in Davidson’s solution and testes (including the epididymides and vaginal tunics) were placed in modified Davidson’s solution], processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. The nasal cavity was sectioned into three levels as described by Boorman et al.^102^ Briefly, Level I is taken at the level of the incisor teeth; Level II is taken midway between the incisors and the first molar; and Level III is taken at the middle of the second molar (between the incisive papilla and the first palatal ridge). Level I is the most rostral level; Level III the most posterior. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 2.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. During the audit of pathology specimens, the pathologist noted potential lesions in the forestomach, glandular stomach, and small intestine (duodenum, jejunum, and ileum) that had not been previously recorded; therefore a special review was conducted of the wet tissue of the gastrointestinal tract of all rats (including the interim evaluation animals) and mice in the 2-year studies. For the 2-year studies, a quality assessment pathologist evaluated slides from all tumors and all potential target organs, which included the bone, liver, lung, and nose of rats and mice; the heart of rats and male mice; the adrenal cortex, small intestine, kidney, glandular stomach, forestomach, and small intestine of rats; the bone marrow, Harderian gland, and mandibular lymph node of mice; and the pancreas of male mice.

The quality assessment report and the reviewed slides were submitted to the NTP PWG coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^100^ and Boorman et al.^102^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^103^

In a subsequent, separate evaluation, a complete longitudinal evaluation was done for the residual uterine tissue of rats in the 2-year study. Slides were made of the additional uterine sections and reviewed by a quality assessment pathologist, who also served as the PWG coordinator for these sections.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^104^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^105^ method for testing two groups for equality and Tarone’s^106^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

#### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-3, Table B-1, Table B-3, Table C-1, Table C-3, Table D-1, and Table D-3 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal kill.

#### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^107-109^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal kill; if the animal died prior to terminal kill and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^107^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^107^ following an evaluation of neoplasm onset time distributions for a variety of site- specific neoplasms in control F344/NTac rats and B6C3F1/N mice.^110^ Bailer and Portier^107^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^111^

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1−P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N). For neoplasms and nonneoplastic lesions detected at the interim evaluation, the Fisher exact test,^112^ a procedure based on the overall proportion of affected animals, was used.

#### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^113^ and Williams.^114,115^ Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^116^ (as modified by Williams^117^) and Dunn.^118^ Jonckheere’s test^119^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^120^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the control group using the Fisher exact test.^112^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^121^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics.

#### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period.^122,123^ In general, the historical database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the current mouse study. The current study is the only study in Wistar Han rats using water as a gavage vehicle in the historical control database; therefore, only historical control incidences for all routes and all vehicles are used for Wistar Han rats in this Technical Report.

## Quality Assurance Methods

The 3-month and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^124^ In addition, as records from the 3-month and 2-year studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of green tea extract was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli and increases in the frequency of micronucleated erythrocytes in mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^125,126^ The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^127^ and the somatic mutation theory of cancer.^128,129^ However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^130^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^131,132^ Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test.^133,134^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^135^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.