# Introduction

Figure 1

Green Tea (CASRN None Available)

Synonyms: Green tea catechin polyphenols; green tea; green tea polyphenols.

Botanical name: Camellia sinensis.

## Chemical and Physical Properties

Green tea extract is obtained from leaves of the plant Camellia sinensis, of the Theaceae family. C. sinensis is indigenous to regions of China, India, and other Southeast Asian countries; however, it is now commercially cultivated in more than 30 countries around the world.^1^

The constituents of C. sinensis leaves include a complex mixture of polyphenolic compounds (30% to 35%), methylxanthines such as caffeine and theobromine (2.5% to 4.0%), proteins (15% to 20%), amino acids (1% to 4%), carbohydrates (5% to 7%), and lipid components (2%); organic acids (1.5%), ash (5%), minerals and trace elements (10% to 15%); and pigments such as chlorophyll (0.5%).^2^ Among the polyphenolic compounds, flavonoids are the most abundant (80% to 90%). The largest proportion of flavonoids are catechin polyphenols (condensed tannins), which make up 30% to 40% of green tea solids. Catechin polyphenol content depends on the maturity and the processing of the C. sinensis leaves during preparation of tea. The catechin polyphenol composition of the leaves also varies with geographic location, season, and cultivation procedures.^3^ Catechin polyphenols are colorless, water-soluble compounds and are very stable in acidic solutions (pH less than 4). However, their solubility progressively decreases as the pH is increased from 4 to 8. A typical tea beverage, prepared in a proportion of 1 g leaf/100 mL water in a 3-minute brew, usually contains from 250 to 300 mg tea solids, composed of 30% to 42% catechins and 3% to 6% caffeine.^2^

Four major catechins present in green tea extract are epigallocatechin-3-gallate (EGCG), (−)-epigallocatechin (EGC), (–)-epicatechin-3-gallate (ECG), and (–)-epicatechin (EC)^2,3^ (Figure 2). EGCG is the most abundant catechin in green tea. Smaller quantities of other catechin polyphenols such as catechin, gallocatechin, epigallocatechin digallate, epicatechindigallate, 3-omethyl EC and EGC, catechin gallate, and gallocatechin gallate are also present in green tea extract.

Figure 2

Structures of Major Catechins in Green Tea Extract

## Production, Use, and Human Exposure

C. sinensis leaves are commonly used for different kinds of tea, such as green tea, oolong tea, and black tea, and the variations in processing these leaves determine the different types of tea produced.^3^ Green tea extract used in dietary supplements differs from the common green tea drink in extraction method and the supplements can have a higher concentration of C. sinensis components than the traditional tea beverage.

Preparation of green tea extract involves steaming of fresh green leaves at high temperatures. This step inactivates the main oxidizing enzyme, polyphenol oxidase, in the C. sinensis leaves and preserves the natural chemistry of the catechins during processing.^3^ Due to growing commercial interest, the physical and chemical properties of green tea catechins have been extensively studied and, based on the findings, the extraction procedures have been modified and refined. Some of the methods used for extraction of individual catechin polyphenols or a mixture of catechin polyphenols include cold or hot water extraction, organic solvent extraction, microwave-assisted extraction, subcritical water extraction, ultrasound-assisted extraction, and ultra high-pressure extraction.^4,5^ Following extraction, the catechin polyphenols are concentrated to remove extraction solvents. After removal of insoluble material by filtration, the tea infusion with soluble solvents is further concentrated using either a stream of inert gas, a rotary evaporator, a vacuum centrifuge, a vacuum dryer with or without heat, or a freeze dryer to obtain crude green tea extracts in powder form. Although challenging, individual catechin polyphenols (e.g., EGCG, EGC, EC) have also been separated and purified using various methods such as caffeine precipitation, solid-phase extraction, column chromatography, and supercritical fluid extraction.^5^ Typically, most green tea extract products are characterized based on the catechin polyphenol content, specifically EGCG, which is thought to be primarily responsible for its pharmacologic activity. In general, catechin polyphenol concentration varies widely among different commercial green tea extract preparations.^6,7^

A United States Pharmacopoeia review lists green tea extract as the fourth most commonly used herbal supplement.^7^ Also, an analysis of 2012 United States herbal supplement sales revealed green tea extract to be among the top 20 single and combination dietary supplements.^8^ Green tea extracts are consumed as weight loss and dietary supplements and are used as ingredients in sunblocks, cream rinses, and other cosmetics.^4,7^ In 2006, a topical ointment (Veregen™) containing 15% green tea catechin polyphenols was granted market authorization by the FDA for treatment of genital warts. In addition, many studies have investigated potential therapeutic effects of green tea extracts in chemoprevention against various cancers, hypercholesterolemia, atherosclerosis, diabetes, and neurodegenerative and cardiovascular diseases.^9-11^ Overall, these studies provide inconsistent evidence on the role of green tea extract in treatment of various diseases and chemoprevention in humans. However, high doses of green tea extract have been shown to be effective in mitigating cancer progression in a few early stage clinical trials. For example, in one clinical trial where 2,000 mg of green tea extract (Polyphenon^®^ E) was administered to cancer patients twice daily for 6 months,^12^ positive responses were reported in the majority of patients. Other clinical trials examined the effects of green tea extracts on diabetes or cancer with doses ranging from 379 to 2,000 mg administered to participants one or more times daily for 1 to 4 months.^13-17^ Nevertheless, very few human studies have been conducted to evaluate long-term safety of green tea extract consumption at high doses.

## Regulatory Status

In the United States, dietary supplements such as green tea extract are regulated under the Dietary Supplement Health and Education Act of 1994. Natural extractives, including distillates, of tea are Generally Recognized as Safe Substances.^18^ In 2006, the FDA approved a topical ointment (Veregen™) containing 15% green tea catechin polyphenols as the active ingredient for treatment of genital warts in immunocompetent patients 18 years or older.^19^

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

### Experimental Animals

Numerous studies have investigated the absorption, distribution, metabolism, and excretion of green tea extract and individual catechin polyphenols, especially EGCG, in experimental animals. Following gavage administration of 200 mg/kg decaffeinated green tea extract in rats, the peak plasma concentrations (C_max_) of three major catechin polyphenols (EGCG, EGC, and EC) were reached 1 to 2 hours after administration.^20,21^ The C_max_ of EGCG (16.3 ng/mL) was lower than that of EGC (1,432.8 ng/mL) or EC (685.4 ng/mL); the absolute bioavailabilities were low at 0.1%, 13.7%, and 31.2% for EGCG, ECG, and EC, respectively. When administered alone to rats, EGCG displayed a 3.6-fold higher absorption rate and a higher bioavailability (1.6%) than as a component in green tea extract. Absorption of EGCG was also rapid in mice with a bioavailability of 26% following gavage administration of 75 mg/kg EGCG.^22^ In general, the low bioavailability of catechin polyphenols has been attributed to several factors such as catechin instability to digestive conditions,^23,24^ transporter-mediated intestinal efflux,^25^ and rapid metabolism and excretion.^26^

Catechin polyphenols were distributed to tissues of rats and mice following gavage or intravenous administration of green tea extract.^20,27^ Higher levels of EGCG, EGC, and EC were reported in the intestine, kidney, and lung.^27^ Furthermore, studies in Sprague-Dawley rats have demonstrated that EGCG and other green tea catechins can cross the blood-brain and placental barriers.^28-30^ In fasting pregnant Sprague-Dawley rats following gavage administration of 166 mg green tea extract (50% EGCG), maternal plasma concentrations of catechins were about 10 times higher than in the placenta and 50 to 100 times higher than in the fetus.^28^ EGCG concentration was higher than the other catechins in maternal plasma and the fetus. Catechin polyphenols were detected in various fetal organs such as brain, eyes, heart, lung, kidney, and liver.^31^

The plasma elimination half-lives of catechin polyphenols following gavage administration of green tea extract in rats were 212 minutes, 45 minutes, and 41 minutes for EGCG, EGC, and EC, respectively.^21^ When EGCG was administered alone, the half-life was shorter (135 minutes), suggesting that other components in green tea extract could affect the disposition of EGCG. The green tea catechin polyphenols were excreted mainly via feces in rodents with over 80% of the total excreta observed in feces within 24 hours.^20,22^ EGCG is mainly excreted in free form in feces, whereas in urine, greater than 90% of the EGCG was detected in conjugated forms.^22^

Similar observations were noted in Sprague Dawley rats administered green tea polyphenols in drinking water; free EGCG was the major catechin found in feces, while EGC and EC were mainly excreted in urine as conjugated forms.^27^

In beagle dogs, the elimination half-life of EGCG was 8.6 hours following oral administration of 250 mg/kg of EGCG with an estimated absolute bioavailability of 20%.^32^ As observed in rodents, the excretion was predominantly via feces. To mimic chronic consumption, 250 mg/kg of EGCG was administered orally in beagle dogs for 27 days and a 25 mg/kg intravenous dose of [3H]-EGCG was given 1 hour prior to terminal kill.^32^ [3H]-EGCG was detected in the tissues including liver (17.47%), small intestine (5.12%), lung (1.16%), and stomach (1.07%). It was also noted that a repeated oral administration resulted in significantly lower blood radioactivity levels compared to a single administration. Repeated administration of green tea extracts to fasted dogs resulted in a two to fourfold increase in the area-under-the-curve (AUC) for catechin polyphenols compared to the fed animals.^33^

There is extensive literature on the metabolism of green tea catechin polyphenols both in vitro and in vivo. Phase I metabolism has not been shown to play a major role in the metabolism of green tea catechin polyphenols. However, tea catechin polyphenols undergo significant Phase II metabolism in the liver and intestine to form numerous glucuronidation, sulfation, methylation, and, to some degree, ring fission products.^22,34^ Figure 3 shows the metabolism of the major catechin polyphenol (EGCG) in green tea extract. In rodents and rabbits, other pathways such as glucosidation and thiol conjugation have also been identified.^35,36^ A cysteine conjugate of EGCG has been detected in the urine of rodents following gavage administration of EGCG and was hypothesized to arise as a result of oxidation of EGCG to a quinone metabolite and subsequent reaction with the sulfhydryl group of glutathione. Metabolic degradation of the catechin polyphenols also occurs in the large intestine.^36,37^ In vitro, EGCG-4′-O-glucuronide was identified as the major EGCG metabolite in human, mouse, and rat liver microsomes and homogenates.^38-41^ Sulfates of EC and EGCG have been identified in rat liver homogenates.^42^

Figure 3

Metabolism of Major Catechins in Green Tea Extract

Adapted from Feng.^34^

EGCG = epigallocatechin gallate; COMT = catechol-O-methyltransferase; SULT = sulfotransferase; UDPGT = uridine diphosphate glucuronosyltransferase.

Studies on the effect of tea catechin polyphenols on expression of drug transporters and metabolizing enzymes have indicated the inhibition of P-glycoprotein and breast cancer resistance protein activity by EGCG.^43-45^ Tea catechin polyphenols have been shown to cause induction of the catalytic activities of CYP1A1, 1A2, 2B, and 3A in both rats and mice, but the results are inconsistent among different studies. Owing to interactions at different stages of metabolism, green tea extract has been reported to affect bioavailability of many drugs such as sunitinib, midazolam, tamoxifen, and verapamil in rats and mice.^46-48^

### Humans

Pharmacokinetic properties of green tea extract and its catechin polyphenols have been well studied in humans. Orally administered green tea extract and its individual catechins are rapidly absorbed and C_max_ was reached between 1.5 and 2.5 hours in almost all the subjects in various clinical trials.^26,49,50^ When subjects were administered 664 mg ECG, 459 mg EGC, or 688 mg EGCG, the C_max_ was 3.1, 1.3, or 5.0 μM, respectively.^51^ When healthy volunteers were orally administered 50, 100, 200, 400, 800, or 1,600 mg EGCG after overnight fasting, the half-life of elimination (t_1/2_) was between 1.9 and 4.8 hours.^50^ Another study investigated the influence of food intake on the absorption of catechin polyphenols in healthy volunteers following ingestion of green tea extract containing up to 1,200 mg EGCG with or without breakfast after overnight fasting.^26^ The AUC and C_max_ of EGCG were significantly higher without food than those obtained with food for all three catechins. EGCG was mostly present in the unconjugated form in plasma while EGC and EC were mainly present in the conjugated forms.^26^ Catechin polyphenol metabolism in humans was reported to be similar to that in rodents. Repeated ingestion induced slight accumulation of metabolites. Urinary excretion of catechin polyphenols was low and only 0.1% of ingested EGCG was excreted in urine; more than 90% of the catechins were excreted in feces within 8 hours.^52^ Catechin polyphenols have been reported to inhibit catechol-O-methyltransferase in human liver microsomes.^53^ In vitro studies in human liver microsomes have demonstrated that green tea extract can inhibit CYP2C9, 2D6, and 3A activities.^46^ However, the results are mixed and vary depending on the experimental conditions in the different studies. Catechin polyphenols have been reported to inhibit UGT1A1, 1A4, and SULT activities in human liver microsomes.^54,55^ Taken together, these studies suggest that green tea extract may have modulating effects on the pharmacokinetics of coadministered drugs.

## Toxicity

### Experimental Animals

Acute and subchronic studies on EGCG and green tea extract have been conducted in rats and dogs in accordance with the Organisation for Economic Co-operation and Development (OECD) guidelines.^56^ The oral LD_50_ of EGCG (93.4% pure) in Wistar (Crl:WI) BR rats was determined to be between 200 and 2,000 mg/kg and the dermal LD_50_ of EGCG (93%) in HanBrl:WIST (SPF) rats was found to be greater than 1,860 mg/kg.

In a 13-week study, F344/DuCrJ rats were administered green tea extract (Sunphenon 100S™) containing EGCG (29.4%) in feed at 0.3%, 1.25%, or 5.0%.^57^ Decreased body weights and significant increases in serum markers of liver toxicity such as AST, ALT, and ALP activities were noted in the 5.0% group. Liver weights were also found to be significantly increased in the 5.0% group; however, there were no corresponding histologic findings. An OECD 408 guideline study was conducted in Sprague-Dawley rats that were administered approximately 50, 150, or 500 mg EGCG preparation (77% EGCG)/kg body weight per day in feed^56^ for 13 weeks. There were no treatment-related deaths, signs of systemic toxicity, or organ damage. Lambert et al.^58^ treated CF-1 mice under fasting conditions with an intragastric administration of single or multiple once-daily doses of 500 or 750 mg/kg EGCG for 2 to 7 days. There were dose- and time-dependent decreases in survival. The cause of mortality was found to be hepatotoxicity demonstrated by increases in plasma markers of liver damage (ALT) and histopathologic changes in the liver. Male albino rats administered 1.25%, 2.5%, or 5.0% green tea extract (EGCG 9.0%) orally for 30 days showed decreased body weight gains associated with marked hypertrophy and/or hyperplasia of the thyroid gland follicles in the 2.5% and 5.0% groups.^59^ Significantly decreased thyroid peroxidase and 5-deiodinase I activities, decreased serum T_3_ and T_4_ levels, and corresponding increases in TSH levels were observed in the top two dose groups. A 1-year dietary exposure of male and female Wistar Hannover GALAS rats to a catechin mixture (containing 43.6% EGCG) led to an increase in liver weight relative to body weight and centrilobular hypertrophy in the liver at the high dose of 3% in males, but this effect was not observed in females.^60^

Studies on Teavigo™ (an EGCG preparation with 90% purity) and Polyphenon^®^ E (containing 56% to 72% EGCG) have demonstrated that the presence of food in the stomach is a major factor that influences toxicity of green tea extract. Oral administration of EGCG (80%) in capsules at doses of 50, 150, or 500 mg/kg per day to beagle dogs under fasting conditions led to vomiting, diarrhea, severe systemic toxicity, and mortality.^56^ Histopathologic lesions in the high-dose groups included necrosis in the liver and kidney, lymphoid atrophy of the thymus, and erosion in the stomach. Total bilirubin was significantly increased in the high-dose groups. Liver necrosis was also observed in one female in the 150 mg/kg group. In the follow-up 13-week study, no evidence of systemic toxicity was observed in dogs administered 50, 300, or 500 mg/kg per day of an EGCG preparation (91% pure) 1 hour after feeding.^56^ Similar results have been reported by Kapetanovic et al.^33^ following chronic (9 months) administration of 200, 500, or 1,000 mg/kg per day of a purified and standardized green tea extract (Polyphenon^®^ E) (85% to 90% catechins; 56% to 72% EGCG) under fasting conditions. Significant morbidity and mortality were observed. Dose-related increases in weights of the adrenal gland, liver, testis, ovary, spleen, and thyroid/parathyroid glands, and decreases in thymus weights were noted in fasted dogs treated with Polyphenon^®^ E. Macroscopic examination demonstrated grey plaques and mottled and granular lesions in the GI tract and intestine. Histopathologic lesions were observed in multiple organs such as liver, esophagus, stomach, small intestine, kidney, spleen, and lymph nodes. In a follow-up study, 200 mg/kg Polyphenon^®^ E was administered to dogs with and without food for 13 weeks.^33^ No mortality was observed in any group. However, animals administered Polyphenon^®^ E on an empty stomach exhibited gastrointestinal irritation as evidenced by vomiting and diarrhea. Histopathologic lesions were observed in the liver, spleen, and bone marrow of the treated dogs.

### Humans

A considerable number of case reports and clinical trials provide data on the toxicity of concentrated green tea extract in humans. Many cases of hepatotoxicity have been associated with consumption of high doses of dietary supplements containing green tea extract. In 2003, 13 cases of elevated liver enzymes and hepatotoxicity were associated with consumption of the weight loss supplement Exoliase^®^ in France and Spain.^7^ In 12 of these 13 cases the symptoms resolved following discontinuation of use of Exoliase^®^. However, in one individual (with coadministration of other drugs and alcohol intake), the symptoms did not resolve and the liver damage progressed to liver failure and death. As a consequence, the regulatory authorities of Spain and France suspended marketing authorization for Exoliase^®^. In a review of the literature, Mazzanti et al.^61^ found that 34 cases of hepatitis following consumption of green tea extract were reported from 1998 to 2008. These reports describe cases of 15 patients that consumed green tea extract preparation alone; while the remaining patients had used combination products. Two recent cases of potential green tea extract-induced hepatitis include 81 and 72-year old women who consumed green tea extract (90% EGCG) for 1 month and 3 months, respectively. Clinical manifestation in both cases included vomiting and increases in plasma markers of hepatotoxicity such as ALT, AST, and jaundice. Several adverse event reports have been filed with the FDA describing reactions such as rash, vomiting, diarrhea, tachycardia, cholestatic hepatitis, hepatic failure, increased blood pressure, and myalgia.^7^

A few clinical trials associated green tea extract consumption with moderate to severe gastrointestinal and liver toxicity, while some clinical studies reported that green tea extract had no severe adverse events associated with ingestion by humans.^13,62,63^ Crew et al.^63^ conducted a 6-month dose escalation of Polyphenon^®^ E (0, 400, 600, or 800 mg decaffeinated green tea extract containing EGC, EC, ECG, and 65% EGCG) in women suffering from breast cancer to evaluate long-term safety and optimal dose. The authors reported five dose-limiting toxicities, specifically rectal bleeding, weight gain, indigestion, insomnia, and liver function abnormality.

## Reproductive and Developmental Toxicity

### Experimental Animals

The potential reproductive toxicity of green tea extract has been reported in several studies. Isbrucker et al.^64^ conducted an FDA guideline two-generation reproductive toxicity study in male and female Sprague Dawley rats administered 0, 1,200, 3,600, or 12,000 ppm EGCG (91% pure) (target exposures were 0, 100, 300, or 1,000 mg/kg) in the diet for 10 weeks; the animals were then mated. The 12,000 ppm group exhibited an increase in pup loss and lower growth rates in both generations. Exposure-related findings such as thin, unkempt appearance, cyanosis, and weakness were observed in the pups of high dose animals. A slight but significant decrease in thymus weight was observed in the high dose F_1_ pups, high dose F_2_ male pups, and all exposed groups of F_1_ female pups.

Several studies have investigated the developmental toxicity of green tea extract and its active ingredient EGCG in experimental animals. An OECD 414 guideline developmental toxicity study of EGCG was conducted in time-mated pregnant Sprague-Dawley rats.^64^ Pregnant dams were administered 1,400, 4,200, or 14,000 ppm [target exposures of 100, 300, or 1,000 mg EGCG (91% pure)/kg body weight per day] in the diet from gestation day 6 through 20. No adverse effects of EGCG administration were apparent on embryo-fetal survival, post-implantation losses, or mean live litter size. No exposure-related external, visceral, or skeletal malformations were noted. A study investigating the developmental toxicity of green tea catechins (30% w/w) administered by gastric intubation to Sprague-Dawley rats demonstrated that there were no fetal malformations or developmental variations related to administration of the test article.^65^

Some studies have examined the effects of green tea extracts on cyclophosphamide (CP)-induced teratogenesis. Gavage administration of 100 mg/kg to Sprague-Dawley rats from gestation day 6 through 12 followed by an 11 mg/kg intraperitoneal injection of CP on gestation day 12 resulted in exacerbation of CP-related effects on fetal weights and malformations.^66^ Green tea extract alone was not found to increase external, visceral, or skeletal abnormalities in the fetuses. Based on these observations, the authors suggested that upregulation of CYP2B and down-regulation of CYP3A activities by green tea extract led to an enhanced activation and reduced detoxification of CP, thereby exacerbating its teratogenic effects. Pregnant CD-1 mice were administered 100, 200, 400, or 800 mg/kg per day green tea extract alone or with CP (20 mg/kg; intraperitoneal injection on day 10) from gestation day 6 through 13.^67^ Given alone, green tea extract was found to increase incidences of microblepharia (abnormal development of eyelids). Administration of 800 mg/kg green tea extract per day with CP to pregnant mice increased the incidences and severities of CP-induced effects such as decreased fetal weights and resorptions. In contrast, moderate doses of green tea extract (200 or 400 mg/kg per day) attenuated the teratogenicity of CP as indicated by decreased incidences of digit, limb, and cranial defects.

### Humans

No reports on the reproductive or developmental toxicity of green tea extract in humans were found in the literature.

## Immunotoxicity

### Experimental Animals

The potential immunotoxicity of green tea extract was investigated by conducting OECD guideline dermal sensitization studies in guinea pigs.^56^ Two assays were used; a non-adjuvant method adopted from Beuhler’s test and an adjuvant method, based on OECD 406, the guinea pig maximization test (GPMT). During the induction phase of the non-adjuvant assay, 5%, 10%, or 30% green tea extract (EGCG 80%) preparation was applied to the right flank of female GOHI (SPF) guinea pigs 5 days per week. Daily application of the green tea extract showed dose-dependent increases in erythema and irritation during the induction phase suggesting that green tea extract was a dermal irritant. After 4 weeks of daily application, the animals were challenged with 0%, 1%, 3%, 5%, or 10% EGCG on the left flank. A second challenge was performed 2 weeks later at concentrations of 0%, 0.1%, 0.5%, 1%, 3%, 5%, or 10%. The green tea extract preparation induced significantly increased erythema responses in the animals following the second challenge suggesting dermal sensitization. An EGCG preparation (90% EGCG) was also tested in female Himalayan strain albino guinea pigs in a study based on the OECD 406 guideline guinea pig maximization test.^56^ On the first day of the induction period, animals were administered intradermal injections of a 1:1 mixture of Freund’s complete adjuvant with water, a 0.1% EGCG preparation, or a 1:1 mixture of 0.2% EGCG preparation with Freund’s complete adjuvant. On day 8, an area between the injection sites was treated with 0.5 mL of a 50% EGCG solution and kept semi-occluded for 48 hours. The animals were challenged 22 days after the injection of green tea extract by applying 0.15 mL of 50% EGCG solution. The challenge reactions were assessed after 24 and 48 hours. The results demonstrated that 9 of 10 test animals developed a moderate and confluent erythema, indicative of a sensitization reaction. Other studies in mice have demonstrated that the dermal responses to green tea extract could vary depending on the animal strain used and the treatment conditions. Stratton et al.^68^ conducted a dermal toxicity study in female BALB/c mice and SKH1 hairless mice topically administered 1%, 3%, or 10% EGCG ointment (w/w) daily for 30 days. Erythema and ulceration were noted in 3% and 10% EGCG treated BALB/c mice that were dehaired using a chemical depilatory agent. However, no toxicity was observed in shaved BALB/c mice exposed to 10% EGCG ointment. Similar to the shaved BALB/c mice, the hairless female SKH1 mice did not show any signs of irritation or dermal toxicity following 30 days of once daily treatment with 10% EGCG ointment. The authors concluded that green tea extract ointment was not an irritant in shaved BALB/c and hairless SKH1 mice except when used with a chemical depilatory agent.

Several studies have also reported immunosuppressive effects of green tea extract in mouse models of autoimmune diseases.^69-71^ NOD mice administered 0.2% green tea polyphenols in drinking water for 3 weeks showed significant reductions in serum autoantibody levels, lymphocyte infiltration in submandibular glands, and reduced Sjogren’s syndrome-induced cytotoxicity in the salivary glands compared to control mice.^71^ Green tea polyphenols (0 or 5 g/L) administered in drinking water for 6 weeks have been reported to decrease ex vivo inflammatory cytokine release from colon explants of treated IL-2−/− mice, an animal model of inflammatory bowel disease.^70^ The authors also reported decreases in severities of colitis in treated IL-2−/− mice when evaluated histopathologically. In a collagen-induced mouse model of rheumatoid arthritis, administration of 0.2% green tea polyphenols in drinking water for 12 weeks significantly reduced levels of inflammatory mediators (COX-2, TNF-α, IFN-γ) in the joints and resulted in a greater than 50% reduction of collagen-induced arthritis in the treated mice.^69^

### Humans

Case reports describing green tea extract-induced asthma in tea factory workers have been published in the literature. These studies also describe immediate dermal and respiratory sensitization responses to powdered green tea extract, crude catechins, EGCG, and noncatechin components.^72,73^ Blood samples from eight workers with green tea-induced asthma showed dose-dependent increases in histamine release following incubation with varying concentrations of EGCG.^72^

## Carcinogenicity

### Experimental Animals

Carcinogenicity of a catechin mixture (containing 43.6% EGCG) was evaluated in Wistar Han GALAS rats.^60^ In this study, dietary exposure of the mixture at 0%, 0.2%, 0.3%, 1%, or 3% (0, 8.4, 122.7, 416.4, or 1,265.8 mg/kg per day for male rats and 0, 10.1, 148.4, 476.2, or 1,539.8 mg/kg per day for female rats) was determined to be not carcinogenic at the administered doses. Male F344 rats were coadministered 0.1% or 1.0% green tea extract (EGCG 53.9%) with various carcinogens such as N-methyl-nitrosourea or 1,2-dimethylhydrazine for 36 weeks.^74^ In the liver, the incidences of tumor nodules were not different between the groups. However, in the pre-neoplastic glutathione-S-transferase placental form, positive foci were dose-dependently increased.

### Humans

No epidemiological data or case reports describing the carcinogenicity of green tea extract in humans were found in the literature.

## Genetic Toxicity

Green tea extracts are complex mixtures of compounds, many of which are bioactive. The composition of the extracts varies depending on the variety and brand of green tea, ratio of tea leaves to water, water quality and temperature, steeping time, whether the brewed tea was lyophilized, and method of extraction from lyophilized tea (e.g., water, ethanol, acetone, ether). Extensive testing of green tea extracts as well as EGCG has produced both positive and negative results in a variety of genotoxicity assays. In addition, green tea extracts have been shown to have antimutagenic effects. With regard to in vivo assays, neither green tea extract nor EGCG were shown to be genotoxic.

In bacterial mutagenicity assays, green tea extract was mutagenic in the absence of exogenous metabolic activation enzymes (S9) in Salmonella typhimurium strain TA100 at a lowest effective dose (LED) of 16 mg/plate^75^ and in an infrequently used tester strain, S. typhimurium BA13 (detects forward mutations via resistance to L-arabinose), in the absence of S9 at a LED of 50 µL/plate.^76^ The mutagenicity of green tea extract was not due to caffeine.^75,77^ Conversely, in a number of other bacterial mutation studies, green tea extract was not mutagenic in S. typhimurium TA98, TA100, TA1535, or TA1537 or Escherichia coli WP2 uvrA^78-80^ with or without S9. Additionally, a green tea extract, Polyphenon^®^ E, that is enriched for the catechin (flavanol) group of flavonoids present in green tea leaves was not mutagenic in S. typhimurium TA98, TA100, TA1535, or TA1537 or E. coli WP2 uvrA^81^ with or without S9. The highest ineffective doses (HID) of green tea extract or Polyphenon^®^ E tested in these studies were 5,000 μg/plate^80,81^ or 500 mL/plate.^79^ In addition to the differences in the concentrations and chemical compositions of various green tea extracts, another complication to assessing the mutagenic potential of green tea extracts arises from the fact that plants can store chemicals as glycones. Some flavonols such as quercetin, kaempferol, and myricetin exist as glycones in tea leaves (Brown and Dietrich,^82^ reviewed in Spencer^83^), and certain flavonol glycones have been shown to be pro-mutagens in bacterial mutagenicity assays, becoming active only after enzymatic or acidic hydrolysis.^78,82^ Although flavonol glycones appear to resist absorption in the small intestine, their β-glycosidic bonds can be hydrolyzed by mammalian colonic microflora, potentially releasing the mutagenic flavonols.^82^ Notably, green tea extract, after being subjected to enzymatic or acid hydrolysis, was shown to be mutagenic in S. typhimurium strains TA98 and TA100 in the presence or absence of S9.^75,78^ Therefore, the mutagenicity of green tea extract may be underestimated in bacterial assays due to infrequent use of a catabolism step to release aglycones.

Green tea extract has been tested in several mammalian cell genotoxicity assays. In murine macrophage-like RAW 264.7 cells and human leukemic HL60 cells, green tea extract induced DNA damage as measured by the comet assay (comet tail length) with LEDs ranging from 1 to 4 μg extract/mL in the absence of S9.^84^ Micronucleus formation also was induced in the same cell lines as measured by the cytokinesis-block micronucleus assay with LEDs ranging from 12 to 25 μg/mL without S9.^84^ Neither study was conducted with S9. Both green tea extract and Polyphenon^®^ E significantly increased the mutant frequency at the Tk locus in mouse lymphoma L5178Y cells with or without S9.^80,81^ Chromosomal aberrations were increased after 6 or 24 hours of incubation with green tea extract in Chinese hamster lung cells at a LED of 266.7 µg/mL in the absence, but not the presence, of S9.^80^

Green tea extract has been tested for genotoxicity in vivo. Micronucleated polychromatic erythrocytes (MN-PCEs) were not increased in the bone marrow of ICR (Crj: CD-1) mice or Harlan Sprague-Dawley rats exposed to green tea extract (two doses of 2,000 mg/kg delivered by gavage, 24 hours apart)^80^ or in bone marrow of ddY male mice following a single exposure to the catechin component of green tea extract (highest ineffective dose of 500 mg/kg by gavage).^85^ In both studies, frequencies of MN-PCEs were measured 24 hours postexposure. Ogura et al.^80^ demonstrated that green tea extract was systemically available to mice and rats under nonfasting conditions. Plasma concentrations of total free catechins reached 572 ng/mL or 2,321 ng/mL in male ICR (Crj: CD-1) mice or male Harlan Sprague-Dawley rats (respectively) 30 minutes after a single dose of 2,000 mg/kg green tea extract administered by gavage.^80^ In a study in which male and female Swiss Webster mice were given single doses of 0, 375, 750, or 1,500 mg/kg Polyphenon^®^ E by gavage, MN-PCEs from bone marrow were significantly increased (P < 0.01) 24 hours after dosing only in the male mice exposed to 375 or 750 mg/kg.^81^ Exposure to 1,000 mg/kg per day Polyphenon^®^ E by gavage for 28 days did not increase the frequency of cII mutations in the liver, lung, or spleen of male or female B6C3F1 Big Blue Transgenic mice.^81^

There has been considerable interest in identifying the specific components of green tea extract that exert genotoxic effects. Research efforts have focused on EGCG, which is considered to be a key active ingredient in green tea extract primarily due to its antioxidant effects, but EGCG has been shown to have pro-oxidant effects, as well.^86^ The genotoxicity of a specific EGCG preparation, Teavigo™ (approximately 90% EGCG), has been studied in a number of different assays, and results were mostly negative.^87^ Teavigo™ was not mutagenic in S. typhimurium strains TA97, TA98, TA100, or TA1535, with or without S9, but it was mutagenic at the Tk locus in mouse lymphoma L5178Y cells, but only with S9 (LEDs ranged from 125 to 150 μg/mL with different incubation times in Teavigo™). Teavigo™ was negative in the bone marrow micronucleus test in NMRI mice administered a single oral dose (HID was 2,000 mg/kg), in CD-1 mice exposed to Teavigo™ in the diet for 10 days (HID was 12,600 ppm, i.e., 1,200 mg/kg per day), and in Wistar rats given two intravenous injections of Teavigo^TM^ spaced 24 hours apart (HID was 50 mg/kg). Levels of MN-PCEs obtained from bone marrow were assessed 24 hours postexposure for each of these studies. By examining plasma concentrations of Teavigo™, Isbrucker et al.^56^ demonstrated that Teavigo™ was orally available to CD-1 mice and that intravenous injection of Teavigo™ into Wistar rats produced plasma levels of EGCG that were 18 to 45 times greater than what could be obtained in humans given an oral dose of 800 mg Teavigo™.^50,88^

The genotoxicity of EGCG has been examined in several in vitro tests and positive results were seen in a number of assays. In murine macrophage-like RAW 264.7 cells and human leukemic HL60 cells, EGCG induced DNA damage in the comet assay (tail length) with LEDs that ranged from 12 to 20 μg/mL.^84^ Additionally, EGCG induced DNA damage in the comet assay (tail moment) in freshly isolated human blood lymphocytes at an LED of 1 mM.^89,90^ In the cytokinesis-block micronucleus assay, EGCG induced micronucleus formation in murine macrophage-like RAW 264.7 cells and human leukemic HL60 cells (LEDs ranging from 12 to 25 μg/mL).^84^ However, EGCG did not induce sister chromatid exchanges (SCE) in Chinese hamster ovary K-1 cells (HID of 20 μg/mL)^85^ and did not increase ouabain resistance in murine mammary carcinoma FM3A cells at a dose of 50 nmol/mL.^91^

Green tea extract and specific chemical components of the extract have been tested far more extensively for their abilities to suppress the genotoxicity of various chemicals than for their genotoxic effects. The majority of this testing has been conducted using bacterial mutagenicity assays although in vitro and in vivo versions of mammalian cell mutation assays, the comet assay, and micronucleus assays have been employed as well. An extensive review of such studies was provided by Gupta et al.,^92^ and the literature on the antigenotoxic effects of green tea extract has continued to expand considerably since then. Green tea extract and EGCG have shown antigenotoxic effects in the majority of these studies, and several studies have provided mechanistic data (e.g., reduced oxidation of DNA or inhibition of DNA adduct formation) to support these observations.^92,93^ However, many antigenotoxicity studies did not include controls showing the effects of green tea extract or EGCG alone and/or did not include information on cytostatic or cytotoxic effects of the exposures. Therefore, many antigenotoxicity studies are not suitable for drawing definitive conclusions.^94^

In summary, green tea extract was positive in some bacterial mutagenicity assays and, along with EGCG, it was positive in a variety of in vitro mammalian cell assays that detect DNA damage, gene mutation, or chromosomal damage. These positive results were obtained mostly in the absence of S9. However, despite the positive results observed in the in vitro mammalian cell assays, green tea extract and EGCG have not been demonstrated to be genotoxic in any of several in vivo mammalian cell assays for gene mutation or chromosomal damage.

## Study Rationale

The purported active ingredient of green tea extract, EGCG, was originally nominated by the National Cancer Institute for toxicity and carcinogenicity studies because it is the most abundant catechin polyphenol in green tea extract, it was being investigated as a potential chemotherapeutic agent, and there was a lack of adequate information with regard to its toxicity. However, NTP selected the green tea extract containing EGCG and other green tea catechin polyphenols as the test article because it was considered more relevant to human exposure and because most commercially available green tea-based products contain a concentrated mixture of various green tea catechin polyphenols. NTP performed 3-month toxicology studies in F344/NTac rats and B6C3F1/N mice and 2-year toxicology and carcinogenicity studies in Wistar Han rats and B6C3F1/N mice using oral gavage administration of green tea extract. Oral gavage was chosen as the route of exposure because it was considered most relevant to human exposure to green tea extract dietary supplements.