# Appendix L Summary of Peer Review Panel Comments

On May 22, 2014, the draft Technical Report on the toxicology and carcinogenesis studies of green tea extract received public review by the National Toxicology Program’s Technical Report Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. C.R. Blystone, NIEHS, introduced the toxicology and carcinogenesis studies of green tea extract by discussing the uses of the chemical and the rationale for study, describing the experimental design, reporting on survival and body weight effects, and commenting on compound-related neoplastic and nonneoplastic lesions in rats and mice. The proposed conclusions, for the 2-year studies were no evidence of carcinogenic activity of green tea extract in male and female Wistar Han rats and in male B6C3F1/N mice, and equivocal evidence of carcinogenic activity of green tea extract in female B6C3F1/N mice

Dr. Carpenter noted receipt and distribution to the Panel of written comments from S.J. Smith on behalf of Taiyo Kagaku Co., LTD (Japan); Dr. T.L. Kurt on his own behalf; Dr. A.W. Wong, Dr. J.C. Griffiths, and H. Nguyen on behalf of the Council for Responsible Nutrition; M. McGuffin on behalf of the American Herbal Products Association; M. Blumenthal, Dr. S. Gafner, and A. Guevara on behalf of the American Botanical Council; and S.P. Mahinka on behalf of non-U.S. parties. He then recognized an oral public commenter, Dr. M. Zimmerman of the American Herbal Products Association, who spoke to the Panel by telephone.

Dr. Mirsalis, the first primary reviewer, noted the report accurately described and interpreted the findings of the 3-month and 2-year studies of green tea extract in rats and mice. He recommended reemphasizing in the report that as a result of the switch to Wistar Han rats, there are no appropriate historical data available for the current rat study. He stated the 1,000 mg/kg dose was too high, which could have been predicted from the effects seen in the 3-month study. Many of the findings in the report were only seen at that high dose. He asked why bilirubin was not measured when the test substance had previously demonstrated biliary toxicity and recommended the measurement should be included in the future. He speculated the accidental deaths in the 2-year rat study could be dose related and could be related to stress. He asked for clarification on the makeup of the green tea extract used in the studies, along with information on how it was prepared. He noted that every batch of green tea extract would be slightly different, and the material selected appeared to be representative of commercially available green tea extract. He asked how commonly nasal lesions are due to retrograde aspiration into the nasal cavity because he did not recall seeing these effects in other NTP studies. He recommended inclusion of a statement about when the studies were conducted, so the reviewer could assess the state of technology and science when evaluating the studies. He suggested removing references to “censoring” data on accidental deaths, as that is a politically charged term. Overall, he agreed with the proposed conclusions of the report.

Dr. Blystone, responding to Dr. Mirsalis’ comments, said more context could be provided regarding the historical controls issue. He noted the 1,000 mg/kg dose was dose limiting and affected survival. Regarding the biliary toxicity, he said there were two markers of biliary toxicity that were assayed, and that was deemed sufficient. The accidental deaths were evaluated and deemed to be gavage accidents with fluid in the lungs. The table in the Discussion section describing the constituents of green tea extract would be moved to the Materials and Methods section (Table 1). He agreed that retrograde aspiration is an uncommon occurrence, and could be discussed more in the report. He noted that the dates of the studies had been provided in the Materials and Methods section of the report. He said “censored” is actually a statistical term. Dr. G.E. Kissling, NIEHS, noted the term does have a specific statistical meaning. Dr. Mirsalis said he would defer to the term’s statistical use.

Dr. Conner, the second primary reviewer, asked whether decreased survival of 1,000 mg/kg rats had an impact on data interpretation. Dr. Blystone said the low survival at the high dose could affect tumor formation response; however, no tumor response was seen at lower doses, so this did not affect the evaluation. Dr. Conner said the lesions underlying the equivocal evidence call for female mice were not sufficient and he would recommend a call of no evidence instead. Dr. Blystone responded that the rarity of the tongue tumors in female B6C3F1/N mice was the basis for the call of equivocal evidence. Dr. Conner also said there is often some degree of retrograde aspiration with compounds known to be irritants, and as rats are nose breathers, both incidental and treatment-related mortality are common. Dr. D.E. Malarkey, NIEHS, added that a retrospective study is underway to assess irritancy and reflux in the lung and nasopharynx.

Dr. Perdew, the third primary reviewer, addressed the reflux issue. He proposed that because green tea extract is quite viscous, some of the material may have remained on the needle as the gavage needle was being withdrawn. He recommended adding details to the report on how the extract was made. He advised that if the company involved is not willing to share the information, NTP should rethink buying from commercial sources. He asked to see full analyses performed on the green tea extract, particularly heavy metal analyses, perhaps in an appendix. He asked to see more information on the rationale for the doses selected, stating that citing literature is not an adequate rationale. He asked for an estimate of how many cups of green tea might be equivalent to the doses used. He said there should be more information in the report about the mutagenic potential of the components of green tea extract, which should be available in the literature.

Dr. Blystone said more details about the extract and its preparation could be added to the report; however, the available information is limited. NTP did measure the components of green tea extract. For the initial dose justification, the information available in the literature was used as the starting point and the National Cancer Institute provided some additional information. He agreed to emphasize that analyses were of the extract, not a beverage. He could provide some information about typical exposure to green tea extract, although that is beyond the purview of the report and enters into risk assessment. He agreed to review the information in the report regarding the mutagenicity of individual components of green tea extract. Referring to the Ames assay, Dr. Perdew asked what it would mean for the mutagenicity of green tea extract if individual components of green tea extract were not mutagenic. Dr. N.J. Walker, NIEHS, noted the extract contained more than the identified components, and this is typical of botanical extracts. Regarding whether to make or purchase the extracts, he said there is criticism attached to both methods of procurement. Dr. Perdew suggested that when a commercial acquisition is planned in the future, a deal should be made with the company to provide full information about the extract.

Dr. P.C. Howard, FDA, cautioned against making any statements of relevance to human consumption because that would force a risk assessment decision with inadequate information within the study. Dr. Walker added that the testing was done on green tea extract, so it would be inappropriate to draw any comparisons with a green tea beverage. Dr. Perdew said perhaps he should have asked for inclusion of information about how the data would relate to the usual dose of green tea extract in humans. Dr. Howard reiterated that great care should be taken about relating these types of data to human consumption. Dr. Walker said in past Technical Reports on botanicals, simple statements relating to human consumption had been included, so this could be discussed for inclusion in this Technical Report.

Dr. Regan echoed Dr. Conner’s remarks about reflux irritation in the nose. She asked if the study group had ever looked for inflammation in the animals’ middle ears. Dr. A.E. Brix, Experimental Pathology Laboratories, Inc., said they had not. Dr. Conner agreed that irritation is often seen in eustachian tubes. Dr. Malarkey said if there was any inflammatory response at that location, it would have been noticed, but that site was not specifically examined. Dr. Regan said it was unlikely it would have been seen unless the area had been specifically examined. She also stated the incidence of two tumors of the tongue was not actual evidence of carcinogenicity. Dr. Mahrt agreed that the lesions of the nose may be related to retrograde aspiration.

Dr. Carpenter called for the draft conclusions to be projected.

Dr. Conner moved that the equivocal evidence conclusion be deleted for female mice, and the conclusion should be there is no evidence of carcinogenic activity at the various doses in both species and both sexes. Dr. Regan seconded the motion. Dr. Walker reminded the panel that the equivocal call had been made because squamous cell carcinoma of the tongue or oral cavity had never been seen before in historical control mice. Dr. Mirsalis said he was more comfortable with the equivocal call, based on the rarity of these neoplasms. Dr. Carpenter called for a vote on the motion. The motion carried, with 5 in favor and 1 opposed. Dr. Mirsalis explained his negative vote was due to the rarity of the tumors seen in two animals.