# Appendix K Sentinel Animal Program

## K.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected and allowed to clot and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter spp. All samples were processed appropriately and evaluated for the presence of pathogens. Samples were sent to BioReliance Corporation (Rockville, MD) or the Research Animal Diagnostic Laboratory (RADIL; University of Missouri, Columbia, MO). The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Table K-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
Three-month Study
ELISA
PVM (pneumonia virus of mice) | Study start, 1 month, study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | Study start, 1 month, study termination
Sendai | Study start, 1 month, study termination
Immunofluorescence Assay
Parvovirus | Study start, 1 month, study termination
RCV/SDA | 1 month
Two-year Study
ELISA
PVM | Study start and 1 month
RCV/SDA | Study start and 1 month
Sendai | Study start and 1 month
Immunofluorescence Assay
Parvovirus | Study start and 1 month
Multiplex Fluorescent Immunoassay
H-1 (Toolan’s H-1 virus) | 6, 12, and 18 months, study termination
KRV (Kilham rat virus) | 6, 12, and 18 months, study termination
Mycoplasma pulmonis | 6, 12, and 18 months, study termination
Parvovirus NS-1 | 6, 12, and 18 months, study termination
PVM | 6, 12, and 18 months, study termination
RCV/SDA | 6, 12, and 18 months, study termination
RMV (rat minute virus) | 6, 12, and 18 months, study termination
RPV (rat parvovirus) | 6, 12, and 18 months, study termination
RTV (rat theliovirus) | 6, 12, and 18 months, study termination
Sendai | 6, 12, and 18 months, study termination
TMEV (Theiler’s murine encephalomyelitis virus) | 6, 12, and 18 months, study termination
Mice
Three-month Study
ELISA
Ectromelia virus | Study start, 1 month, study termination
EDIM (epizootic diarrhea of infant mice) | Study start, 1 month, study termination
GDVII (mouse encephalomyelitis virus) | Study start, 1 month, study termination
LCM (lymphocytic choriomeningitis virus) | Study start, 1 month, study termination
Mouse adenoma virus-FL | Study start, 1 month, study termination
MHV (mouse hepatitis virus) | Study start, 1 month, study termination
MMV VP2 (mouse minute virus viral protein 2) | Study start, 1 month, study termination
MPV VP2 (mouse parvovirus viral protein 2) | Study start, 1 month, study termination
PVM | Study start, 1 month, study termination
Reovirus 3 | Study start, 1 month, study termination
Sendai | Study start, 1 month, study termination
Two-year Study
ELISA
Ectromelia virus | Study start and 1 month
EDIM | Study start and 1 month
GDVII | Study start and 1 month
LCM | Study start and 1 month
Mouse adenoma virus-1 | Study start and 1 month
MHV | Study start and 1 month
MMV VP2 | Study start and 1 month
MPV VP2 | Study start and 1 month
PVM | Study start and 1 month
Reovirus 3 | Study start and 1 month
Sendai | Study start and 1 month
Multiplex Fluorescent Immunoassay
Ectromelia virus | 6, 12, and 18 months, study termination
EDIM | 6, 12, and 18 months, study termination
LCM | 6, 12, and 18 months, study termination
MHV | 6, 12, and 18 months, study termination
MMV | 6, 12, and 18 months, study termination
MNV (mouse norovirus) | 6, 12, and 18 months, study termination
MPV | 6, 12, and 18 months, study termination
M. pulmonis | 6, 12, and 18 months, study termination
Parvovirus NS-1 | 6, 12, and 18 months, study termination
PVM | 6, 12, and 18 months, study termination
Reovirus 3 | 6, 12, and 18 months, study termination
TMEV GDVII | 6, 12, and 18 months, study termination
Sendai | 6, 12, and 18 months, study termination
Polymerase Chain Reaction
Helicobacter spp. | 18 months

## K.2 Results

All test results were negative.