# Appendix I Chemical Characterization and Dose Formulation Studies

## I.1 Procurement and Characterization of Green Tea Extract

Green tea extract was obtained from Amax NutraSource, Inc. (Eugene, OR), in one lot (GTE50-A0302031114) that was used in the 3-month and 2-year studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle Chemistry Support Services, a division of Battelle Columbus Operations (Columbus, OH) and by the study laboratory at Battelle Columbus Operations. Reports on analyses performed in support of the green tea extract studies are on file at the National Institute of Environmental Health Sciences.

Lot GTE50-A0302031114 of the chemical, a light-brown powder, was identified as green tea extract by the analytical chemistry laboratory and the study laboratory using infrared spectroscopy. All spectra were consistent with spectra obtained from another lot, and the overall absorbances and spectral composition were consistent with the components that make up typical green tea extract. A representative infrared spectrum is presented in Figure I-1.

The moisture content of lot GTE50-A0302031114 was determined by the analytical chemistry and study laboratories using weight loss on drying; moisture content was also determined by Prevalere Life Sciences, Inc. (Whitesboro, NY), and Galbraith Laboratories (Knoxville, TN) using Karl Fischer titration. The analytical chemistry laboratory determined the purity of the test article using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection. Components of the purity profile were identified by comparing the retention times from a chromatogram of lot GTE50-A0302031114 to a chromatogram of a solution containing nine potential green tea extract components; these components were quantified by standard addition using authentic standards (Aldrich, Milwaukee, WI, or Sigma, St. Louis, MO). HPLC with mass spectrometry (MS) detection was used to confirm the identity of these components.

For lot GTE50-A0302031114, weight loss on drying conducted at two laboratories indicated 4.77% and 5.8% water. Karl Fischer titration conducted at one laboratory indicated 6% to 11.6% water and similar analyses conducted at a second laboratory indicated 3% to 4% water; the latter values were consistent with the 3.32% water indicated in the manufacturer’s Certificate of Analysis. HPLC/UV using system A indicated eight components with areas greater than or equal to 1% of the total peak area (Table I-1). Six of these peaks were tentatively identified by matching retention times as epicatechin, catechin gallate, caffeine, epigallocatechin gallate, gallocatechin gallate, and epicatechin gallate. The total area of the major polyphenol peaks represented approximately 84.8% of the total peak area; caffeine constituted 12.27% of the total area, and the remainder was two unidentified components. Nine components of the test article HPLC purity profile were identified and quantified by standard addition using the same chromatography system; these components were gallocatechin, epigallocatechin, catechin, epicatechin, catechin gallate, caffeine, epigallocatechin gallate, gallocatechin gallate, and epicatechin gallate. HPLC/MS using system B confirmed the identity of eight of the nine components; epigallocatechin was not identified due to the concentration being below the detection limit in the test article sample. The weight percentage contents of epigallocatechin gallate, epicatechin gallate, epigallocatechin, epicatechin, and caffeine were determined to be 48.4%, 12.8%, 2.26%, 2.83%, and 4.99%, respectively; these values were comparable to those listed in the manufacturer’s Certificate of Analysis (53.11%, 13.7%, 2.88%, 3.97%, and 5.42%, respectively). Other catechin polyphenols that were quantified included gallocatechin, catechin, catechin gallate, gallocatechin gallate, and the weight percentage contents were determined to be 0.52%, 0.51%, 0.45%, and 4.6%, respectively. Taken together, these data indicate that lot GTE50-A0302031114 of the test material was green tea extract. One aliquot of green tea extract was submitted to Covance Laboratories, Inc., (Madison, WI) for nutritional and contaminant testing using standard methods. For this lot, heavy metals present in the extract included antimony (<10 ppb), arsenic (43.9 ppb), cadmium (<10 ppb), lead (9.79 ppb), and mercury (<10 ppb). For mycotoxin analysis, levels of ochratoxin and zearalinine were less than 5 and 50 ppb, respectively; levels for aflatoxins B1, B2, G1, and G2 could not be quantified due to matrix interferences. The pesticide screen also experienced significant matrix effects that prevented quantitation of analytes.

Stability studies of the bulk chemical were performed by the analytical chemistry laboratory using HPLC/UV by system C. These studies indicated that green tea extract was stable as a bulk chemical for at least 14 days when stored in sealed amber glass containers at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature in sealed amber glass containers. Periodic reanalyses of the bulk chemical were performed by the study laboratory during the 3-month and 2-year studies using HPLC/UV by system A, and no degradation of the bulk chemical was detected.

## I.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing green tea extract with deionized water to give the required concentrations (Table I-2). The dose formulations were stored at room temperature in sealed clear glass bottles, enclosed in amber plastic bags for up to 8 (3-month studies) or 22 (2-year studies) days.

The analytical chemistry laboratory performed a gavageability study of the 200 mg/mL dose formulation using a 25-gauge needle and stability studies of the 6.25 mg/mL dose formulation using HPLC/UV by system C (Table I-1). Gavageability was confirmed and stability was confirmed for at least 42 days for dose formulations stored in sealed amber glass bottles, at room temperature and for at least 3 hours under simulated animal room conditions.

The study laboratory performed gavageability studies of the 100 and 200 mg/mL dose formulations using 20- and 18-gauge ball-tipped stainless steel needles, respectively; in addition, homogeneity studies of the 6.25, 12.5, 100, and 200 mg/mL dose formulations and stability studies of the 6.25, 25, and 200 mg/mL dose formulations were performed using HPLC/UV by system A. Gavageability and homogeneity were confirmed. Stability was confirmed for at least 22 days for dose formulations prepared with sterile water, bottles, caps, and stir bars; the formulas were stored in clear glass bottles sealed in amber plastic bags at room temperature.

Periodic analyses of the dose formulations of green tea extract were conducted by the study laboratory using HPLC/UV by system A. During the 3-month studies, the dose formulations were analyzed three times for EGCG concentraations; all 18 dose formulations were within 10% of the target concentrations (Table I-3). Animal room samples of these dose formulations were also analyzed; all 15 for rats and 14 of 15 for mice were within 10% of the target concentrations. During the 2-year studies, the dose formulations were analyzed approximately every 2 to 3 months; animal room samples were also analyzed (Table I-4). Of the dose formulations analyzed, all 63 for rats and all 33 for mice were within 10% of the target concentrations; all 12 animal room samples for rats and 12 of 13 for mice were within 10% of the target concentrations.

Table I-1 High-Performance Liquid Chromatography Systems Used in the Gavage Studies of Green Tea Extract^a^

Detection System | Column | Solvent System
System A
Ultraviolet (274 nm) light | Aqua^®^ C_18_, 150 mm × 4.6 mm, 3 μm (Phenomenex, Torrance, CA) | A) Milli-Q water with 0.1% formic acid and B) acetonitrile with 0.1% formic acid; linear gradient from 97% A:3% B to 90% A:10% B in 30 minutes, then linear gradient to 70% A:30% B in 10 minutes, held for 10 minutes, then linear gradient to 97% A:3% B in 1 minute, held for 9 minutes; flow rate 1.0 mL/minute
System B
Mass spectrometry | Aqua^®^ C_18_, 150 mm × 4.6 mm, 3 μm (Phenomenex) | A) Milli-Q water with 0.1% formic acid and B) acetonitrile with 0.1% formic acid; linear gradient from 97% A:3% B to 90% A:10% B in 30 minutes, then linear gradient to 70% A:30% B in 10 minutes, held for 10 minutes, then linear gradient to 97% A:3% B in 1 minute, held for 14 minutes; flow rate 1.0 mL/minute
System C
Ultraviolet (274 nm) light | Aqua^®^ C_18_, 150 mm × 4.6 mm, 3 μm (Phenomenex) | A) 97:3:0.1 Milli-Q water:acetonitrile:formic acid and B) 70:30:0.1 Milli-Q water:acetonitrile:formic acid; linear gradient from 100% A to 75% A:25% B in 30 minutes, then linear gradient to 100% B in 10 minutes, held for 10 minutes, then linear gradient to 100% A in 1 minute, held for 14 minutes; flow rate 1.0 mL/minute

^a^ The high-performance liquid chromatographs were manufactured by Waters Corporation (Milford, MA) or Agilent Technologies (Palo Alto, CA). The mass spectrometer was manufactured by Micromass UK Ltd. (Manchester, England

Table I-2 Preparation and Storage of Dose Formulations in the Gavage Studies of Green Tea Extract

Three-month Studies | Two-year Studies
Preparation
To prepare the 6.25 mg/mL dose formulation, the specified amount of green tea extract was weighed into a beaker and then analytically transferred to a calibrated glass bottle with at least three rinses of deionized water. For the 12.5 through 200 mg/mL dose formulations, the appropriate amount of test article was weighed directly into a calibrated glass bottle. For all formulations, deionized water was added to approximately half the final bottle volume, the bottle was capped and shaken for approximately 2 minutes, inverted at least 10 times, diluted to final volume with deionized water, capped, and sonicated (kept below 35°C) for at least 15 minutes or until the test article was dissolved, then shaken vigorously by hand for approximately 1 minute and stirred with an overhead stirrer for approximately 5 minutes. The dose formulations were prepared approximately weekly. | To prepare the 3 mg/mL dose formulation, the specified amount of green tea extract was weighed into a beaker and then analytically transferred to a calibrated glass bottle with at least three rinses of deionized water. For the 10 through 200 mg/mL dose formulations, the appropriate amount of test article was weighed directly into a calibrated glass bottle. For all formulations, deionized water was added to approximately half the final bottle volume and the bottles were further processed as described for the 3-month studies. Due to extensive foaming during the final dilution of the 200 mg/mL formulation, the volume of this formulation was confirmed by weighing the formulation and using the density to verify the correct volume. Sterile materials (water, beakers, bottles, caps, and stir bars) were used throughout these procedures. The dose formulations were prepared approximately every 3 weeks.
Chemical Lot Number
GTE50-A0302031114 | GTE50-A0302031114
Maximum Storage Time
8 days | 22 days
Storage Conditions
Stored in sealed clear glass bottles enclosed in amber plastic bags at room temperature | Stored in clear glass bottles sealed in amber plastic bags at room temperature
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)

Table I-3 Results of Analyses of Dose Formulations Administered to F344/NTac Rats and B6C3F1/N Mice in the Three-month Gavage Studies of Green Tea Extract

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/mL) | Determined Concentration^b^ (mg/mL) | Difference from Target (%)
Rats
April 14, 2006 | April 13–16, 2006 | 12.5 | 12.50 | 0
| | 25 | 24.89 | 0
| | 50 | 50.60 | +1
| | 100 | 103.5 | +4
| | 200 | 198.6 | −1
| April 27–29, May 1, 2006^c^ | 12.5 | 12.12 | −3
| | 25 | 24.93 | 0
| | 50 | 49.53 | −1
| | 100 | 98.33 | −2
| | 200 | 194.8 | −3
June 2, 2006 | June 1–3, 2006 | 12.5 | 12.39 | −1
| | 25 | 24.78 | −1
| | 50 | 49.48 | −1
| | 100 | 98.72 | −1
| | 200 | 192.3 | −4
| June 12–14, 2006^c^ | 12.5 | 12.49 | 0
| | 25 | 25.05 | 0
| | 50 | 49.27 | −1
| | 100 | 101.1 | +1
| | 200 | 198.9 | −1
July 12, 2006 | July 12–14, 2006 | 12.5 | 12.19 | −2
| | 25 | 24.06 | −4
| | 50 | 47.85 | −4
| | 100 | 96.30 | −4
| | 200 | 208.9 | +4
| July 31–August 2, 2006^c^ | 12.5 | 12.50 | 0
| | 25 | 24.29 | −3
| | 50 | 49.66 | −1
| | 100 | 99.40 | −1
| | 200 | 210.6 | +5
Mice
April 14, 2006 | April 13–16, 2006 | 6.25 | 6.335 | +1
| | 12.5 | 12.50 | 0
| | 25 | 24.89 | 0
| | 50 | 50.60 | +1
| | 100 | 103.5 | +4
| April 27−29, May 1, 2006^c^ | 6.25 | 5.987 | −4
| | 12.5 | 12.07 | −3
| | 25 | 24.65 | −1
| | 50 | 49.75 | −1
| | 100 | 99.15 | −1
June 2, 2006 | June 1–3, 2006 | 6.25 | 6.165 | −1
| | 12.5 | 12.39 | −1
| | 25 | 24.78 | −1
| | 50 | 49.48 | −1
| | 100 | 98.72 | −1
| June 12–14, 2006^c^ | 6.25 | 6.128 | −2
| | 12.5 | 12.45 | 0
| | 25 | 25.04 | 0
| | 50 | 49.11 | −2
| | 100 | 100.3 | 0
July 12, 2006 | July 12–14, 2006 | 6.25 | 6.123 | −2
| | 12.5 | 12.19 | −2
| | 25 | 24.06 | −4
| | 50 | 47.85 | −4
| | 100 | 96.30 | −4
| July 31–August 2, 2006^c^ | 6.25 | 1.027^d^ | −84
| | 12.5 | 13.15 | +5
| | 25 | 25.95 | +4
| | 50 | 52.50 | +5
| | 100 | 106.7 | +7

^a^ Due to the length of the analytical runs, the date of analysis may precede the date of preparation.

^b^ Results of duplicate analyses. For rats, dosing volume = 5 mL/kg; 12.5 mg/mL = 62.5 mg/kg, 25 mg/mL = 125 mg/kg, 50 mg/mL = 250 mg/kg, 100 mg/mL = 500 mg/kg, 200 mg/mL = 1,000 mg/kg. For mice, dosing volume = 10 mL/kg; 6.25 mg/mL = 62.5 mg/kg, 12.5 mg/mL = 125 mg/kg, 25 mg/mL = 250 mg/kg, 50 mg/mL = 500 mg/kg, 100 mg/mL = 1,000 mg/kg.

^c^ Animal room samples.

^d^ Results of four replicate analyses; evidence indicated that the sample was hydrolyzed.

Table I-4 Results of Analyses of Dose Formulations Administered to Wistar Han Rats and B6C3F1/N Mice in the Two-year Gavage Studies of Green Tea Extract

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/mL) | Determined Concentration^b^ (mg/mL) | Difference from Target (%)
Rats
July 5, 2007 | July 3–5, 2007 | 20 | 21.1 | +6
| | 20 | 21.1 | +6
| | 60 | 62.9 | +5
| | 60 | 60.9 | +2
| | 200 | 193 | −4
| | 200 | 204 | +2
| August 2, 2007^c^ | 20 | 20.3 | +2
| | 60 | 62.5 | +4
| | 200 | 191 | −5
September 6, 2007 | September 6, 2007 | 20 | 20.5 | +3
| | 20 | 20.5 | +3
| | 60 | 60.6 | +1
| | 60 | 61.3 | +2
| | 200 | 216 | +8
September 11, 2007 | September 10, 2007 | 200 | 214 | +7
November 8, 2007 | November 7–8, 2007 | 20 | 20.5 | +3
| | 20 | 20.6 | +3
| | 60 | 61.8 | +3
| | 60 | 60.8 | +1
| | 200 | 206 | +3
| | 200 | 206 | +3
January 31, 2008 | January 30–31, 2008 | 20 | 21.2 | +6
| | 20 | 20.8 | +4
| | 60 | 62.1 | +4
| | 60 | 61.5 | +3
| | 200 | 208 | +4
| | 200 | 209 | +5
| February 22, 2008^c^ | 20 | 20.9 | +5
| | 60 | 61.7 | +3
| | 200 | 207 | +4
April 3, 2008 | April 2, 2008 | 20 | 20.3 | +2
| | 20 | 20.6 | +3
| | 60 | 63.0 | +5
| | 60 | 64.0 | +7
| | 200 | 193 | −4
| | 200 | 200 | 0
June 5, 2008 | June 4, 2008 | 20 | 21.0 | +5
| | 20 | 20.4 | +2
| | 60 | 61.5 | +3
| | 60 | 59.7 | −1
| | 200 | 209 | +5
| | 200 | 208 | +4
August 28, 2008 | August 27, 2008 | 20 | 20.9 | +5
| | 20 | 20.0 | 0
| | 60 | 63.4 | +6
| | 60 | 61.8 | +3
| | 200 | 206 | +3
| | 200 | 198 | −1
| September 19, 2008^c^ | 20 | 20.1 | +1
| | 60 | 62.0 | +3
| | 200 | 206 | +3
October 30, 2008 | October 29, 2008 | 20 | 20.9 | +5
| | 20 | 21.3 | +7
| | 60 | 63.1 | +5
| | 60 | 64.4 | +7
| | 200 | 214 | +7
| | 200 | 215 | +8
January 22, 2009 | January 21, 2009 | 20 | 20.6 | +3
| | 20 | 20.8 | +4
| | 60 | 62.7 | +5
| | 60 | 60.9 | +2
| | 200 | 209 | +5
March 26, 2009 | March 26, 2009 | 20 | 21.0 | +5
| | 20 | 21.1 | +6
| | 60 | 62.6 | +4
| | 60 | 63.4 | +6
| | 200 | 208 | +4
| April 20, 2009^c^ | 20 | 20.2 | +1
| | 60 | 61.9 | +3
| | 200 | 210 | +5
June 18, 2009 | June 17, 2009 | 20 | 20.7 | +4
| | 20 | 21.8 | +9
| | 60 | 63.4 | +6
| | 60 | 64.5 | +8
| | 200 | 211 | +6
Mice
July 5, 2007 | July 3, 2007 | 3 | 3.10 | +3
| | 10 | 10.4 | +4
| | 30 | 31.3 | +4
| August 2, 2007^c^ | 3 | 1.61^d^ | −46
| August 16, 2007^c^ | 10 | 10.3 | +3
| | 30 | 29.9 | 0
July 26, 2007 | August 16, 2007^c^ | 3 | 2.76 | −8
September 6, 2007 | September 6, 2007 | 3 | 3.05 | +2
| | 10 | 10.2 | +2
| | 30 | 30.8 | +3
November 8, 2007 | November 7–8, 2007 | 3 | 3.07 | +2
| | 10 | 10.3 | +3
| | 30 | 29.8 | −1
January 31, 2008 | January 30, 2008 | 3 | 3.08 | +3
| | 10 | 10.5 | +5
| | 30 | 31.4 | +5
| February 22, 2008^c^ | 3 | 2.89 | −4
| | 10 | 10.3 | +3
| | 30 | 30.7 | +2
April 3, 2008 | April 2, 2008 | 3 | 3.02 | +1
| | 10 | 10.0 | 0
| | 30 | 30.1 | 0
June 5, 2008 | June 4, 2008 | 3 | 3.14 | +5
| | 10 | 10.4 | +4
| | 30 | 31.0 | +3
August 28, 2008 | August 27, 2008 | 3 | 3.07 | +2
| | 10 | 9.98 | 0
| | 30 | 30.1 | 0
| September 19, 2008^c^ | 3 | 2.96 | −1
| | 10 | 10.0 | 0
| | 30 | 30.9 | +3
October 30, 2008 | October 29, 2009 | 3 | 3.05 | +2
| | 10 | 10.4 | +4
| | 30 | 30.9 | +3
January 22, 2009 | January 21, 2009 | 3 | 3.05 | +2
| | 10 | 10.2 | +2
| | 30 | 31.0 | +3
March 26, 2009 | March 26, 2009 | 3 | 2.94 | −2
| | 10 | 10.1 | +1
| | 30 | 31.0 | +3
| April 20, 2009^c^ | 3 | 3.02 | +1
| | 10 | 9.83 | −2
| | 30 | 30.1 | 0
June 18, 2009 | June 17, 2009 | 3 | 3.09 | +3
| | 10 | 10.5 | +5
| | 30 | 31.0 | +3

^a^ Due to the length of the analytical runs, the date of analysis may precede the date of preparation.

^b^ Results of duplicate analyses. For rats, dosing volume = 5 mL/kg; 20 mg/mL = 100 mg/kg, 60 mg/mL = 300 mg/kg, 200 mg/mL = 1,000 mg/kg. For mice, dosing volume = 10 mL/kg; 3 mg/mL = 30 mg/kg, 10 mg/mL = 100 mg/kg, 30 mg/mL = 300 mg/kg.

^c^ Animal room samples.

^d^ Sample contained a fungal growth.

Figure I-1

Infrared Absorption Spectrum of Green Tea Extract