# Appendix H Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table H-1 Summary of Reproductive Tissue Evaluations for Male F344/NTac Rats in the Three-month Gavage Study of Green Tea Extract^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 340 ± 4 | 318 ± 4** | 302 ± 5** | 293 ± 4**
L. Cauda epididymis | 0.1351 ± 0.0027 | 0.1387 ± 0.0023 | 0.1307 ± 0.0036 | 0.1193 ± 0.0040**
L. Epididymis | 0.4100 ± 0.0063 | 0.4103 ± 0.0051 | 0.4038 ± 0.0071 | 0.3702 ± 0.0061**
L. Testis | 1.4643 ± 0.0162 | 1.4329 ± 0.0190 | 1.4099 ± 0.0161 | 1.4011 ± 0.0175*
Spermatid measurements
Spermatid heads (10^6^/testis) | 211.00 ± 6.70 | 206.75 ± 5.73 | 209.75 ± 6.55 | 198.50 ± 9.08
Spermatid heads (10^6^/g testis) | 172.1 ± 4.4 | 169.0 ± 5.0 | 172.4 ± 4.5 | 167.3 ± 7.2
Epididymal spermatozoal measurements
Sperm motility (%) | 84.8 ± 0.5 | 83.7 ± 0.4 | 83.8 ± 0.4 | 84.0 ± 0.4
Sperm (10^6^/cauda epididymis) | 108.90 ± 5.20 | 117.78 ± 4.57 | 97.15 ± 5.63 | 93.40 ± 6.22
Sperm (10^6^/g cauda epididymis) | 806 ± 33 | 849 ± 30 | 746 ± 42 | 783 ± 48

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s or Williams’ test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table H-2 Estrous Cycle Characterization for Female F344/NTac Rats in the Three-month Gavage Study of Green Tea Extract^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 188 ± 2 | 176 ± 2* | 179 ± 4 | 176 ± 3**
Proportion of regular cycling females^b^ | 9/10 | 10/10 | 10/10 | 6/9
Estrous cycle length (days) | 4.7 ± 0.18 | 4.9 ± 0.06 | 5.0 ± 0.00 | 5.4 ± 0.42^c^
Estrous stages (% of cycle)
Diestrus | 58.1 | 61.3 | 58.1 | 65.6
Proestrus | 10.6 | 13.8 | 18.1 | 13.1
Estrus | 25.0 | 23.1 | 22.5 | 20.6
Metestrus | 5.6 | 1.3 | 0.6 | 0.6
Uncertain diagnoses | 0.6 | 0.6 | 0.6 | 0.0

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

** P ≤ 0.01.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunn’s test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated 1,000 mg/kg females spent significantly more time in extended diestrus than did the vehicle controls.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.

Table H-3 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Gavage Study of Green Tea Extract^a^

| Vehicle Control | 125 mg/kg | 250 mg/kg | 500 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 40.7 ± 1.0 | 39.4 ± 1.0 | 35.4 ± 0.9** | 34.1 ± 0.9**
L. Cauda epididymis | 0.0155 ± 0.0011 | 0.0143 ± 0.0013 | 0.0149 ± 0.0009 | 0.0121 ± 0.0016
L. Epididymis | 0.0436 ± 0.0041 | 0.0431 ± 0.0017 | 0.0428 ± 0.0008 | 0.0412 ± 0.0038
L. Testis | 0.1178 ± 0.0061 | 0.1145 ± 0.0014 | 0.1117 ± 0.0021 | 0.1132 ± 0.0013
Spermatid measurements
Spermatid heads (10^6^/testis) | 21.99 ± 0.78 | 20.20 ± 0.79 | 19.67 ± 0.77 | 19.55 ± 1.16*
Spermatid heads (10^6^/g testis) | 221.6 ± 9.7 | 203.7 ± 8.9 | 202.8 ± 8.6 | 218.2 ± 13.7
Epididymal spermatozoal measurements
Sperm motility (%) | 87.1 ± 0.6 | 87.3 ± 0.4 | 86.5 ± 0.7 | 86.0 ± 0.5
Sperm (10^6^/cauda epididymis) | 20.81 ± 1.42 | 20.40 ± 1.01 | 19.75 ± 1.83 | 21.43 ± 0.97
Sperm (10^6^/g cauda epididymis) | 1,356 ± 73 | 1,484 ± 89 | 1,378 ± 170 | 2,164 ± 386

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s test.

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid heads/g testis and epididymal spermatozoal measurements).

Table H-4 Estrous Cycle Characterization for Female Mice in the Three-month Gavage Study of Green Tea Extract^a^

| Vehicle Control | 125 mg/kg | 250 mg/kg | 500 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 30.4 ± 0.6 | 26.6 ± 0.7** | 26.8 ± 0.7** | 24.3 ± 0.4**
Proportion of regular cycling females^b^ | 9/10 | 10/10 | 9/10 | 9/10
Estrous cycle length (days) | 4.5 ± 0.13 | 3.9 ± 0.05** | 4.2 ± 0.10 | 4.3 ± 0.14
Estrous stages (% of cycle)
Diestrus | 35.6 | 28.1 | 30.6 | 37.5
Proestrus | 1.3 | 0.0 | 0.0 | 0.0
Estrus | 41.3 | 46.9 | 47.5 | 41.3
Metestrus | 21.9 | 25.0 | 21.9 | 21.3

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test (body weights) or Dunn’s test (estrous cycle length).

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated 500 mg/kg females spent significantly more time in extended diestrus than did the vehicle controls.

^b^ Number of females with a regular cycle/number of females cycling.