# Appendix G Organ Weights and Organ-Weight-To-Body-Weight Ratios

Table G-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/NTac Rats in the Three-month Gavage Study of Green Tea Extract^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 340 ± 4 | 330 ± 4 | 330 ± 4 | 318 ± 4** | 302 ± 5** | 293 ± 4**
Heart
Absolute | 1.04 ± 0.02 | 1.00 ± 0.02 | 0.98 ± 0.02 | 1.00 ± 0.02 | 0.98 ± 0.03 | 0.94 ± 0.02**
Relative | 3.071 ± 0.030 | 3.033 ± 0.036 | 2.966 ± 0.036 | 3.143 ± 0.070 | 3.261 ± 0.051* | 3.205 ± 0.042*
R. Kidney
Absolute | 1.09 ± 0.01 | 1.08 ± 0.02 | 1.09 ± 0.01 | 1.09 ± 0.02 | 1.07 ± 0.03 | 1.04 ± 0.02
Relative | 3.216 ± 0.036 | 3.284 ± 0.042 | 3.310 ± 0.012 | 3.433 ± 0.045** | 3.557 ± 0.054** | 3.559 ± 0.057**
Liver
Absolute | 12.61 ± 0.30 | 12.13 ± 0.025 | 12.14 ± 0.23 | 11.25 ± 0.23** | 10.68 ± 0.30** | 11.06 ± 0.27**
Relative | 37.128 ± 0.659 | 36.761 ± 0.500 | 36.865 ± 0.682 | 35.369 ± 0.489 | 35.365 ± 0.609 | 37.751 ± 0.771
Lung
Absolute | 2.30 ± 0.10 | 1.90 ± 0.07* | 2.04 ± 0.08* | 2.01 ± 0.09* | 1.87 ± 0.10** | 1.83 ± 0.06**
Relative | 6.775 ± 0.270 | 5.778 ± 0.227* | 6.194 ± 0.266 | 6.345 ± 0.309 | 6.172 ± 0.266 | 6.244 ± 0.233
Spleen
Absolute | 0.722 ± 0.016 | 0.677 ± 0.011* | 0.679 ± 0.014* | 0.679 ± 0.012* | 0.621 ± 0.007** | 0.543 ± 0.011**
Relative | 2.126 ± 0.031 | 2.053 ± 0.025 | 2.061 ± 0.039 | 2.135 ± 0.040 | 2.063 ± 0.035 | 1.856 ± 0.047**
R. Testis
Absolute | 1.429 ± 0.023 | 1.422 ± 0.027 | 1.408 ± 0.028 | 1.357 ± 0.035 | 1.367 ± 0.021 | 1.331 ± 0.013*
Relative | 4.210 ± 0.064 | 4.314 ± 0.094 | 4.273 ± 0.070 | 4.271 ± 0.124 | 4.545 ± 0.098* | 4.556 ± 0.058**
Thymus
Absolute | 0.364 ± 0.016 | 0.354 ± 0.013 | 0.330 ± 0.014 | 0.317 ± 0.022* | 0.289 ± 0.012** | 0.231 ± 0.011**
Relative | 1.071 ± 0.040 | 1.076 ± 0.047 | 1.003 ± 0.044 | 0.994 ± 0.067 | 0.957 ± 0.035 | 0.790 ± 0.040**
Female
n | 10 | 10 | 9 | 10 | 10 | 10
Necropsy body wt | 188 ± 2 | 184 ± 3 | 184 ± 3 | 176 ± 2* | 179 ± 4* | 176 ± 3**
Heart
Absolute | 0.69 ± 0.02 | 0.68 ± 0.01 | 0.67 ± 0.01 | 0.64 ± 0.01* | 0.64 ± 0.01* | 0.65 ± 0.01*
Relative | 3.647 ± 0.072 | 3.703 ± 0.053 | 3.634 ± 0.040 | 3.637 ± 0.065 | 3.594 ± 0.050 | 3.722 ± 0.090
R. Kidney
Absolute | 0.70 ± 0.01 | 0.66 ± 0.01 | 0.70 ± 0.02 | 0.64 ± 0.01* | 0.65 ± 0.02 | 0.67 ± 0.02
Relative | 3.705 ± 0.060 | 3.603 ± 0.031 | 3.828 ± 0.084 | 3.619 ± 0.057 | 3.647 ± 0.034 | 3.787 ± 0.070
Liver
Absolute | 6.57 ± 0.014 | 6.30 ± 0.015 | 6.37 ± 0.013 | 5.95 ± 0.015* | 6.26 ± 0.016 | 6.53 ± 0.014
Relative | 34.930 ± 0.604 | 34.257 ± 0.557 | 34.665 ± 0.618 | 33.786 ± 0.758 | 35.041 ± 0.629 | 37.232 ± 0.554*
Lung
Absolute | 1.34 ± 0.06 | 1.32 ± 0.06 | 1.39 ± 0.05 | 1.21 ± 0.04 | 1.29 ± 0.04 | 1.20 ± 0.06
Relative | 7.119 ± 0.275 | 7.190 ± 0.332 | 7.531 ± 0.202 | 6.876 ± 0.207 | 7.236 ± 0.159 | 6.814 ± 0.262
Spleen
Absolute | 0.495 ± 0.010 | 0.453 ± 0.011 | 0.473 ± 0.020 | 0.457 ± 0.008 | 0.468 ± 0.009 | 0.464 ± 0.009
Relative | 2.630 ± 0.045 | 2.463 ± 0.041 | 2.577 ± 0.117 | 2.598 ± 0.050 | 2.627 ± 0.058 | 2.647 ± 0.060
Thymus
Absolute | 0.277 ± 0.006 | 0.265 ± 0.015 | 0.253 ± 0.009 | 0.251 ± 0.008 | 0.230 ± 0.009** | 0.235 ± 0.015**
Relative | 1.474 ± 0.028 | 1.433 ± 0.064 | 1.376 ± 0.050 | 1.428 ± 0.044 | 1.289 ± 0.050* | 1.334 ± 0.075*

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Wistar Han Rats at the Three-month Interim Evaluation in the Two-year Gavage Study of Green Tea Extract^a^

| Vehicle Control | 1,000 mg/kg
n | 10 | 10
Male
Necropsy body wt | 391 ± 9 | 379 ± 13
Heart
Absolute | 1.13 ± 0.04 | 1.11 ± 0.05
Relative | 2.88 ± 0.07 | 2.93 ± 0.05
R. Kidney
Absolute | 1.28 ± 0.05 | 1.37 ± 0.05
Relative | 3.26 ± 0.08 | 3.61 ± 0.08**
Liver
Absolute | 14.33 ± 0.52 | 13.85 ± 0.58
Relative | 36.59 ± 0.90 | 36.54 ± 0.67
Lung
Absolute | 1.93 ± 0.08 | 2.03 ± 0.10
Relative | 4.92 ± 0.18 | 5.41 ± 0.29
R. Testis
Absolute | 1.893 ± 0.050 | 1.894 ± 0.054
Relative | 4.867 ± 0.186 | 5.020 ± 0.092
Thymus
Absolute | 0.392 ± 0.024 | 0.365 ± 0.025
Relative | 0.998 ± 0.047 | 0.966 ± 0.068
Female
Necropsy body wt | 228 ± 3 | 227 ± 5
Heart
Absolute | 0.75 ± 0.02 | 0.77 ± 0.02
Relative | 3.29 ± 0.09 | 3.41 ± 0.08
R. Kidney
Absolute | 0.84 ± 0.02 | 0.88 ± 0.03
Relative | 3.67 ± 0.07 | 3.85 ± 0.07
Liver
Absolute | 8.39 ± 0.24 | 8.75 ± 0.023
Relative | 36.78 ± 0.84 | 38.64 ± 1.13
Lung
Absolute | 1.45 ± 0.05 | 1.48 ± 0.06
Relative | 6.34 ± 0.18 | 6.53 ± 0.23
Thymus
Absolute | 0.370 ± 0.015 | 0.312 ± 0.023*
Relative | 1.625 ± 0.064 | 1.369 ± 0.082*

* Significantly different (P ≤ 0.05) from the vehicle control group by a t-test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error

Table G-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Gavage Study of Green Tea Extract^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 4
Necropsy body wt | 40.7 ± 1.0 | 38.5 ± 1.1 | 39.4 ± 1.0 | 35.4 ± 0.9** | 34.1 ± 0.9** | 30.8 ± 0.9**
Heart
Absolute | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.21 ± 0.01 | 0.20 ± 0.01 | 0.21 ± 0.01 | 0.19 ± 0.01
Relative | 5.316 ± 0.217 | 5.780 ± 0.246 | 5.435 ± 0.303 | 5.542 ± 0.242 | 6.158 ± 0.324 | 6.291 ± 0.504
R. Kidney
Absolute | 0.31 ± 0.01 | 0.31 ± 0.01 | 0.31 ± 0.01 | 0.29 ± 0.01 | 0.27 ± 0.01** | 0.30 ± 0.01*
Relative | 7.535 ± 0.142 | 8.096 ± 0.129 | 7.794 ± 0.135 | 8.187 ± 0.156* | 7.943 ± 0.181* | 9.573 ± 0.235**
Liver
Absolute | 1.79 ± 0.06 | 1.74 ± 0.06 | 1.66 ± 0.07 | 1.46 ± 0.05** | 1.49 ± 0.05** | 1.51 ± 0.09**
Relative | 43.913 ± 0.537 | 45.215 ± 0.723 | 42.085 ± 0.909 | 41.215 ± 0.536 | 43.595 ± 0.757 | 48.868 ± 1.938**
Lung
Absolute | 0.28 ± 0.02 | 0.32 ± 0.02 | 0.29 ± 0.02 | 0.29 ± 0.02 | 0.27 ± 0.02 | 0.27 ± 0.02
Relative | 6.968 ± 0.551 | 8.288 ± 0.443 | 7.381 ± 0.563 | 8.035 ± 0.616 | 7.885 ± 0.497 | 8.879 ± 0.857
Spleen
Absolute | 0.070 ± 0.002 | 0.071 ± 0.003 | 0.072 ± 0.004 | 0.067 ± 0.001 | 0.067 ± 0.002 | 0.072 ± 0.003
Relative | 1.709 ± 0.027 | 1.855 ± 0.046 | 1.826 ± 0.086 | 1.900 ± 0.047* | 1.981 ± 0.055** | 2.345 ± 0.086**
R. Testis
Absolute | 0.119 ± 0.002 | 0.118 ± 0.002 | 0.119 ± 0.002 | 0.119 ± 0.002 | 0.119 ± 0.002 | 0.117 ± 0.004
Relative | 2.929 ± 0.087 | 3.072 ± 0.085 | 3.022 ± 0.070 | 3.366 ± 0.080** | 3.499 ± 0.102** | 3.789 ± 0.170**
Thymus
Absolute | 0.056 ± 0.005 | 0.055 ± 0.003 | 0.057 ± 0.004 | 0.050 ± 0.003 | 0.047 ± 0.002 | 0.037 ± 0.003**
Relative | 1.358 ± 0.100 | 1.418 ± 0.074 | 1.437 ± 0.071 | 1.418 ± 0.072 | 1.375 ± 0.047 | 1.181 ± 0.053
Female
n | 10 | 10 | 10 | 10 | 10 | 6
Necropsy body wt | 30.4 ± 0.6 | 32.9 ± 1.1 | 26.6 ± 0.7** | 26.8 ± 0.7** | 24.3 ± 0.4** | 26.2 ± 0.3**
Heart
Absolute | 0.17 ± 0.01 | 0.18 ± 0.01 | 0.15 ± 0.01 | 0.16 ± 0.00 | 0.15 ± 0.01 | 0.16 ± 0.01
Relative | 5.518 ± 0.219 | 5.606 ± 0.228 | 5.664 ± 0.203 | 5.984 ± 0.145 | 6.306 ± 0.282 | 5.930 ± 0.364
R. Kidney
Absolute | 0.17 ± 0.00 | 0.18 ± 0.00* | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.16 ± 0.01 | 0.17 ± 0.01
Relative | 5.506 ± 0.138 | 5.613 ± 0.186 | 6.081 ± 0.159* | 6.013 ± 0.174* | 6.486 ± 0.158** | 6.535 ± 0.276**
Liver
Absolute | 1.23 ± 0.03 | 1.39 ± 0.04** | 1.15 ± 0.04 | 1.09 ± 0.03* | 1.04 ± 0.03** | 1.36 ± 0.03
Relative | 40.493 ± 0.710 | 42.256 ± 0.415 | 43.110 ± 0.447 | 40.712 ± 0.973 | 42.658 ± 0.753* | 52.036 ± 1.236**
Lung
Absolute | 0.28 ± 0.01 | 0.30 ± 0.01 | 0.28 ± 0.02 | 0.30 ± 0.01 | 0.30 ± 0.01 | 0.29 ± 0.01
Relative | 9.209 ± 0.538 | 9.152 ± 0.402 | 10.686 ± 0.803 | 11.236 ± 0.529* | 12.148 ± 0.382** | 11.149 ± 0.546**
Spleen
Absolute | 0.078 ± 0.002 | 0.094 ± 0.004** | 0.081 ± 0.004 | 0.079 ± 0.003 | 0.076 ± 0.003 | 0.089 ± 0.004
Relative | 2.589 ± 0.080 | 2.888 ± 0.144 | 3.077 ± 0.152* | 2.946 ± 0.119* | 3.140 ± 0.123** | 3.391 ± 0.185**
Thymus
Absolute | 0.061 ± 0.002 | 0.066 ± 0.004 | 0.055 ± 0.002 | 0.055 ± 0.002 | 0.047 ± 0.002** | 0.055 ± 0.004*
Relative | 2.005 ± 0.064 | 2.015 ± 0.103 | 2.057 ± 0.067 | 2.032 ± 0.064 | 1.912 ± 0.077 | 2.117 ± 0.146

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).