# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for F344/NTac Rats in the Three-month Gavage Study of Green Tea Extract^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
Hematology
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 9 | 10 | 10 | 10 | 10 | 10
Hematocrit (%)
Day 4 | 44.3 ± 0.4 | 44.9 ± 0.2 | 45.6 ± 0.5 | 46.2 ± 0.5* | 44.7 ± 0.4 | 46.4 ± 0.5*
Day 23 | 47.1 ± 0.4 | 46.3 ± 0.4 | 47.7 ± 0.4 | 46.5 ± 0.8 | 45.9 ± 0.6 | 47.4 ± 0.8
Week 14 | 45.5 ± 0.6 | 44.5 ± 0.3 | 45.4 ± 0.4 | 45.3 ± 0.2 | 45.7 ± 0.4 | 45.6 ± 0.4
Hemoglobin (g/dL)
Day 4 | 13.4 ± 0.1 | 13.6 ± 0.1 | 13.8 ± 0.2 | 13.9 ± 0.1 | 13.4 ± 0.1 | 13.9 ± 0.2*
Day 23 | 15.5 ± 0.2 | 15.0 ± 0.2 | 15.3 ± 0.1 | 15.1 ± 0.2 | 14.8 ± 0.2 | 15.3 ± 0.3
Week 14 | 15.3 ± 0.2 | 15.0 ± 0.1 | 15.2 ± 0.1 | 15.1 ± 0.1 | 15.4 ± 0.1 | 15.5 ± 0.1
Erythrocytes (10^6^/μL)
Day 4 | 7.24 ± 0.08 | 7.42 ± 0.04 | 7.48 ± 0.08 | 7.57 ± 0.11 | 7.33 ± 0.08 | 7.53 ± 0.11
Day 23 | 8.25 ± 0.07 | 8.19 ± 0.07 | 8.29 ± 0.09 | 8.22 ± 0.16 | 8.11 ± 0.10 | 8.37 ± 0.17
Week 14 | 9.42 ± 0.14 | 9.18 ± 0.05 | 9.34 ± 0.06 | 9.34 ± 0.05 | 9.35 ± 0.07 | 9.46 ± 0.09
Reticulocytes (10^6^/μL)
Day 4 | 590.6 ± 17.1 | 511.6 ± 29.7 | 510.3 ± 31.2 | 533.4 ± 18.6 | 534.7 ± 24.9 | 485.3 ± 16.2**
Day 23 | 320.5 ± 14.9 | 303.9 ± 7.7 | 340.0 ± 11.2 | 336.9 ± 24.9 | 331.9 ± 18.1 | 334.5 ± 13.2
Week 14 | 227.0 ± 7.1 | 210.8 ± 8.4 | 211.0 ± 3.8 | 224.7 ± 7.0 | 221.7 ± 4.4 | 168.7 ± 10.8**
Mean cell volume (fL)
Day 4 | 61.3 ± 0.3 | 60.5 ± 0.3 | 61.0 ± 0.3 | 61.0 ± 0.4 | 61.1 ± 0.3 | 61.6 ± 0.4
Day 23 | 57.2 ± 0.2 | 56.6 ± 0.3 | 57.5 ± 0.2 | 56.5 ± 0.3 | 56.6 ± 0.3 | 56.7 ± 0.4
Week 14 | 48.3 ± 0.3 | 48.5 ± 0.2 | 48.7 ± 0.3 | 48.4 ± 0.2 | 48.9 ± 0.2 | 48.2 ± 0.2
Mean cell hemoglobin (pg)
Day 4 | 18.5 ± 0.1 | 18.3 ± 0.1 | 18.4 ± 0.1 | 18.4 ± 0.1 | 18.3 ± 0.1 | 18.5 ± 0.1
Day 23 | 18.7 ± 0.1 | 18.3 ± 0.1 | 18.5 ± 0.1 | 18.4 ± 0.1 | 18.3 ± 0.1* | 18.3 ± 0.1*
Week 14 | 16.2 ± 0.1 | 16.3 ± 0.1 | 16.3 ± 0.1 | 16.2 ± 0.1 | 16.5 ± 0.1 | 16.4 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 30.1 ± 0.2 | 30.2 ± 0.1 | 30.2 ± 0.2 | 30.1 ± 0.1 | 30.0 ± 0.1 | 30.0 ± 0.2
Day 23 | 32.8 ± 0.2 | 32.3 ± 0.1 | 32.1 ± 0.2 | 32.5 ± 0.2 | 32.3 ± 0.2 | 32.3 ± 0.3
Week 14 | 33.6 ± 0.2 | 33.6 ± 0.2 | 33.5 ± 0.1 | 33.4 ± 0.2 | 33.6 ± 0.1 | 33.9 ± 0.1
Platelets (10^3^/μL)
Day 4 | 1,129.3 ± 42.9 | 1,176.7 ± 37.5 | 1,181.8 ± 47.9 | 1,172.9 ± 40.6 | 1,237.7 ± 36.8 | 1,232.3 ± 38.9
Day 23 | 899.7 ± 60.3 | 946.7 ± 48.5 | 893.8 ± 62.7 | 975.9 ± 65.2 | 1,015.7 ± 52.2 | 936.4 ± 70.9
Week 14 | 695.0 ± 63.4 | 715.1 ± 13.5 | 736.3 ± 15.8 | 769.5 ± 22.3 | 769.4 ± 25.1 | 799.0 ± 40.0
Leukocytes (10^3^/μL)
Day 4 | 7.75 ± 0.18 | 7.09 ± 0.37 | 7.20 ± 0.29 | 7.60 ± 0.51 | 6.57 ± 0.22** | 7.11 ± 0.29
Day 23 | 6.99 ± 0.57 | 6.60 ± 0.60 | 6.91 ± 0.46 | 8.41 ± 0.40 | 7.92 ± 0.67 | 6.65 ± 0.49
Week 14 | 6.95 ± 0.44 | 5.28 ± 0.47 | 6.04 ± 0.49 | 5.73 ± 0.46 | 6.31 ± 0.40 | 7.84 ± 0.41
Segmented neutrophils (10^3^/μL)
Day 4 | 1.27 ± 0.05 | 1.46 ± 0.08 | 1.43 ± 0.13 | 1.83 ± 0.30 | 1.43 ± 0.05 | 1.55 ± 0.13
Day 23 | 1.25 ± 0.11 | 1.52 ± 0.21 | 1.46 ± 0.07 | 2.43 ± 0.32** | 2.84 ± 0.52** | 1.98 ± 0.29**
Week 14 | 1.53 ± 0.12 | 1.11 ± 0.10 | 1.11 ± 0.09 | 1.43 ± 0.12 | 1.64 ± 0.13 | 2.03 ± 0.15
Lymphocytes (10^3^/μL)
Day 4 | 6.12 ± 0.18 | 5.27 ± 0.31* | 5.41 ± 0.24* | 5.43 ± 0.24* | 4.81 ± 0.22** | 5.23 ± 0.23**
Day 23 | 5.43 ± 0.47 | 4.77 ± 0.47 | 5.11 ± 0.41 | 5.59 ± 0.33 | 4.75 ± 0.44 | 4.43 ± 0.29
Week 14 | 5.12 ± 0.34 | 3.97 ± 0.40 | 4.69 ± 0.42 | 4.08 ± 0.36 | 4.41 ± 0.38 | 5.53 ± 0.36
Monocytes (10^3^/μL)
Day 4 | 0.24 ± 0.01 | 0.23 ± 0.03 | 0.24 ± 0.02 | 0.23 ± 0.03 | 0.22 ± 0.04 | 0.23 ± 0.03
Day 23 | 0.13 ± 0.02 | 0.12 ± 0.02 | 0.16 ± 0.02 | 0.20 ± 0.02 | 0.16 ± 0.02 | 0.13 ± 0.02
Week 14 | 0.17 ± 0.02 | 0.11 ± 0.02 | 0.13 ± 0.01 | 0.14 ± 0.02 | 0.16 ± 0.01 | 0.20 ± 0.02
Basophils (10^3^/μL)
Day 4 | 0.064 ± 0.008 | 0.060 ± 0.009 | 0.061 ± 0.010 | 0.047 ± 0.005 | 0.052 ± 0.006 | 0.054 ± 0.005
Day 23 | 0.055 ± 0.004 | 0.036 ± 0.007 | 0.073 ± 0.015 | 0.057 ± 0.008 | 0.045 ± 0.005 | 0.031 ± 0.005*
Week 14 | 0.022 ± 0.004 | 0.018 ± 0.003 | 0.023 ± 0.004 | 0.021 ± 0.003 | 0.024 ± 0.003 | 0.025 ± 0.004
Eosinophils (10^3^/μL)
Day 4 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.01 | 0.05 ± 0.00
Day 23 | 0.12 ± 0.02 | 0.15 ± 0.04 | 0.11 ± 0.01 | 0.14 ± 0.03 | 0.12 ± 0.02 | 0.08 ± 0.01
Week 14 | 0.10 ± 0.02 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 9.1 ± 0.3 | 10.1 ± 0.2 | 9.3 ± 0.4 | 10.4 ± 0.5 | 8.2 ± 0.5 | 9.9 ± 0.8
Day 23 | 17.5 ± 0.5 | 12.7 ± 0.6** | 13.6 ± 1.1** | 13.2 ± 1.0** | 10.6 ± 0.6** | 11.6 ± 0.5**
Week 14 | 15.1 ± 0.7 | 15.2 ± 0.6 | 15.2 ± 0.6 | 13.2 ± 0.6 | 15.2 ± 0.7 | 15.1 ± 0.9
Creatinine (mg/dL)
Day 4 | 0.48 ± 0.01 | 0.50 ± 0.00 | 0.49 ± 0.01 | 0.51 ± 0.01* | 0.51 ± 0.01* | 0.52 ± 0.01*
Day 23 | 0.55 ± 0.02 | 0.58 ± 0.01 | 0.58 ± 0.01 | 0.60 ± 0.01 | 0.59 ± 0.01 | 0.60 ± 0.01
Week 14 | 0.61 ± 0.01 | 0.62 ± 0.01 | 0.67 ± 0.02* | 0.64 ± 0.02 | 0.63 ± 0.02 | 0.63 ± 0.02
Serum glucose (mg/dL)
Day 4 | 136 ± 2 | 129 ± 2 | 132 ± 4 | 132 ± 4 | 125 ± 3* | 132 ± 3
Day 23 | 142 ± 5 | 135 ± 2 | 131 ± 3 | 135 ± 3 | 134 ± 4 | 135 ± 3
Week 14 | 134 ± 4 | 135 ± 2 | 135 ± 3 | 137 ± 5 | 128 ± 3 | 134 ± 5
Total protein (g/dL)
Day 4 | 5.6 ± 0.0 | 5.6 ± 0.1 | 5.8 ± 0.1 | 5.8 ± 0.1* | 5.8 ± 0.1 | 5.8 ± 0.1
Day 23 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.7 ± 0.1 | 6.5 ± 0.1 | 6.6 ± 0.1 | 6.6 ± 0.1
Week 14 | 7.2 ± 0.1 | 7.1 ± 0.0 | 7.1 ± 0.0 | 6.9 ± 0.0** | 7.0 ± 0.1* | 6.8 ± 0.1**
Albumin (g/dL)
Day 4 | 4.1 ± 0.0 | 4.1 ± 0.0 | 4.2 ± 0.1 | 4.2 ± 0.0 | 4.2 ± 0.1 | 4.2 ± 0.1
Day 23 | 4.6 ± 0.0 | 4.5 ± 0.0 | 4.6 ± 0.0 | 4.4 ± 0.0* | 4.5 ± 0.1 | 4.6 ± 0.1
Week 14 | 4.6 ± 0.1 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.5 ± 0.0 | 4.5 ± 0.1 | 4.5 ± 0.1
Alanine aminotransferase (IU/L)
Day 4 | 61 ± 2 | 64 ± 2 | 64 ± 3 | 74 ± 6 | 71 ± 2** | 72 ± 5*
Day 23 | 54 ± 2 | 55 ± 2 | 61 ± 1 | 52 ± 2 | 66 ± 2** | 63 ± 3**
Week 14 | 70 ± 4 | 81 ± 7 | 73 ± 5 | 62 ± 1 | 59 ± 2 | 75 ± 2
Alkaline phosphatase (IU/L)
Day 4 | 652 ± 10 | 631 ± 16 | 636 ± 17 | 637 ± 16 | 653 ± 18 | 667 ± 29
Day 23 | 447 ± 24 | 523 ± 8* | 561 ± 10** | 515 ± 15* | 556 ± 21** | 602 ± 28**
Week 14 | 243 ± 4 | 245 ± 6 | 236 ± 5 | 230 ± 4 | 202 ± 5** | 215 ± 11**
Creatine kinase (IU/L)
Day 4 | 334 ± 25 | 515 ± 49* | 488 ± 93 | 668 ± 83** | 431 ± 38 | 529 ± 53*
Day 23 | 248 ± 25 | 384 ± 53 | 420 ± 40* | 426 ± 59* | 355 ± 48 | 369 ± 44
Week 14 | 448 ± 106 | 520 ± 82 | 380 ± 74 | 491 ± 83 | 340 ± 34 | 508 ± 57
Sorbitol dehydrogenase (IU/L)
Day 4 | 13 ± 0 | 13 ± 1 | 14 ± 1 | 15 ± 2 | 15 ± 1 | 15 ± 2
Day 23 | 16 ± 1 | 16 ± 1 | 18 ± 1 | 16 ± 1 | 15 ± 1 | 16 ± 0
Week 14 | 23 ± 2 | 28 ± 5 | 26 ± 1 | 20 ± 1 | 20 ± 2 | 19 ± 2
Bile salts (µmol/L)
Day 4 | 23.6 ± 2.2 | 31.3 ± 2.7 | 21.7 ± 3.3 | 21.3 ± 3.3 | 14.1 ± 2.6 | 18.8 ± 3.1
Day 23 | 13.3 ± 2.1 | 14.6 ± 1.2 | 9.2 ± 0.7 | 13.8 ± 2.4 | 14.6 ± 2.4 | 13.3 ± 1.3
Week 14 | 8.7 ± 1.9 | 7.8 ± 1.2 | 8.6 ± 1.1 | 13.6 ± 1.8* | 14.3 ± 1.7* | 44.3 ± 6.6**
Female
Hematology
n
Day 4 | 10 | 10 | 9 | 10 | 10 | 9
Day 23 | 10 | 10 | 8 | 10 | 10 | 10
Week 14 | 10 | 9 | 9 | 10 | 9 | 10
Hematocrit (%)
Day 4 | 45.7 ± 0.7 | 46.4 ± 0.6 | 47.3 ± 0.6 | 46.5 ± 0.8 | 48.1 ± 0.3** | 48.7 ± 0.8**
Day 23 | 44.5 ± 0.3 | 44.6 ± 0.4 | 44.9 ± 0.3 | 45.6 ± 0.8 | 45.4 ± 0.6 | 44.5 ± 0.3
Week 14 | 44.1 ± 0.3 | 43.8 ± 0.4 | 43.6 ± 0.5 | 43.1 ± 0.3 | 43.2 ± 0.5 | 44.7 ± 0.9
Hemoglobin (g/dL)
Day 4 | 14.0 ± 0.2 | 14.2 ± 0.2 | 14.5 ± 0.2 | 14.1 ± 0.3 | 14.7 ± 0.2* | 14.9 ± 0.3*
Day 23 | 15.3 ± 0.1 | 15.3 ± 0.1 | 15.4 ± 0.1 | 15.4 ± 0.2 | 15.3 ± 0.2 | 15.1 ± 0.2
Week 14 | 15.1 ± 0.1 | 15.1 ± 0.1 | 14.9 ± 0.1 | 14.8 ± 0.1 | 14.7 ± 0.2 | 15.3 ± 0.3
Erythrocytes (10^6^/μL)
Day 4 | 7.67 ± 0.13 | 7.77 ± 0.09 | 7.90 ± 0.10 | 7.70 ± 0.13 | 8.06 ± 0.08* | 8.18 ± 0.13*
Day 23 | 8.11 ± 0.05 | 8.12 ± 0.06 | 8.14 ± 0.09 | 8.26 ± 0.12 | 8.28 ± 0.10 | 8.20 ± 0.06
Week 14 | 8.60 ± 0.05 | 8.62 ± 0.06 | 8.56 ± 0.08 | 8.48 ± 0.06 | 8.46 ± 0.08 | 8.83 ± 0.17
Reticulocytes (10^6^/μL)
Day 4 | 442.9 ± 28.5 | 429.2 ± 17.8 | 424.5 ± 21.1 | 465.5 ± 22.8 | 447.4 ± 24.1 | 448.4 ± 25.4
Day 23 | 200.8 ± 7.5 | 200.2 ± 6.4 | 196.2 ± 7.6 | 213.7 ± 11.1 | 208.8 ± 15.8 | 236.2 ± 16.0
Week 14 | 199.0 ± 9.1 | 176.3 ± 10.2 | 181.3 ± 12.3 | 182.8 ± 5.0 | 217.8 ± 9.8 | 189.9 ± 9.6
Mean cell volume (fL)
Day 4 | 59.7 ± 0.3 | 59.7 ± 0.3 | 59.9 ± 0.2 | 60.3 ± 0.3 | 59.7 ± 0.3 | 59.5 ± 0.4
Day 23 | 55.0 ± 0.2 | 54.9 ± 0.2 | 55.2 ± 0.2 | 55.2 ± 0.3 | 54.8 ± 0.3 | 54.3 ± 0.3
Week 14 | 51.4 ± 0.3 | 50.8 ± 0.2 | 50.9 ± 0.3 | 50.9 ± 0.2 | 51.0 ± 0.2 | 50.6 ± 0.3
Mean cell hemoglobin (pg)
Day 4 | 18.3 ± 0.1 | 18.2 ± 0.1 | 18.3 ± 0.1 | 18.2 ± 0.1 | 18.2 ± 0.1 | 18.2 ± 0.2
Day 23 | 18.9 ± 0.1 | 18.9 ± 0.1 | 18.9 ± 0.1 | 18.7 ± 0.1 | 18.5 ± 0.1* | 18.5 ± 0.2
Week 14 | 17.6 ± 0.1 | 17.5 ± 0.1 | 17.4 ± 0.1 | 17.5 ± 0.1 | 17.3 ± 0.1 | 17.3 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 30.6 ± 0.2 | 30.5 ± 0.2 | 30.6 ± 0.2 | 30.2 ± 0.1 | 30.6 ± 0.2 | 30.6 ± 0.2
Day 23 | 34.4 ± 0.1 | 34.3 ± 0.2 | 34.3 ± 0.2 | 33.9 ± 0.2 | 33.8 ± 0.2 | 34.0 ± 0.3
Week 14 | 34.2 ± 0.1 | 34.4 ± 0.2 | 34.2 ± 0.2 | 34.4 ± 0.1 | 34.0 ± 0.2 | 34.2 ± 0.2
Platelets (10^3^/μL)
Day 4 | 1,029.0 ± 40.5 | 1,031.8 ± 45.0 | 943.7 ± 46.9 | 1,019.7 ± 29.8 | 1,004.4 ± 49.0 | 1,017.0 ± 47.1
Day 23 | 851.5 ± 25.0 | 870.9 ± 51.7 | 842.1 ± 38.9 | 874.0 ± 13.5 | 959.7 ± 34.3 | 901.8 ± 51.1
Week 14 | 748.7 ± 30.7 | 763.0 ± 16.7 | 799.8 ± 38.2 | 807.8 ± 29.7 | 799.4 ± 26.2 | 812.8 ± 30.3
Leukocytes (10^3^/μL)
Day 4 | 7.96 ± 0.28 | 7.84 ± 0.30 | 6.82 ± 0.53 | 7.61 ± 0.31 | 6.82 ± 0.56 | 6.52 ± 0.60
Day 23 | 6.60 ± 0.27 | 5.29 ± 0.47 | 5.44 ± 0.59 | 5.70 ± 0.41 | 6.32 ± 0.44 | 5.75 ± 0.53
Week 14 | 5.93 ± 0.25 | 4.56 ± 0.27 | 5.49 ± 0.66 | 5.55 ± 0.59 | 5.98 ± 0.60 | 6.55 ± 0.56
Segmented neutrophils (10^3^/μL)
Day 4 | 1.24 ± 0.08 | 1.15 ± 0.09 | 1.11 ± 0.09 | 1.18 ± 0.07 | 1.18 ± 0.09 | 1.30 ± 0.17
Day 23 | 1.37 ± 0.08 | 1.26 ± 0.22 | 1.33 ± 0.22 | 1.44 ± 0.21 | 1.51 ± 0.12 | 2.06 ± 0.32
Week 14 | 1.40 ± 0.11 | 1.11 ± 0.12 | 1.33 ± 0.22 | 1.26 ± 0.12 | 1.35 ± 0.20 | 1.62 ± 0.16
Lymphocytes (10^3^/μL)
Day 4 | 6.33 ± 0.25 | 6.30 ± 0.27 | 5.36 ± 0.42 | 6.07 ± 0.26 | 5.27 ± 0.50* | 4.91 ± 0.55*
Day 23 | 4.96 ± 0.21 | 3.79 ± 0.39 | 3.89 ± 0.39 | 4.00 ± 0.44 | 4.58 ± 0.43 | 3.44 ± 0.29**
Week 14 | 4.26 ± 0.17 | 3.28 ± 0.20 | 3.93 ± 0.42 | 4.08 ± 0.48 | 4.40 ± 0.42 | 4.63 ± 0.41
Monocytes (10^3^/μL)
Day 4 | 0.24 ± 0.01 | 0.25 ± 0.03 | 0.19 ± 0.03 | 0.22 ± 0.02 | 0.21 ± 0.01 | 0.18 ± 0.02
Day 23 | 0.14 ± 0.01 | 0.10 ± 0.01 | 0.11 ± 0.02 | 0.10 ± 0.01 | 0.12 ± 0.02 | 0.12 ± 0.02
Week 14 | 0.16 ± 0.01 | 0.11 ± 0.01 | 0.15 ± 0.03 | 0.13 ± 0.02 | 0.14 ± 0.03 | 0.21 ± 0.05
Basophils (10^3^/μL)
Day 4 | 0.062 ± 0.007 | 0.061 ± 0.007 | 0.056 ± 0.010 | 0.069 ± 0.007 | 0.055 ± 0.006 | 0.046 ± 0.006
Day 23 | 0.029 ± 0.003 | 0.023 ± 0.003 | 0.019 ± 0.002 | 0.024 ± 0.003 | 0.023 ± 0.004 | 0.017 ± 0.003*
Week 14 | 0.022 ± 0.004 | 0.011 ± 0.002 | 0.026 ± 0.007 | 0.025 ± 0.005 | 0.020 ± 0.005 | 0.020 ± 0.003
Eosinophils (10^3^/μL)
Day 4 | 0.08 ± 0.01 | 0.08 ± 0.02 | 0.10 ± 0.02 | 0.08 ± 0.02 | 0.11 ± 0.03 | 0.09 ± 0.01
Day 23 | 0.11 ± 0.01 | 0.12 ± 0.02 | 0.09 ± 0.02 | 0.13 ± 0.03 | 0.09 ± 0.02 | 0.13 ± 0.02
Week 14 | 0.05 ± 0.01 | 0.05 ± 0.00 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.01
Clinical Chemistry
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 9 | 10 | 10 | 10
Week 14 | 10 | 10 | 9 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 10.1 ± 0.3 | 10.3 ± 0.4 | 9.7 ± 0.5 | 8.7 ± 0.6^b^ | 8.9 ± 0.3 | 9.3 ± 0.6^b^
Day 23 | 13.3 ± 0.5 | 13.4 ± 0.4 | 12.2 ± 0.5 | 11.7 ± 0.6 | 11.4 ± 0.4 | 12.5 ± 1.0
Week 14 | 13.6 ± 0.5 | 14.9 ± 0.6 | 14.6 ± 0.3 | 13.8 ± 0.6 | 11.1 ± 0.8 | 14.2 ± 1.2
Creatinine (mg/dL)
Day 4 | 0.46 ± 0.02 | 0.46 ± 0.02 | 0.47 ± 0.02 | 0.43 ± 0.02^b^ | 0.48 ± 0.01 | 0.50 ± 0.02^b^
Day 23 | 0.50 ± 0.00 | 0.55 ± 0.02 | 0.52 ± 0.02 | 0.57 ± 0.02* | 0.59 ± 0.01** | 0.54 ± 0.02
Week 14 | 0.65 ± 0.03 | 0.62 ± 0.02 | 0.61 ± 0.01 | 0.63 ± 0.02 | 0.63 ± 0.02 | 0.63 ± 0.02
Serum glucose (mg/dL)
Day 4 | 129 ± 2^c^ | 133 ± 3^b^ | 131 ± 3 | 123 ± 2^c^ | 123 ± 2^d^ | 122 ± 3^d^
Day 23 | 136 ± 2 | 144 ± 2 | 138 ± 6 | 137 ± 4 | 128 ± 3 | 136 ± 3
Week 14 | 129 ± 5 | 141 ± 6 | 134 ± 5 | 128 ± 4 | 131 ± 5 | 140 ± 9
Total protein (g/dL)
Day 4 | 5.7 ± 0.1^c^ | 5.7 ± 0.1^b^ | 5.8 ± 0.1 | 5.8 ± 0.1^c^ | 5.8 ± 0.1^d^ | 5.8 ± 0.1^d^
Day 23 | 6.2 ± 0.1 | 6.2 ± 0.1 | 6.2 ± 0.1 | 6.3 ± 0.1 | 6.2 ± 0.1 | 6.0 ± 0.1
Week 14 | 7.4 ± 0.1 | 7.1 ± 0.1 | 7.1 ± 0.1 | 6.8 ± 0.1** | 6.7 ± 0.1** | 6.6 ± 0.1**
Albumin (g/dL)
Day 4 | 4.2 ± 0.0^c^ | 4.2 ± 0.0^b^ | 4.3 ± 0.1* | 4.3 ± 0.1^c^ | 4.3 ± 0.1^d^ | 4.3 ± 0.0^d^
Day 23 | 4.5 ± 0.0 | 4.5 ± 0.0 | 4.5 ± 0.1 | 4.6 ± 0.1 | 4.5 ± 0.0 | 4.4 ± 0.0**
Week 14 | 5.0 ± 0.1 | 4.8 ± 0.1 | 4.8 ± 0.0 | 4.6 ± 0.1** | 4.6 ± 0.0** | 4.6 ± 0.1**
Alanine aminotransferase (IU/L)
Day 4 | 58 ± 2 | 60 ± 3 | 62 ± 2 | 63 ± 2 | 71 ± 3** | 73 ± 4**
Day 23 | 38 ± 1 | 41 ± 1 | 48 ± 2** | 45 ± 2** | 42 ± 1* | 58 ± 3**
Week 14 | 54 ± 3 | 58 ± 3 | 49 ± 3 | 56 ± 3 | 55 ± 3 | 837 ± 772
Alkaline phosphatase (IU/L)
Day 4 | 552 ± 11 | 550 ± 11 | 540 ± 11 | 575 ± 11 | 558 ± 12 | 520 ± 14
Day 23 | 380 ± 9 | 394 ± 6 | 406 ± 8* | 432 ± 13** | 457 ± 9** | 435 ± 14**
Week 14 | 209 ± 3 | 217 ± 8 | 196 ± 3 | 202 ± 6 | 199 ± 3 | 228 ± 9
Creatine kinase (IU/L)
Day 4 | 434 ± 29^c^ | 597 ± 62^b^ | 422 ± 55 | 449 ± 39^c^ | 583 ± 95^d^ | 501 ± 83^d^
Day 23 | 244 ± 23 | 274 ± 30 | 292 ± 34 | 282 ± 39 | 244 ± 27 | 366 ± 48
Week 14 | 304 ± 41 | 481 ± 63 | 379 ± 104 | 360 ± 77 | 439 ± 85 | 615 ± 120
Sorbitol dehydrogenase (IU/L)
Day 4 | 13 ± 1 | 13 ± 0 | 13 ± 1 | 14 ± 1 | 13 ± 1 | 14 ± 1
Day 23 | 16 ± 1 | 16 ± 1 | 16 ± 1 | 17 ± 1 | 16 ± 1 | 15 ± 0
Week 14 | 18 ± 1 | 16 ± 1 | 15 ± 1 | 16 ± 1 | 15 ± 1 | 16 ± 1
Bile salts (µmol/L)
Day 4 | 14.7 ± 2.2 | 14.9 ± 1.7 | 13.4 ± 2.2 | 19.6 ± 2.6 | 17.6 ± 3.0 | 17.7 ± 4.3
Day 23 | 9.3 ± 1.1 | 9.1 ± 1.1 | 10.9 ± 1.8 | 7.8 ± 1.0 | 7.5 ± 1.1 | 12.9 ± 1.8
Week 14 | 9.4 ± 1.3 | 10.2 ± 1.7 | 9.7 ± 0.8 | 14.8 ± 2.7 | 17.9 ± 3.2* | 46.3 ± 26.2**

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 8.

^d^ n = 7.

Table F-2 Hematology Data for Mice in the Three-month Gavage Study of Green Tea Extract^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 4
Hematocrit (%) | 51.9 ± 1.4 | 51.8 ± 0.5 | 50.8 ± 0.7 | 51.4 ± 0.7 | 50.3 ± 0.7 | 48.7 ± 0.7
Hemoglobin (g/dL) | 16.5 ± 0.5 | 16.5 ± 0.2 | 16.2 ± 0.3 | 16.3 ± 0.3 | 16.0 ± 0.2 | 15.5 ± 0.2
Erythrocytes (10^6^/µL) | 10.76 ± 0.31 | 10.71 ± 0.12 | 10.62 ± 0.16 | 10.68 ± 0.14 | 10.49 ± 0.16 | 10.29 ± 0.16
Reticulocytes (10^6^/µL) | 276.9 ± 11.7 | 279.6 ± 10.2 | 297.0 ± 3.7 | 293.1 ± 9.4 | 291.8 ± 11.9 | 291.1 ± 46.1
Mean cell volume (fL) | 48.3 ± 0.1 | 48.4 ± 0.2 | 47.9 ± 0.2 | 48.1 ± 0.1 | 48.0 ± 0.1 | 47.4 ± 0.2**
Mean cell hemoglobin (pg) | 15.3 ± 0.1 | 15.4 ± 0.1 | 15.2 ± 0.1 | 15.3 ± 0.1 | 15.3 ± 0.1 | 15.0 ± 0.0
Mean cell hemoglobin concentration (g/dL) | 31.7 ± 0.2 | 31.8 ± 0.1 | 31.7 ± 0.2 | 31.8 ± 0.2 | 31.9 ± 0.1 | 31.7 ± 0.1
Platelets (10^3^/µL) | 986.3 ± 69.6 | 924.9 ± 44.5 | 983.2 ± 46.5 | 1,061.7 ± 64.6 | 1,019.5 ± 59.8 | 1,214.3 ± 133.5
Leukocytes (10^3^/µL) | 4.59 ± 0.34 | 4.25 ± 0.35 | 3.81 ± 0.38 | 3.60 ± 0.31 | 4.02 ± 0.31 | 5.02 ± 0.82
Segmented neutrophils (10^3^/µL) | 0.68 ± 0.07 | 0.59 ± 0.09 | 0.57 ± 0.05 | 0.54 ± 0.05 | 0.59 ± 0.06 | 0.63 ± 0.08
Lymphocytes (10^3^/µL) | 3.68 ± 0.28 | 3.47 ± 0.26 | 3.05 ± 0.33 | 2.93 ± 0.25 | 3.29 ± 0.26 | 4.16 ± 0.75
Monocytes (10^3^/µL) | 0.15 ± 0.02 | 0.12 ± 0.02 | 0.11 ± 0.02 | 0.07 ± 0.01** | 0.07 ± 0.01** | 0.10 ± 0.02*
Basophils (10^3^/µL) | 0.012 ± 0.002 | 0.008 ± 0.002 | 0.007 ± 0.002 | 0.004 ± 0.002* | 0.006 ± 0.002 | 0.020 ± 0.006
Eosinophils (10^3^/µL) | 0.07 ± 0.01 | 0.08 ± 0.02 | 0.08 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.11 ± 0.03
Female
n | 9 | 10 | 10 | 9 | 10 | 6
Hematocrit (%) | 51.4 ± 0.8 | 51.3 ± 0.8 | 50.4 ± 0.9 | 53.0 ± 0.8 | 52.2 ± 0.8 | 51.3 ± 1.5
Hemoglobin (g/dL) | 16.7 ± 0.3 | 16.5 ± 0.3 | 16.3 ± 0.3 | 17.1 ± 0.3 | 16.8 ± 0.3 | 16.7 ± 0.6
Erythrocytes (10^6^/µL) | 10.82 ± 0.16 | 10.59 ± 0.15 | 10.54 ± 0.20 | 11.08 ± 0.15 | 10.87 ± 0.15 | 10.77 ± 0.31
Reticulocytes (10^6^/µL) | 265.1 ± 14.6 | 311.9 ± 25.4 | 290.0 ± 18.3 | 302.2 ± 8.8 | 259.0 ± 23.6 | 321.3 ± 12.8
Mean cell volume (fL) | 47.5 ± 0.2 | 48.5 ± 0.1** | 47.8 ± 0.2 | 47.8 ± 0.2 | 48.1 ± 0.3 | 47.6 ± 0.3
Mean cell hemoglobin (pg) | 15.4 ± 0.1 | 15.6 ± 0.1 | 15.5 ± 0.1 | 15.5 ± 0.1 | 15.5 ± 0.1 | 15.5 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 32.4 ± 0.1 | 32.1 ± 0.1 | 32.4 ± 0.1 | 32.3 ± 0.2 | 32.2 ± 0.2 | 32.5 ± 0.3
Platelets (10^3^/µL) | 757.7 ± 56.8 | 732.7 ± 54.6 | 798.2 ± 61.0 | 668.0 ± 56.1 | 785.8 ± 82.1 | 989.3 ± 114.4
Leukocytes (10^3^/µL) | 3.80 ± 0.42 | 3.43 ± 0.28 | 3.68 ± 0.34 | 3.91 ± 0.21 | 3.85 ± 0.21 | 3.54 ± 0.45
Segmented neutrophils (10^3^/µL) | 0.51 ± 0.06 | 0.37 ± 0.04 | 0.44 ± 0.05 | 0.46 ± 0.09 | 0.43 ± 0.04 | 0.55 ± 0.15
Lymphocytes (10^3^/µL) | 3.13 ± 0.35 | 2.95 ± 0.25 | 3.12 ± 0.30 | 3.30 ± 0.17 | 3.27 ± 0.17 | 2.84 ± 0.41
Monocytes (10^3^/µL) | 0.07 ± 0.02 | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.01 | 0.08 ± 0.02
Basophils (10^3^/µL) | 0.010 ± 0.003 | 0.005 ± 0.002 | 0.006 ± 0.002 | 0.011 ± 0.003 | 0.017 ± 0.004 | 0.012 ± 0.005
Eosinophils (10^3^/µL) | 0.08 ± 0.03 | 0.07 ± 0.02 | 0.07 ± 0.01 | 0.06 ± 0.02 | 0.08 ± 0.01 | 0.07 ± 0.02

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.