# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

Testing procedures were modified from those reported by Zeiger et al.^154^ Samples of green tea extract (the same chemical lot that was used in the 3-month and 2-year studies) were sent to the laboratory as coded aliquots. They were incubated with the Salmonella typhimurium tester strains TA98 and TA100 and Escherichia coli strain WP2 uvrA/pKM101 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine (or tryptophan for the E. coli strain) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of green tea extract. The high dose was limited by toxicity. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine- or tryptophan-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

## E.2 Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.^155^ At the end of the 3-month study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in each of four (1,000 mg/kg males) or five mice per dose group. In addition, the percentage of circulating polychromatic erthyrocytes (PCEs; reticulocytes) in 1,000 total erythrocytes per animal was determined to provide a measure of chemical-induced bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose groups using a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the vehicle control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Results of the 3-month study were accepted without repeat tests because additional test data could not be observed. Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## E.3 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## E.4 Results

Green tea extract (50 to 2,000 µg/plate), from the same lot that was tested in the 3-month and 2-year studies, was mutagenic in S. typhimurium strains TA98 and TA100 in the presence of induced rat liver S9; no mutagenicity was observed in these strains without S9 or in the E. coli strain WP2 uvrA/pKM101 (10 to 1,000 µg/plate) with or without S9 (Table E-1). In vivo, no increases in the frequencies of micronucleated NCEs were seen in peripheral blood of male or female B6C3F1/N mice administered green tea extract (62.5 to 1,000 mg/kg per day) for 3 months by gavage; no significant changes were observed in the percentage of PCEs among total erythrocytes in the blood of either males or females, suggesting that green tea extract did not induce bone marrow toxicity (Table E-2).

Table E-1 Mutagenicity of Green Tea Extract in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 65 ± 9 | 39 ± 3 | 73 ± 4 | 51 ± 5 | 69 ± 13
| 50 | 51 ± 2 | 54 ± 2 | 72 ± 10 | 97 ± 9 | 72 ± 3
| 100 | 62 ± 8 | 63 ± 7 | 73 ± 9 | 105 ± 8 | 67 ± 5
| 500 | 64 ± 7 | 55 ± 1 | 70 ± 7 | 108 ± 5 | 124 ± 19
| 1,000 | 45 ± 4 | 45 ± 4 | 47 ± 3 | 149 ± 7 | 120 ± 7
| 2,000 | 28 ± 6 | 7 ± 2 | 121 ± 5 | 130 ± 11 | 126 ± 2
Trial summary | | Negative | Negative | Negative | Positive | Positive
Positive control^b^ | | 459 ± 5 | 617 ± 27 | 740 ± 78 | 768 ± 36 | 670 ± 88
TA98
| 0 | 32 ± 3 | 24 ± 1 | 26 ± 3 | 27 ± 1
| 50 | 36 ± 2 | 26 ± 4 | 31 ± 5 | 36 ± 2
| 100 | 31 ± 5 | 24 ± 1 | 38 ± 2 | 40 ± 2
| 500 | 34 ± 2 | 45 ± 5 | 67 ± 5 | 84 ± 4
| 1,000 | 30 ± 1 | 34 ± 1 | 63 ± 8 | 115 ± 4
| 2,000 | 23 ± 6 | 27 ± 3 | 66 ± 6 | 119 ± 8
Trial summary | | Negative | Negative | Positive | Positive
Positive control | | 413 ± 14 | 429 ± 11 | 840 ± 81 | 649 ± 49
Escherichia coli WP2 uvrA/pKM101 (analogous to TA102)
| | Without S9 | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9 | With 10% Rat S9
| 0 | 135 ± 6 | 153 ± 11 | 208 ± 6 | 180 ± 5 | 149 ± 12 | 220 ± 14
| 10 | 142 ± 7 | 148 ± 3 | 220 ± 6 | 183 ± 11 | 166 ± 9 | 217 ± 3
| 50 | 147 ± 16 | 147 ± 11 | 206 ± 5 | 220 ± 25 | 178 ± 6 | 221 ± 11
| 100 | 133 ± 4 | 158 ± 6 | 211 ± 8 | 174 ± 1 | 177 ± 9 | 271 ± 27
| 500 | Toxic | 116 ± 12 | 146 ± 11 | 130 ± 8 | 130 ± 6 | 153 ± 9
| 1,000 | Toxic | 46 ± 4 | 75 ± 20^c^ | Toxic | 53 ± 12 | 95 ± 4
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 804 ± 31 | 1,101 ± 55 | 724 ± 12 | 821 ± 28 | 734 ± 7 | 789 ± 19

^a^ SITEK Research Laboratories used a modification of the Zeiger et al.^154^ protocol and the same lot (GTE50-A0302031114) that was used in the 3-month and 2-year studies. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

^c^ Slight toxicity.

Table E-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Administration of Green Tea Extract by Gavage for Three Months^a^

| Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Water^d^ | 0 | 5 | 1.90 ± 0.33 | | 4.40 ± 0.18
Green tea extract | 62.5 | 5 | 2.60 ± 0.24 | 0.1481 | 4.54 ± 0.22
| 125 | 5 | 2.20 ± 0.34 | 0.3195 | 4.50 ± 0.24
| 250 | 5 | 1.90 ± 0.43 | 0.5000 | 4.10 ± 0.11
| 500 | 5 | 1.70 ± 0.25 | 0.6307 | 3.72 ± 0.31
| 1,000 | 4 | 1.88 ± 0.24 | 0.5153 | 4.28 ± 0.30
| | | P = 0.780^e^
Female
Water | 0 | 5 | 1.50 ± 0.16 | | 3.70 ± 0.14
Green tea extract | 62.5 | 5 | 1.90 ± 0.33 | 0.2462 | 4.00 ± 0.25
| 125 | 5 | 1.70 ± 0.34 | 0.3617 | 3.18 ± 0.17
| 250 | 5 | 1.40 ± 0.10 | 0.5737 | 3.72 ± 0.24
| 500 | 5 | 1.40 ± 0.19 | 0.5737 | 3.44 ± 0.31
| 1,000 | 5 | 1.20 ± 0.12 | 0.7183 | 3.48 ± 0.20
| | | P = 0.863

NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^155^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at P ≤ 0.005.

^d^ Vehicle control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.