# Appendix D Summary of Lesions in Female Mice in the Two-year Gavage Study of Green Tea Extract

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Gavage Study of Green Tea Extract^a^

| Vehicle Control | 30 mg/kg | 100 mg/kg | 300 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | 3 | 6 | 1 | –
Moribund | 10 | 2 | 2 | 6
Natural deaths | 3 | 9 | 3 | 5
Survivors
Died last week of study | – | 1 | – | –
Terminal kill | 34 | 32 | 44 | 39
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (49) | (49) | (50)
Gallbladder | (49) | (48) | (50) | (49)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (48) | (40) | (49) | (48)
Adenoma | – | 1 (3%) | – | –
Epithelium, adenocarcinoma | – | – | 1 (2%) | –
Intestine small, ileum | (49) | (46) | (49) | (48)
Intestine small, jejunum | (48) | (43) | (49) | (48)
Leiomyosarcoma | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Cystadenocarcinoma, metastatic, ovary | 1 (2%) | – | – | –
Hemangiosarcoma | 1 (2%) | – | – | –
Hepatocellular adenoma | 7 (14%) | 8 (16%) | 3 (6%) | –
Hepatocellular adenoma, multiple | 5 (10%) | 1 (2%) | – | –
Hepatocellular carcinoma | 5 (10%) | 6 (12%) | 4 (8%) | 1 (2%)
Hepatocellular carcinoma, multiple | – | 1 (2%) | – | –
Hepatocholangiocarcinoma, multiple | – | – | 1 (2%) | –
Mesentery | (6) | (0) | (3) | (2)
Hemangiosarcoma | – | – | 1 (33%) | –
Leiomyosarcoma, metastatic, intestine small, jejunum | 1 (17%) | – | – | –
Pancreas | (50) | (49) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Salivary glands | (50) | (48) | (49) | (48)
Stomach, forestomach | (49) | (49) | (50) | (49)
Squamous cell carcinoma | 1 (2%) | – | – | –
Squamous cell papilloma | 1 (2%) | – | – | –
Stomach, glandular | (49) | (48) | (49) | (49)
Tongue | (0) | (0) | (0) | (2)
Squamous cell carcinoma | – | – | – | 1 (50%)
Squamous cell papilloma | – | – | – | 1 (50%)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (49) | (50) | (50)
Endocrine system
Adrenal cortex | (49) | (50) | (50) | (50)
Hepatocellular carcinoma, metastatic, liver | – | 1 (2%) | – | –
Subcapsular, adenoma | – | 1 (2%) | – | –
Adrenal medulla | (49) | (50) | (50) | (50)
Pheochromocytoma benign | – | 1 (2%) | 1 (2%) | –
Islets, pancreatic | (50) | (49) | (50) | (50)
Adenoma | 1 (2%) | – | – | 1 (2%)
Parathyroid gland | (35) | (40) | (41) | (35)
Pituitary gland | (50) | (48) | (49) | (50)
Thyroid gland | (50) | (48) | (49) | (49)
C-cell, carcinoma | – | 1 (2%) | – | –
Follicular cell, adenoma | – | 1 (2%) | – | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (49) | (49) | (50) | (50)
Ovary | (50) | (50) | (50) | (49)
Cystadenocarcinoma | 1 (2%) | 1 (2%) | – | –
Cystadenoma | 2 (4%) | 1 (2%) | 5 (10%) | 4 (8%)
Sarcoma | 1 (2%) | – | – | –
Bilateral, cystadenoma | 1 (2%) | – | – | –
Uterus | (50) | (50) | (50) | (50)
Polyp stromal | 2 (4%) | – | 3 (6%) | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hemangiocarcinoma | 1 (2%) | – | – | –
Lymph node | (5) | (5) | (3) | (2)
Lymph node, mandibular | (50) | (48) | (49) | (48)
Lymph node, mesenteric | (50) | (49) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Spleen | (50) | (49) | (50) | (50)
Thymus | (47) | (49) | (49) | (50)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Skin | (50) | (50) | (50) | (50)
Fibrosarcoma | – | – | – | 1 (2%)
Subcutaneous tissue, fibrosarcoma | – | 1 (2%) | – | –
Subcutaneous tissue, hemangiosarcoma | – | – | 1 (2%) | –
Subcutaneous tissue, sarcoma | – | – | – | 1 (2%)
Subcutaneous tissue, schwannoma malignant | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (4) | (0) | (0) | (3)
Leiomyosarcoma, metastatic, intestine small, jejunum | 1 (25%) | – | – | –
Rhabdomyosarcoma | 2 (50%) | – | – | 2 (67%)
Nervous System
Brain | (50) | (49) | (50) | (50)
Respiratory System
Lung | (50) | (49) | (50) | (50)
Alveolar/bronchiolar adenoma | 5 (10%) | 2 (4%) | 1 (2%) | 3 (6%)
Alveolar/bronchiolar carcinoma | – | 1 (2%) | 1 (2%) | 1 (2%)
Alveolar/bronchiolar carcinoma, multiple | 1 (2%) | – | – | –
Carcinoma, metastatic, Harderian gland | 1 (2%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | 3 (6%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Rhabdomyosarcoma, metastatic, skeletal muscle | 1 (2%) | – | – | –
Mediastinum, rhabdomyosarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Nose | (48) | (48) | (50) | (50)
Glands, adenoma | 1 (2%) | – | – | –
Trachea | (50) | (48) | (49) | (49)
Special Senses System
Eye | (50) | (48) | (49) | (50)
Harderian gland | (50) | (46) | (49) | (50)
Adenoma | 2 (4%) | 1 (2%) | 3 (6%) | 3 (6%)
Carcinoma | 2 (4%) | – | – | 1 (2%)
Zymbal’s gland | (0) | (0) | (0) | (1)
Carcinoma | – | – | – | 1 (100%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Bilateral, renal tubule, carcinoma | – | – | 1 (2%) | –
Renal tubule, carcinoma | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Leiomyosarcoma, metastatic, intestine small, jejunum | 1 (2%) | – | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | 2 (4%) | 1 (2%) | 1 (2%)
Lymphoma malignant | 7 (14%) | 9 (18%) | 6 (12%) | 4 (8%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 29 | 30 | 23 | 22
Total primary neoplasms | 50 | 40 | 34 | 27
Total animals with benign neoplasms | 20 | 17 | 13 | 13
Total benign neoplasms | 27 | 17 | 16 | 13
Total animals with malignant neoplasms | 18 | 18 | 16 | 12
Total malignant neoplasms | 23 | 23 | 18 | 14
Total animals with metastatic neoplasms | 5 | 3 | 1 | 1
Total metastatic neoplasms | 7 | 4 | 3 | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | 30 mg/kg | 100 mg/kg | 300 mg/kg
Harderian Gland: Adenoma
Overall rate^a^ | 2/50 (4%) | 1/50 (2%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate^b^ | 4.6% | 2.5% | 6.3% | 6.7%
Terminal rate^c^ | 1/34 (3%) | 1/33 (3%) | 2/44 (5%) | 3/39 (8%)
First incidence (days) | 722 | 729 (T) | 564 | 729 (T)
Poly-3 test^d^ | P = 0.350 | P = 0.528N | P = 0.538 | P = 0.510
Harderian Gland: Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 1/50 (2%) | 3/50 (6%) | 4/50 (8%)
Adjusted rate | 9.1% | 2.5% | 6.3% | 8.9%
Terminal rate | 3/34 (9%) | 1/33 (3%) | 2/44 (5%) | 4/39 (10%)
First incidence (days) | 722 | 729 (T) | 564 | 729 (T)
Poly-3 test | P = 0.399 | P = 0.204N | P = 0.455N | P = 0.631N
Liver: Hepatocellular Adenoma
Overall rate | 12/50 (24%) | 9/50 (18%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 27.2% | 22.3% | 6.4% | 0.0%
Terminal rate | 10/34 (29%) | 9/33 (27%) | 3/44 (7%) | 0/39 (0%)
First incidence (days) | 661 | 729 (T) | 729 (T) | –^e^
Poly-3 test | P < 0.001N | P = 0.393N | P = 0.007N | P < 0.001N
Liver: Hepatocellular Carcinoma
Overall rate | 5/50 (10%) | 7/50 (14%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate | 11.4% | 17.0% | 8.5% | 2.2%
Terminal rate | 3/34 (9%) | 3/33 (9%) | 4/44 (9%) | 0/39 (0%)
First incidence (days) | 709 | 630 | 729 (T) | 715
Poly-3 test | P = 0.032N | P = 0.333 | P = 0.457N | P = 0.096N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 14/50 (28%) | 15/50 (30%) | 7/50 (14%) | 1/50 (2%)
Adjusted rate | 31.7% | 36.5% | 14.9% | 2.2%
Terminal rate | 11/34 (32%) | 11/33 (33%) | 7/44 (16%) | 0/39 (0%)
First incidence (days) | 661 | 630 | 729 (T) | 715
Poly-3 test | P < 0.001N | P = 0.407 | P = 0.047N | P < 0.001N
Lung: Alveolar/Bronchiolar Adenoma
Overall rate | 5/50 (10%) | 2/49 (4%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 11.4% | 5.1% | 2.1% | 6.7%
Terminal rate | 4/34 (12%) | 2/33 (6%) | 1/44 (2%) | 3/39 (8%)
First incidence (days) | 722 | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.446N | P = 0.258N | P = 0.086N | P = 0.344N
Lung: Alveolar/Bronchiolar Adenoma or Carcinoma
Overall rate | 6/50 (12%) | 3/49 (6%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 13.7% | 7.6% | 4.3% | 8.9%
Terminal rate | 4/34 (12%) | 3/33 (9%) | 2/44 (5%) | 4/39 (10%)
First incidence (days) | 686 | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.444N | P = 0.295N | P = 0.112N | P = 0.357N
Ovary: Cystadenoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 5/50 (10%) | 4/49 (8%)
Adjusted rate | 6.9% | 2.5% | 10.6% | 9.0%
Terminal rate | 3/34 (9%) | 1/33 (3%) | 5/44 (11%) | 3/39 (8%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 715
Poly-3 test | P = 0.319 | P = 0.334N | P = 0.397 | P = 0.507
Uterus: Stromal Polyp
Overall rate | 2/50 (4%) | 0/50 (0%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 4.6% | 0.0% | 6.4% | 2.2%
Terminal rate | 2/34 (6%) | 0/33 (0%) | 3/44 (7%) | 1/39 (3%)
First incidence (days) | 729 (T) | – | 729 (T) | 729 (T)
Poly-3 test | P = 0.543N | P = 0.255N | P = 0.533 | P = 0.492N
All Organs: Malignant Lymphoma
Overall rate | 7/50 (14%) | 9/50 (18%) | 6/50 (12%) | 4/50 (8%)
Adjusted rate | 15.6% | 21.9% | 12.6% | 8.7%
Terminal rate | 4/34 (12%) | 7/33 (21%) | 5/44 (11%) | 1/39 (3%)
First incidence (days) | 581 | 506 | 564 | 479
Poly-3 test | P = 0.111N | P = 0.317 | P = 0.457N | P = 0.249N
All Organs: Benign Neoplasms
Overall rate | 20/50 (40%) | 17/50 (34%) | 13/50 (26%) | 13/50 (26%)
Adjusted rate | 45.4% | 41.6% | 27.3% | 29.0%
Terminal rate | 17/34 (50%) | 16/33 (49%) | 12/44 (27%) | 12/39 (31%)
First incidence (days) | 661 | 584 | 564 | 715
Poly-3 test | P = 0.072N | P = 0.448N | P = 0.055N | P = 0.081N
All Organs: Malignant Neoplasms
Overall rate | 18/50 (36%) | 18/50 (36%) | 16/50 (32%) | 12/50 (24%)
Adjusted rate | 39.3% | 42.6% | 32.8% | 25.5%
Terminal rate | 9/34 (27%) | 11/33 (33%) | 12/44 (27%) | 5/39 (13%)
First incidence (days) | 581 | 506 | 380 | 479
Poly-3 test | P = 0.057N | P = 0.462 | P = 0.330N | P = 0.115N
All Organs: Benign or Malignant Neoplasms
Overall rate | 29/50 (58%) | 30/50 (60%) | 23/50 (46%) | 22/50 (44%)
Adjusted rate | 62.9% | 70.9% | 47.1% | 46.8%
Terminal rate | 19/34 (56%) | 23/33 (70%) | 19/44 (43%) | 15/39 (39%)
First incidence (days) | 581 | 506 | 380 | 479
Poly-3 test | P = 0.026N | P = 0.284 | P = 0.090N | P = 0.086N

T = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, and ovary; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table D-3 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Gavage Study of Green Tea Extract^a^

| Vehicle Control | 30 mg/kg | 100 mg/kg | 300 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | 3 | 6 | 1 | –
Moribund | 10 | 2 | 2 | 6
Natural deaths | 3 | 9 | 3 | 5
Survivors
Died last week of study | – | 1 | – | –
Terminal kill | 34 | 32 | 44 | 39
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (49) | (49) | (50)
Inflammation | – | 1 (2%) | 1 (2%) | 1 (2%)
Perforation | 2 (4%) | 4 (8%) | – | –
Muscularis, necrosis | – | 1 (2%) | – | –
Gallbladder | (49) | (48) | (50) | (49)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (48) | (40) | (49) | (48)
Serosa, inflammation | – | – | – | 1 (2%)
Intestine small, ileum | (49) | (46) | (49) | (48)
Hyperplasia | – | – | 1 (2%) | –
Ulcer | – | – | 1 (2%) | –
Serosa, inflammation | – | – | – | 1 (2%)
Intestine small, jejunum | (48) | (43) | (49) | (48)
Peyer’s patch, hyperplasia, lymphoid | 2 (4%) | 1 (2%) | 1 (2%) | –
Serosa, inflammation | – | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | 1 (2%)
Basophilic focus | 5 (10%) | 1 (2%) | 2 (4%) | 5 (10%)
Clear cell focus | 3 (6%) | 1 (2%) | – | –
Eosinophilic focus | 23 (46%) | 14 (28%) | 8 (16%) | 3 (6%)
Fatty change | 4 (8%) | 1 (2%) | – | –
Hematopoietic cell proliferation | 3 (6%) | 1 (2%) | 7 (14%) | 3 (6%)
Hemorrhage | 1 (2%) | – | – | –
Infiltration cellular, lymphocyte | 5 (10%) | 2 (4%) | 6 (12%) | 4 (8%)
Inflammation | 6 (12%) | 3 (6%) | 6 (12%) | 5 (10%)
Mixed cell focus | 4 (8%) | 1 (2%) | 2 (4%) | 1 (2%)
Pigmentation | 4 (8%) | 1 (2%) | – | –
Bile duct, cyst | – | – | 1 (2%) | –
Hepatocyte, necrosis | 8 (16%) | 4 (8%) | 3 (6%) | 3 (6%)
Kupffer cell, hyperplasia | 1 (2%) | – | – | 1 (2%)
Serosa, fibrosis | – | – | – | 1 (2%)
Serosa, inflammation | – | – | – | 1 (2%)
Mesentery | (6) | (0) | (3) | (2)
Artery, inflammation | – | – | 1 (33%) | –
Fat, necrosis | 5 (83%) | – | 1 (33%) | 2 (100%)
Pancreas | (50) | (49) | (50) | (50)
Cyst | – | 1 (2%) | – | –
Inflammation | – | – | – | 1 (2%)
Acinus, atrophy | – | 1 (2%) | 1 (2%) | 1 (2%)
Salivary glands | (50) | (48) | (49) | (48)
Artery, inflammation | – | 1 (2%) | – | –
Stomach, forestomach | (49) | (49) | (50) | (49)
Erosion | – | 1 (2%) | – | –
Inflammation | – | 1 (2%) | – | –
Mineralization | – | 1 (2%) | – | –
Epithelium, hyperplasia | – | 1 (2%) | 1 (2%) | 2 (4%)
Stomach, glandular | (49) | (48) | (49) | (49)
Erosion | – | – | – | 1 (2%)
Inflammation | – | – | 1 (2%) | –
Mineralization | – | – | – | 1 (2%)
Ulcer | – | – | – | 1 (2%)
Epithelium, pigmentation | – | 1 (2%) | – | –
Serosa, inflammation | – | – | – | 1 (2%)
Tongue | (0) | (0) | (0) | (2)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | –
Aorta, inflammation | – | – | 2 (4%) | –
Aorta, mineralization | – | – | – | 1 (2%)
Carotid artery, inflammation | – | – | 1 (2%) | –
Heart | (50) | (49) | (50) | (50)
Cardiomyopathy | 12 (24%) | 9 (18%) | 5 (10%) | 8 (16%)
Infiltration cellular, lymphocyte | – | 1 (2%) | – | –
Inflammation | 1 (2%) | – | – | –
Mineralization | – | 1 (2%) | – | 1 (2%)
Artery, degeneration | – | – | – | 1 (2%)
Artery, inflammation | – | 1 (2%) | – | 1 (2%)
Valve, thrombosis | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (49) | (50) | (50) | (50)
Hematopoietic cell proliferation | – | – | 1 (2%) | –
Hypertrophy | – | 1 (2%) | 3 (6%) | 1 (2%)
Adrenal medulla | (49) | (50) | (50) | (50)
Hyperplasia | – | – | 1 (2%) | 2 (4%)
Islets, pancreatic | (50) | (49) | (50) | (50)
Hyperplasia | 1 (2%) | 3 (6%) | – | –
Parathyroid gland | (35) | (40) | (41) | (35)
Pituitary gland | (50) | (48) | (49) | (50)
Pars distalis, hyperplasia | 2 (4%) | 3 (6%) | 1 (2%) | –
Thyroid gland | (50) | (48) | (49) | (49)
Infiltration cellular, lymphocyte | – | – | – | 1 (2%)
C-cell, hyperplasia | 1 (2%) | – | – | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (49) | (49) | (50) | (50)
Ovary | (50) | (50) | (50) | (49)
Angiectasis | 1 (2%) | – | 1 (2%) | 1 (2%)
Cyst | 3 (6%) | 11 (22%) | 6 (12%) | 4 (8%)
Hyperplasia, tubular | – | – | – | 1 (2%)
Thrombosis | 1 (2%) | – | 2 (4%) | –
Corpus luteum, hyperplasia | – | 1 (2%) | – | –
Uterus | (50) | (50) | (50) | (50)
Angiectasis | 2 (4%) | – | 1 (2%) | 2 (4%)
Inflammation | – | – | – | 1 (2%)
Thrombosis | 1 (2%) | – | – | –
Endometrium, hyperplasia, cystic | 32 (64%) | 28 (56%) | 19 (38%) | 25 (50%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hyperplasia | 6 (12%) | 11 (22%) | 41 (82%) | 34 (68%)
Lymph node | (5) | (5) | (3) | (2)
Hyperplasia | – | – | 1 (33%) | –
Lumbar, inflammation | – | – | 1 (33%) | –
Mediastinal, hyperplasia, lymphoid | 1 (20%) | – | – | 1 (50%)
Renal, ectasia | 2 (40%) | 1 (20%) | – | –
Lymph node, mandibular | (50) | (48) | (49) | (48)
Atrophy | 3 (6%) | 4 (8%) | – | –
Hyperplasia, lymphoid | – | 1 (2%) | 8 (16%) | 12 (25%)
Infiltration cellular, plasma cell | – | – | 31 (63%) | 18 (38%)
Lymph node, mesenteric | (50) | (49) | (50) | (50)
Atrophy | 1 (2%) | 1 (2%) | 6 (12%) | 5 (10%)
Ectasia | 1 (2%) | – | – | –
Hyperplasia, lymphoid | 2 (4%) | – | – | –
Infiltration cellular, plasma cell | 1 (2%) | – | – | 1 (2%)
Spleen | (50) | (49) | (50) | (50)
Hematopoietic cell proliferation | 35 (70%) | 34 (69%) | 38 (76%) | 30 (60%)
Necrosis | – | 1 (2%) | – | –
Pigmentation, hemosiderin | 2 (4%) | 5 (10%) | 3 (6%) | 2 (4%)
Lymphoid follicle, hyperplasia | 19 (38%) | 13 (27%) | 14 (28%) | 8 (16%)
White pulp, atrophy | 8 (16%) | 10 (20%) | 7 (14%) | 6 (12%)
Thymus | (47) | (49) | (49) | (50)
Atrophy | 32 (68%) | 28 (57%) | 27 (55%) | 30 (60%)
Hyperplasia, lymphoid | 6 (13%) | 4 (8%) | 8 (16%) | 4 (8%)
Necrosis | 2 (4%) | 4 (8%) | 1 (2%) | 1 (2%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Skin | (50) | (50) | (50) | (50)
Ulcer | 1 (2%) | – | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 12 (24%) | 15 (30%) | 8 (16%) | 23 (46%)
Periosteum, fibrosis | – | 1 (2%) | – | –
Skeletal muscle | (4) | (0) | (0) | (3)
Nervous System
Brain | (50) | (49) | (50) | (50)
Necrosis | 3 (6%) | – | – | 1 (2%)
Arteriole, inflammation | – | – | – | 1 (2%)
Respiratory System
Lung | (50) | (49) | (50) | (50)
Infiltration cellular, lymphocyte | 3 (6%) | 1 (2%) | 3 (6%) | 5 (10%)
Inflammation | – | 1 (2%) | 2 (4%) | –
Thrombosis | – | 1 (2%) | – | –
Alveolar epithelium, hyperplasia | 6 (12%) | 3 (6%) | 3 (6%) | 2 (4%)
Serosa, inflammation | 3 (6%) | 5 (10%) | 1 (2%) | 1 (2%)
Nose | (48) | (48) | (50) | (50)
Foreign body | 4 (8%) | 8 (17%) | 13 (26%) | 17 (34%)
Hyperostosis | – | – | 21 (42%) | 48 (96%)
Infiltration cellular, histiocyte | – | – | – | 1 (2%)
Inflammation, suppurative | 4 (8%) | 24 (50%) | 44 (88%) | 47 (94%)
Glands, respiratory epithelium, hyperplasia | 3 (6%) | – | – | –
Lumen, pigmentation | – | 19 (40%) | 3 (6%) | 16 (32%)
Nasopharyngeal duct, degeneration | – | – | 2 (4%) | 4 (8%)
Nasopharyngeal duct, inflammation | – | – | 1 (2%) | 3 (6%)
Nerve, atrophy | – | 13 (27%) | 47 (94%) | 48 (96%)
Olfactory epithelium, accumulation, hyaline droplet | 41 (85%) | 41 (85%) | 3 (6%) | –
Olfactory epithelium, atrophy | – | 18 (38%) | 26 (52%) | 17 (34%)
Olfactory epithelium, fibrosis | – | 1 (2%) | 39 (78%) | 43 (86%)
Olfactory epithelium, metaplasia, respiratory | 2 (4%) | 36 (75%) | 49 (98%) | 48 (96%)
Olfactory epithelium, necrosis | – | 2 (4%) | 1 (2%) | –
Respiratory epithelium, accumulation, hyaline droplet | 45 (94%) | 42 (88%) | 19 (38%) | 35 (70%)
Respiratory epithelium, atrophy | – | – | 1 (2%) | –
Respiratory epithelium, hyperplasia | 1 (2%) | 1 (2%) | 22 (44%) | 15 (30%)
Respiratory epithelium, metaplasia, squamous | – | 8 (17%) | 42 (84%) | 42 (84%)
Respiratory epithelium, necrosis | – | 4 (8%) | 28 (56%) | 32 (64%)
Septum, perforation | – | – | 38 (76%) | 42 (84%)
Turbinate, atrophy | – | – | 40 (80%) | 48 (96%)
Trachea | (50) | (48) | (49) | (49)
Special Senses System
Eye | (50) | (48) | (49) | (50)
Cornea, inflammation | 1 (2%) | 1 (2%) | 1 (2%) | –
Harderian gland | (50) | (46) | (49) | (50)
Hyperplasia | – | 3 (7%) | 3 (6%) | –
Zymbal’s gland | (0) | (0) | (0) | (1)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Accumulation, hyaline droplet | – | 2 (4%) | 1 (2%) | 1 (2%)
Hydronephrosis | – | – | 1 (2%) | –
Infarct | 3 (6%) | – | 1 (2%) | 6 (12%)
Infiltration cellular, lymphocyte | 1 (2%) | – | 1 (2%) | 1 (2%)
Mineralization | – | – | – | 1 (2%)
Nephropathy | 13 (26%) | 12 (24%) | 11 (22%) | 5 (10%)
Artery, inflammation | 1 (2%) | – | 2 (4%) | 1 (2%)
Cortex, cyst | 1 (2%) | – | 1 (2%) | –
Renal tubule, necrosis | 2 (4%) | 1 (2%) | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Infiltration cellular, lymphocyte | 1 (2%) | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.