# Appendix C Summary of Lesions in Male Mice in the Two-year Gavage Study of Green Tea Extract

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Gavage Study of Green Tea Extract^a^

| Vehicle Control | 30 mg/kg | 100 mg/kg | 300 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | – | – | – | 2
Moribund | 6 | 8 | 7 | 10
Natural deaths | 11 | 6 | 10 | 1
Survivors
Died last week of study | – | – | 1 | –
Terminal kill | 33 | 36 | 32 | 37
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (49) | (50) | (50)
Gallbladder | (50) | (48) | (49) | (49)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Leiomyoma | – | – | 1 (2%) | –
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (43) | (50) | (47) | (49)
Adenoma | – | – | 1 (2%) | –
Intestine small, ileum | (47) | (50) | (48) | (50)
Intestine small, jejunum | (45) | (50) | (49) | (50)
Adenocarcinoma | – | – | 1 (2%) | 1 (2%)
Adenoma | – | – | – | 1 (2%)
Carcinoma | 2 (4%) | 1 (2%) | – | –
Liver | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Hemangioma | 2 (4%) | – | 2 (4%) | –
Hemangiosarcoma | 3 (6%) | 3 (6%) | 3 (6%) | –
Hepatoblastoma | 2 (4%) | – | – | 1 (2%)
Hepatocellular adenoma | 19 (38%) | 14 (28%) | 19 (38%) | 14 (28%)
Hepatocellular adenoma, multiple | 16 (32%) | 15 (30%) | 6 (12%) | 2 (4%)
Hepatocellular carcinoma | 13 (26%) | 11 (22%) | 8 (16%) | 7 (14%)
Hepatocellular carcinoma, multiple | 2 (4%) | 7 (14%) | 5 (10%) | 1 (2%)
Hepatocholangiocarcinoma | – | 3 (6%) | – | –
Squamous cell carcinoma, metastatic, stomach, forestomach | – | 1 (2%) | – | –
Mesentery | (1) | (4) | (2) | (1)
Pancreas | (50) | (50) | (50) | (50)
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell carcinoma | – | 1 (2%) | – | –
Squamous cell papilloma | – | – | – | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Tooth | (0) | (1) | (0) | (1)
Odontoma | – | 1 (100%) | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Aorta, hepatoblastoma, metastatic, liver | – | – | – | 1 (2%)
Heart | (50) | (50) | (50) | (50)
Hepatoblastoma, metastatic, liver | – | – | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (49) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Hepatoblastoma, metastatic, liver | – | – | – | 1 (2%)
Subcapsular, adenoma | 1 (2%) | – | 1 (2%) | –
Adrenal medulla | (49) | (50) | (50) | (50)
Pheochromocytoma benign | – | 1 (2%) | 1 (2%) | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | 3 (6%) | – | –
Carcinoma | 1 (2%) | – | – | –
Parathyroid gland | (41) | (30) | (46) | (44)
Pituitary gland | (49) | (50) | (49) | (50)
Pars distalis, adenoma | 1 (2%) | – | – | –
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, carcinoma | – | – | – | 1 (2%)
Follicular cell, adenoma | 1 (2%) | 2 (4%) | – | –
General Body System
None
Genital System
Coagulating gland | (1) | (0) | (0) | (0)
Sarcoma | 1 (100%) | – | – | –
Epididymis | (50) | (50) | (50) | (50)
Preputial gland | (50) | (50) | (50) | (50)
Prostate | (50) | (50) | (50) | (50)
Seminal vesicle | (50) | (50) | (50) | (50)
Testes | (50) | (50) | (50) | (50)
Interstitial cell, adenoma | 1 (2%) | 3 (6%) | – | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | – | – | –
Lymph node | (2) | (3) | (1) | (0)
Renal, hemangiosarcoma | – | – | 1 (100%) | –
Lymph node, mandibular | (50) | (50) | (50) | (50)
Lymph node, mesenteric | (50) | (49) | (48) | (50)
Hemangiosarcoma | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (50)
Hemangiosarcoma | 2 (4%) | 1 (2%) | – | –
Thymus | (44) | (49) | (46) | (48)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (0) | (2) | (0) | (1)
Skin | (50) | (50) | (50) | (50)
Carcinoma, metastatic, liver | 1 (2%) | – | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (0) | (1) | (1) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 12 (24%) | 7 (14%) | 8 (16%) | 4 (8%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (2%) | 2 (4%) | 1 (2%)
Alveolar/bronchiolar carcinoma | – | 3 (6%) | 2 (4%) | –
Alveolar/bronchiolar carcinoma, multiple | 2 (4%) | 4 (8%) | 1 (2%) | –
Carcinoma, metastatic, Harderian gland | – | 1 (2%) | – | –
Carcinoma, metastatic, kidney | 1 (2%) | – | – | –
Hepatoblastoma, metastatic, liver | | | | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 4 (8%) | 5 (10%) | 2 (4%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | 3 (6%) | – | –
Mediastinum, hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Nose | (50) | (49) | (50) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Adenoma | 7 (14%) | 1 (2%) | 6 (12%) | 4 (8%)
Carcinoma | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Hemangioma | – | – | – | 1 (2%)
Hepatoblastoma, metastatic, liver | – | – | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Bilateral, renal tubule, carcinoma | 2 (4%) | – | – | –
Renal tubule, adenoma | 1 (2%) | – | – | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | 1 (2%) | – | –
Lymphoma malignant | 4 (8%) | 6 (12%) | 2 (4%) | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 49 | 48 | 42 | 30
Total primary neoplasms | 99 | 91 | 72 | 42
Total animals with benign neoplasms | 43 | 37 | 31 | 26
Total benign neoplasms | 62 | 49 | 48 | 30
Total animals with malignant neoplasms | 28 | 34 | 23 | 12
Total malignant neoplasms | 37 | 42 | 24 | 12
Total animals with metastatic neoplasms | 5 | 12 | 2 | 1
Total metastatic neoplasms | 7 | 15 | 2 | 5

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | 30 mg/kg | 100 mg/kg | 300 mg/kg
Harderian Gland: Adenoma
Overall rate^a^ | 7/50 (14%) | 1/50 (2%) | 6/50 (12%) | 4/50 (8%)
Adjusted rate^b^ | 15.7% | 2.2% | 13.1% | 8.8%
Terminal rate^c^ | 6/33 (18%) | 0/36 (0%) | 4/32 (13%) | 3/37 (8%)
First incidence (days) | 616 | 708 | 685 | 675
Poly-3 test^d^ | P = 0.495N | P = 0.028N | P = 0.479N | P = 0.252N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 8/50 (16%) | 2/50 (4%) | 7/50 (14%) | 5/50 (10%)
Adjusted rate | 17.9% | 4.4% | 15.3% | 11.0%
Terminal rate | 7/33 (21%) | 1/36 (3%) | 5/32 (16%) | 4/37 (11%)
First incidence (days) | 616 | 708 | 685 | 675
Poly-3 test | P = 0.495N | P = 0.042N | P = 0.477N | P = 0.265N
Kidney (Renal Tubule): Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 6.7% | 0.0% | 0.0% | 2.2%
Terminal rate | 1/33 (3%) | 0/36 (0%) | 0/32 (0%) | 1/37 (3%)
First incidence (days) | 637 | –^e^ | – | 730 (T)
Poly-3 test | P = 0.451N | P = 0.116N | P = 0.116N | P = 0.303N
Liver: Hemangiosarcoma
Overall rate | 3/50 (6%) | 3/50 (6%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 6.8% | 6.6% | 6.6% | 0.0%
Terminal rate | 3/33 (9%) | 3/36 (8%) | 2/32 (6%) | 0/37 (0%)
First incidence (days) | 730 (T) | 730 (T) | 675 | –
Poly-3 test | P = 0.080N | P = 0.651N | P = 0.647N | P = 0.115N
Liver: Hepatocellular Adenoma
Overall rate | 35/50 (70%) | 29/50 (58%) | 25/50 (50%) | 16/50 (32%)
Adjusted rate | 74.6% | 61.5% | 52.7% | 34.8%
Terminal rate | 26/33 (79%) | 24/36 (67%) | 15/32 (47%) | 14/37 (38%)
First incidence (days) | 587 | 528 | 536 | 450
Poly-3 test | P < 0.001N | P = 0.119N | P = 0.019N | P < 0.001N
Liver: Hepatocellular Carcinoma
Overall rate | 15/50 (30%) | 18/50 (36%) | 13/50 (26%) | 8/50 (16%)
Adjusted rate | 32.4% | 38.4% | 27.4% | 17.5%
Terminal rate | 10/33 (30%) | 12/36 (33%) | 5/32 (16%) | 6/37 (16%)
First incidence (days) | 335 | 462 | 514 | 592
Poly-3 test | P = 0.023N | P = 0.350 | P = 0.379N | P = 0.076N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 40/50 (80%) | 39/50 (78%) | 35/50 (70%) | 21/50 (42%)
Adjusted rate | 82.6% | 80.0% | 71.1% | 44.9%
Terminal rate | 28/33 (85%) | 28/36 (78%) | 19/32 (59%) | 17/37 (46%)
First incidence (days) | 335 | 462 | 514 | 450
Poly-3 test | P < 0.001N | P = 0.475N | P = 0.128N | P < 0.001N
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 17/50 (34%) | 18/50 (36%) | 13/50 (26%) | 9/50 (18%)
Adjusted rate | 36.4% | 38.4% | 27.4% | 19.5%
Terminal rate | 11/33 (33%) | 12/36 (33%) | 5/32 (16%) | 6/37 (16%)
First incidence (days) | 335 | 462 | 514 | 592
Poly-3 test | P = 0.023N | P = 0.506 | P = 0.236N | P = 0.054N
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 40/50 (80%) | 39/50 (78%) | 35/50 (70%) | 22/50 (44%)
Adjusted rate | 82.6% | 80.0% | 71.1% | 46.7%
Terminal rate | 28/33 (85%) | 28/36 (78%) | 19/32 (59%) | 17/37 (46%)
First incidence (days) | 335 | 462 | 514 | 450
Poly-3 test | P < 0.001N | P = 0.475N | P = 0.128N | P < 0.001N
Liver: Hepatocholangiocarcinoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 0.0% | 6.5% | 0.0% | 0.0%
Terminal rate | 0/33 (0%) | 1/36 (3%) | 0/32 (0%) | 0/37 (0%)
First incidence (days) | – | 546 | – | –
Poly-3 test | P = 0.242N | P = 0.127 | –^f^ | –
Lung: Alveolar/Bronchiolar Adenoma
Overall rate | 12/50 (24%) | 8/50 (16%) | 10/50 (20%) | 5/50 (10%)
Adjusted rate | 26.6% | 17.5% | 21.7% | 10.9%
Terminal rate | 8/33 (24%) | 6/36 (17%) | 7/32 (22%) | 4/37 (11%)
First incidence (days) | 587 | 644 | 632 | 449
Poly-3 test | P = 0.065N | P = 0.213N | P = 0.379N | P = 0.047N
Lung: Alveolar/Bronchiolar Carcinoma
Overall rate | 2/50 (4%) | 7/50 (14%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 4.5% | 15.2% | 6.6% | 0.0%
Terminal rate | 1/33 (3%) | 4/36 (11%) | 3/32 (9%) | 0/37 (0%)
First incidence (days) | 721 | 637 | 730 (T) | –
Poly-3 test | P = 0.037N | P = 0.087 | P = 0.513 | P = 0.233N
Lung: Alveolar/Bronchiolar Adenoma or Carcinoma
Overall rate | 14/50 (28%) | 15/50 (30%) | 12/50 (24%) | 5/50 (10%)
Adjusted rate | 31.0% | 32.4% | 26.0% | 10.9%
Terminal rate | 9/33 (27%) | 10/36 (28%) | 9/32 (28%) | 4/37 (11%)
First incidence (days) | 587 | 637 | 632 | 449
Poly-3 test | P = 0.006N | P = 0.534 | P = 0.382N | P = 0.016N
Pancreatic Islets: Adenoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 2.2% | 6.6% | 0.0% | 0.0%
Terminal rate | 0/33 (0%) | 2/36 (6%) | 0/32 (0%) | 0/37 (0%)
First incidence (days) | 616 | 658 | – | –
Poly-3 test | P = 0.146N | P = 0.313 | P = 0.496N | P = 0.498N
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 4.5% | 6.6% | 0.0% | 0.0%
Terminal rate | 1/33 (3%) | 2/36 (6%) | 0/32 (0%) | 0/37 (0%)
First incidence (days) | 616 | 658 | – | –
Poly-3 test | P = 0.087N | P = 0.510 | P = 0.233N | P = 0.235N
Testes: Adenoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 2.2% | 6.6% | 0.0% | 2.2%
Terminal rate | 0/33 (0%) | 3/36 (8%) | 0/32 (0%) | 1/37 (3%)
First incidence (days) | 553 | 730 (T) | – | 730 (T)
Poly-3 test | P = 0.425N | P = 0.309 | P = 0.497N | P = 0.759N
All Organs: Hemangiosarcoma
Overall rate | 5/50 (10%) | 4/50 (8%) | 4/50 (8%) | 0/50 (0%)
Adjusted rate | 11.3% | 8.8% | 8.7% | 0.0%
Terminal rate | 5/33 (15%) | 4/36 (11%) | 3/32 (9%) | 0/37 (0%)
First incidence (days) | 730 (T) | 730 (T) | 675 | –
Poly-3 test | P = 0.027N | P = 0.484N | P = 0.479N | P = 0.029N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 7/50 (14%) | 4/50 (8%) | 6/50 (12%) | 1/50 (2%)
Adjusted rate | 15.7% | 8.8% | 13.1% | 2.2%
Terminal rate | 5/33 (15%) | 4/36 (11%) | 5/32 (16%) | 0/37 (0%)
First incidence (days) | 668 | 730 (T) | 675 | 693
Poly-3 test | P = 0.040N | P = 0.250N | P = 0.479N | P = 0.028N
All Organs: Malignant Lymphoma
Overall rate | 4/50 (8%) | 6/50 (12%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 9.0% | 13.0% | 4.4% | 0.0%
Terminal rate | 4/33 (12%) | 4/36 (11%) | 2/32 (6%) | 0/37 (0%)
First incidence (days) | 730 (T) | 528 | 730 (T) | –
Poly-3 test | P = 0.018N | P = 0.394 | P = 0.324N | P = 0.058N
All Organs: Benign Neoplasms
Overall rate | 43/50 (86%) | 37/50 (74%) | 31/50 (62%) | 26/50 (52%)
Adjusted rate | 89.4% | 77.6% | 64.9% | 55.2%
Terminal rate | 31/33 (94%) | 28/36 (78%) | 20/32 (63%) | 21/37 (57%)
First incidence (days) | 553 | 528 | 536 | 449
Poly-3 test | P < 0.001N | P = 0.089N | P = 0.002N | P < 0.001N
All Organs: Malignant Neoplasms
Overall rate | 28/50 (56%) | 34/50 (68%) | 23/50 (46%) | 12/50 (24%)
Adjusted rate | 58.7% | 69.4% | 48.0% | 26.0%
Terminal rate | 18/33 (55%) | 23/36 (64%) | 13/32 (41%) | 9/37 (24%)
First incidence (days) | 335 | 462 | 514 | 592
Poly-3 test | P < 0.001N | P = 0.184 | P = 0.198N | P < 0.001N
All Organs: Benign or Malignant Neoplasms
Overall rate | 49/50 (98%) | 48/50 (96%) | 42/50 (84%) | 30/50 (60%)
Adjusted rate | 98.0% | 96.0% | 84.7% | 62.3%
Terminal rate | 32/33 (97%) | 34/36 (94%) | 25/32 (78%) | 22/37 (60%)
First incidence (days) | 335 | 462 | 514 | 449
Poly-3 test | P < 0.001N | P = 0.500N | P = 0.019N | P < 0.001N

T = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for kidney, liver, lung, pancreatic islets, and testes; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table C-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Gavage Study of Green Tea Extract^a^

| Vehicle Control | 30 mg/kg | 100 mg/kg | 300 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | – | – | – | 2
Moribund | 6 | 8 | 7 | 10
Natural deaths | 11 | 6 | 10 | 1
Survivors
Died last week of study | – | – | 1 | –
Terminal kill | 33 | 36 | 32 | 37
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (49) | (50) | (50)
Inflammation | – | 1 (2%) | 1 (2%) | 1 (2%)
Perforation | – | – | – | 1 (2%)
Muscularis, degeneration | 1 (2%) | – | – | –
Periesophageal tissue, inflammation | – | – | 1 (2%) | –
Gallbladder | (50) | (48) | (49) | (49)
Intestine large, cecum | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Epithelium, hyperplasia, adenomatous | – | – | – | 1 (2%)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (43) | (50) | (47) | (49)
Intestine small, ileum | (47) | (50) | (48) | (50)
Hyperplasia | – | 1 (2%) | – | –
Inflammation | – | 1 (2%) | – | –
Intestine small, jejunum | (45) | (50) | (49) | (50)
Angiectasis | – | – | – | 1 (2%)
Inflammation, granulomatous | – | – | 1 (2%) | –
Peyer’s patch, hyperplasia, lymphoid | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Basophilic focus | 8 (16%) | 13 (26%) | 6 (12%) | 6 (12%)
Clear cell focus | 24 (48%) | 17 (34%) | 6 (12%) | 1 (2%)
Embolus bacterial | – | – | 3 (6%) | –
Eosinophilic focus | 24 (48%) | 27 (54%) | 22 (44%) | 13 (26%)
Fatty change | 2 (4%) | 1 (2%) | – | 1 (2%)
Fibrosis | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 2 (4%) | 2 (4%) | 6 (12%) | 10 (20%)
Hemorrhage | 1 (2%) | – | –
Hepatodiaphragmatic nodule | – | 2 (4%) | – | 1 (2%)
Infarct | – | 1 (2%) | – | –
Infiltration cellular, lymphocyte | – | 1 (2%) | 1 (2%) | 1 (2%)
Inflammation | 4 (8%) | 1 (2%) | 5 (10%) | 12 (24%)
Mixed cell focus | 9 (18%) | 4 (8%) | 5 (10%) | 2 (4%)
Tension lipidosis | – | – | 1 (2%) | –
Thrombosis | – | 2 (4%) | – | –
Bile duct, cyst | 1 (2%) | – | – | –
Hepatocyte, necrosis | 7 (14%) | 12 (24%) | 7 (14%) | 4 (8%)
Hepatocyte, vacuolization cytoplasmic | – | – | 1 (2%) | –
Kupffer cell, hyperplasia | 3 (6%) | – | – | –
Mesentery | (1) | (4) | (2) | (1)
Inflammation | – | – | 2 (100%) | –
Fat, necrosis | 1 (100%) | 4 (100%) | – | 1 (100%)
Pancreas | (50) | (50) | (50) | (50)
Acinus, atrophy | – | – | – | 4 (8%)
Duct, inflammation | – | – | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
Necrosis | 1 (2%) | – | – | –
Duct, hyperplasia | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Inflammation | 5 (10%) | 3 (6%) | 1 (2%) | 2 (4%)
Ulcer | 3 (6%) | – | 2 (4%) | –
Epithelium, hyperplasia | 5 (10%) | 4 (8%) | 2 (4%) | 1 (2%)
Epithelium, hyperplasia, focal | 1 (2%) | – | – | –
Stomach, glandular | (50) | (50) | (50) | (50)
Erosion | 2 (4%) | – | 1 (2%) | –
Fungus | – | – | 1 (2%) | –
Inflammation | 1 (2%) | 2 (4%) | 1 (2%) | –
Metaplasia, squamous | – | 1 (2%) | – | –
Epithelium, mineralization | – | – | 1 (2%) | –
Epithelium, necrosis | – | – | 1 (2%) | –
Glands, hyperplasia | 2 (4%) | – | – | –
Tooth | (0) | (1) | (0) | (1)
Inflammation, chronic active | – | – | – | 1 (100%)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Aorta, inflammation | – | – | 2 (4%) | 1 (2%)
Carotid artery, inflammation | – | – | – | 1 (2%)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 15 (30%) | 15 (30%) | 11 (22%) | 11 (22%)
Inflammation | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Mineralization | – | – | 1 (2%) | –
Thrombosis | – | – | 1 (2%) | –
Artery, inflammation | 1 (2%) | – | 2 (4%) | 2 (4%)
Pericardium, inflammation | – | – | 1 (2%) | –
Valve, thrombosis | 3 (6%) | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (49) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | 1 (2%)
Degeneration, cystic | – | 1 (2%) | – | –
Hyperplasia | 2 (4%) | 3 (6%) | – | 3 (6%)
Hypertrophy | 10 (20%) | 8 (16%) | 1 (2%) | 2 (4%)
Necrosis | – | – | 1 (2%) | –
Adrenal medulla | (49) | (50) | (50) | (50)
Hyperplasia | – | 1 (2%) | 1 (2%) | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 22 (44%) | 18 (36%) | 19 (38%) | 1 (2%)
Parathyroid gland | (41) | (30) | (46) | (44)
Pituitary gland | (49) | (50) | (49) | (50)
Pars distalis, hyperplasia | 2 (4%) | – | – | –
Thyroid gland | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Coagulating gland | (1) | (0) | (0) | (0)
Epididymis | (50) | (50) | (50) | (50)
Granuloma sperm | 1 (2%) | – | – | –
Preputial gland | (50) | (50) | (50) | (50)
Ectasia | 1 (2%) | 4 (8%) | 5 (10%) | 4 (8%)
Inflammation | – | 1 (2%) | – | –
Prostate | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | 1 (2%) | – | –
Seminal vesicle | (50) | (50) | (50) | (50)
Dilatation | – | – | – | 1 (2%)
Infiltration cellular, lymphocyte | – | 1 (2%) | – | –
Inflammation | 1 (2%) | 1 (2%) | – | 1 (2%)
Testes | (50) | (50) | (50) | (50)
Germinal epithelium, degeneration | 4 (8%) | 3 (6%) | 1 (2%) | –
Germinal epithelium, mineralization | 1 (2%) | – | – | –
Interstitial cell, hyperplasia | 2 (4%) | 1 (2%) | – | 2 (4%)
Tunic, inflammation | – | – | 1 (2%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hyperplasia | 5 (10%) | 42 (84%) | 38 (76%) | 46 (92%)
Infiltration cellular, plasma cell | 1 (2%) | – | – | –
Lymph node | (2) | (3) | (1) | (0)
Infiltration cellular, plasma cell | – | 1 (33%) | – | –
Lymph node, mandibular | (50) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | 1 (2%)
Hyperplasia, lymphoid | – | 1 (2%) | 31 (62%) | 37 (74%)
Infiltration cellular, plasma cell | 1 (2%) | 1 (2%) | 24 (48%) | 41 (82%)
Inflammation | – | – | 1 (2%) | –
Necrosis | – | – | 1 (2%) | –
Lymph node, mesenteric | (50) | (49) | (48) | (50)
Amyloid deposition | – | 1 (2%) | – | –
Atrophy | 3 (6%) | 2 (4%) | 1 (2%) | 7 (14%)
Ectasia | 1 (2%) | 1 (2%) | – | –
Fibrosis | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Hyperplasia, lymphoid | 3 (6%) | 3 (6%) | 1 (2%) | 1 (2%)
Inflammation | 2 (4%) | 1 (2%) | 1 (2%) | –
Spleen | (50) | (50) | (50) | (50)
Hematopoietic cell proliferation | 18 (36%) | 25 (50%) | 29 (58%) | 25 (50%)
Infiltration cellular, plasma cell | – | 1 (2%) | – | –
Pigmentation, hemosiderin | – | – | – | 2 (4%)
Lymphoid follicle, hyperplasia | 9 (18%) | 14 (28%) | 7 (14%) | –
Red pulp, atrophy | 2 (4%) | 3 (6%) | 1 (2%) | 1 (2%)
White pulp, atrophy | 9 (18%) | 7 (14%) | 13 (26%) | 2 (4%)
Thymus | (44) | (49) | (46) | (48)
Atrophy | 44 (100%) | 45 (92%) | 45 (98%) | 44 (92%)
Integumentary System
Mammary gland | (0) | (2) | (0) | (1)
Skin | (50) | (50) | (50) | (50)
Inflammation | 2 (4%) | 1 (2%) | 1 (2%) | –
Ulcer | 1 (2%) | – | – | 3 (6%)
Subcutaneous tissue, necrosis | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 1 (2%) | 3 (6%) | 1 (2%) | 1 (2%)
Fibrous dysplasia | – | – | – | 1 (2%)
Tendon, inflammation | 1 (2%) | – | – | –
Skeletal muscle | (0) | (1) | (1) | (0)
Inflammation | – | 1 (100%) | 1 (100%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | – | 1 (2%) | – | –
Edema, multifocal | – | – | 1 (2%) | –
Hemorrhage | – | – | 1 (2%) | –
Inflammation | – | – | 2 (4%) | –
Necrosis | – | 1 (2%) | 1 (2%) | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Hemorrhage | – | – | 1 (2%) | –
Infiltration cellular, lymphocyte | 1 (2%) | – | – | 4 (8%)
Inflammation | 1 (2%) | – | 6 (12%) | 5 (10%)
Thrombosis | 1 (2%) | 1 (2%) | 1 (2%) | –
Alveolar epithelium, hyperplasia | 5 (10%) | 4 (8%) | 5 (10%) | 1 (2%)
Alveolus, infiltration cellular, histiocyte | 2 (4%) | 1 (2%) | – | –
Bronchiole, hyperplasia | 1 (2%) | 1 (2%) | – | –
Mediastinum, inflammation | – | – | 2 (4%) | –
Mediastinum, necrosis | – | – | 1 (2%) | –
Nose | (50) | (49) | (50) | (50)
Foreign body | 1 (2%) | 10 (20%) | 16 (32%) | 25 (50%)
Hemorrhage | – | – | 1 (2%) | –
Hyperostosis | – | – | 28 (56%) | 46 (92%)
Inflammation, suppurative | 14 (28%) | 40 (82%) | 49 (98%) | 48 (96%)
Polyp, inflammatory | 3 (6%) | – | – | –
Glands, respiratory epithelium, hyperplasia | 3 (6%) | 8 (16%) | 3 (6%) | 1 (2%)
Lumen, pigmentation | – | 3 (6%) | 4 (8%) | 2 (4%)
Nasopharyngeal duct, degeneration | – | – | 4 (8%) | 9 (18%)
Nasopharyngeal duct, inflammation | – | 1 (2%) | 2 (4%) | 4 (8%)
Nasopharyngeal duct, metaplasia, squamous | – | – | – | 1 (2%)
Nerve, atrophy | – | 26 (53%) | 49 (98%) | 50 (100%)
Olfactory epithelium, accumulation, hyaline droplet | 37 (74%) | 47 (96%) | 3 (6%) | –
Olfactory epithelium, atrophy | 4 (8%) | 24 (49%) | 28 (56%) | 3 (6%)
Olfactory epithelium, fibrosis | – | 4 (8%) | 37 (74%) | 43 (86%)
Olfactory epithelium, metaplasia, respiratory | 11 (22%) | 45 (92%) | 49 (98%) | 49 (98%)
Olfactory epithelium, metaplasia, squamous | 1 (2%) | – | 1 (2%) | –
Olfactory epithelium, necrosis | – | 2 (4%) | 1 (2%) | –
Respiratory epithelium, accumulation, hyaline droplet | 49 (98%) | 49 (100%) | 34 (68%) | 5 (10%)
Respiratory epithelium, hyperplasia | 5 (10%) | 20 (41%) | 10 (20%) | 19 (38%)
Respiratory epithelium, metaplasia, squamous | – | 14 (29%) | 39 (78%) | 46 (92%)
Respiratory epithelium, necrosis | – | 7 (14%) | 16 (32%) | 27 (54%)
Septum, perforation | 1 (2%) | – | 26 (52%) | 37 (74%)
Squamous epithelium, necrosis | – | 1 (2%) | – | –
Turbinate, atrophy | – | – | 41 (82%) | 50 (100%)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Cornea, inflammation | 1 (2%) | – | – | –
Optic nerve, demyelination | – | – | – | 1 (2%)
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | 3 (6%) | 1 (2%) | 4 (8%) | 1 (2%)
Inflammation | – | – | 1 (2%) | –
Necrosis | – | – | 1 (2%) | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Accumulation, hyaline droplet | – | 1 (2%) | – | –
Cyst | – | 1 (2%) | – | –
Hydronephrosis | – | – | – | 1 (2%)
Infarct | 5 (10%) | 3 (6%) | 7 (14%) | 4 (8%)
Infiltration cellular, lymphocyte | 1 (2%) | – | 1 (2%) | –
Infiltration cellular, plasma cell | – | 1 (2%) | – | –
Inflammation | – | – | 2 (4%) | –
Nephropathy | 38 (76%) | 41 (82%) | 35 (70%) | 42 (84%)
Artery, inflammation | – | – | – | 1 (2%)
Cortex, cyst | 3 (6%) | 1 (2%) | 2 (4%) | 2 (4%)
Pelvis, inflammation | – | 2 (4%) | – | –
Renal tubule, hyperplasia | 2 (4%) | 2 (4%) | – | –
Renal tubule, necrosis | – | 2 (4%) | – | –
Vein, inflammation, chronic active | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Calculus gross observation | – | 1 (2%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.