# Appendix B Summary of Lesions in Female Wistar Han Rats in the Two-year Gavage Study of Green Tea Extract

Table B-1 Summary of the Incidence of Neoplasms in Female Rats in the Two-year Gavage Study of Green Tea Extract^a^

| Vehicle Control | 100 mg/kg | 300 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation | 10 | – | – | 10
Early deaths
Accidental deaths | – | – | 1 | 3
Moribund | 14 | 12 | 17 | 8
Natural deaths | 10 | 10 | 9 | 35
Survivors
Terminal kill | 26 | 28 | 23 | 4
Animals examined microscopically | 60 | 50 | 50 | 60
Systems Examined at Three Months with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Fibrosarcoma | – | 1 (2%) | – | –
Intestine large, cecum | (49) | (49) | (48) | (44)
Sarcoma, metastatic, uterus | – | – | 1 (2%) | –
Intestine large, colon | (49) | (49) | (48) | (44)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | –
Sarcoma, metastatic, uterus | – | – | 1 (2%) | –
Intestine large, rectum | (49) | (49) | (50) | (45)
Intestine small, duodenum | (47) | (48) | (48) | (39)
Sarcoma, metastatic, uterus | – | – | 1 (2%) | –
Serosa, adenocarcinoma, metastatic, uterus | – | 1 (2%) | – | –
Intestine small, ileum | (45) | (46) | (47) | (36)
Serosa, adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Intestine small, jejunum | (45) | (43) | (45) | (40)
Leiomyosarcoma | 1 (2%) | 1 (2%) | – | –
Sarcoma, metastatic, uterus | – | – | 1 (2%) | –
Liver | (50) | (48) | (49) | (46)
Adenocarcinoma, metastatic, uterus | – | 2 (4%) | 1 (2%) | –
Carcinoma, metastatic, pancreas | – | – | – | 2 (4%)
Cholangioma | – | 1 (2%) | – | –
Hepatocellular adenoma | 1 (2%) | 2 (4%) | – | 2 (4%)
Sarcoma, metastatic, uterus | – | – | 1 (2%) | –
Capsule, adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Mesentery | (6) | (3) | (3) | (2)
Adenocarcinoma, metastatic, uterus | 1 (17%) | 3 (100%) | 2 (67%) | –
Carcinoma, metastatic, pancreas | – | – | – | 1 (50%)
Hemangiosarcoma | 1 (17%) | – | – | –
Oral mucosa | (1) | (0) | (0) | (0)
Squamous cell carcinoma | 1 (100%) | – | – | –
Pancreas | (50) | (49) | (48) | (44)
Adenocarcinoma, metastatic, uterus | 1 (2%) | 1 (2%) | 1 (2%) | –
Carcinoma | – | – | – | 2 (5%)
Carcinoma, metastatic, uterus | – | 1 (2%) | – | –
Salivary glands | (49) | (48) | (50) | (46)
Stomach, forestomach | (50) | (50) | (49) | (44)
Adenocarcinoma, metastatic, uterus | – | 2 (4%) | 1 (2%) | –
Leiomyosarcoma | – | 1 (2%) | – | –
Squamous cell carcinoma | 1 (2%) | – | – | –
Stomach, glandular | (50) | (49) | (49) | (44)
Adenocarcinoma, metastatic, uterus | – | 2 (4%) | – | –
Carcinoma, metastatic, uterus | 1 (2%) | – | – | –
Fibrosarcoma | – | – | – | 1 (2%)
Cardiovascular System
Blood vessel | (50) | (48) | (50) | (46)
Aorta, sarcoma, metastatic, uterus | – | – | 1 (2%) | –
Heart | (50) | (48) | (50) | (48)
Sarcoma, metastatic, uterus | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (49) | (49) | (47)
Adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Adenoma | – | 2 (4%) | 1 (2%) | –
Capsule, adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Adrenal medulla | (50) | (49) | (49) | (47)
Pheochromocytoma benign | 1 (2%) | – | 2 (4%) | –
Islets, pancreatic | (50) | (49) | (48) | (44)
Parathyroid gland | (47) | (46) | (48) | (44)
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, adenoma | 29 (58%) | 17 (34%) | 12 (24%) | 6 (12%)
Pars distalis, adenoma, multiple | 3 (6%) | 4 (8%) | 1 (2%) | 2 (4%)
Pars distalis, carcinoma | – | – | 1 (2%) | –
Pars intermedia, adenoma | 1 (2%) | – | 2 (4%) | –
Pars intermedia, adenoma, multiple | 1 (2%) | – | – | –
Pars nervosa, schwannoma malignant | – | – | – | 1 (2%)
Thyroid gland | (50) | (49) | (50) | (47)
Sarcoma, metastatic, uterus | – | – | 1 (2%) | –
Bilateral, C-cell, adenoma | – | 1 (2%) | – | –
C-cell, adenoma | 3 (6%) | 3 (6%) | 4 (8%) | 1 (2%)
C-cell, carcinoma | 1 (2%) | – | – | –
Follicular cell, adenoma | 1 (2%) | – | 4 (8%) | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (49) | (49) | (50) | (46)
Adenoma | – | – | 1 (2%) | –
Carcinoma | – | – | 1 (2%) | –
Sarcoma | – | – | 1 (2%) | –
Ovary | (50) | (49) | (49) | (44)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | 2 (4%) | –
Carcinoma, metastatic, pancreas | – | – | – | 1 (2%)
Sarcoma stromal, metastatic, uterus | – | – | 1 (2%) | –
Oviduct | (1) | (0) | (0) | (0)
Uterus | (50) | (49) | (49) | (44)
Adenocarcinoma | 3 (6%) | 9 (18%) | 5 (10%) | 3 (7%)
Adenocarcinoma, squamous differentiation | – | – | – | 1 (2%)
Adenoma | – | – | – | 1 (2%)
Polyp stromal | 2 (4%) | 1 (2%) | 1 (2%) | 3 (7%)
Sarcoma stromal | – | 1 (2%) | 2 (4%) | –
Schwannoma malignant | 1 (2%) | – | 2 (4%) | 1 (2%)
Cervix, polyp stromal | 1 (2%) | – | – | –
Cervix, sarcoma stromal | 1 (2%) | – | – | –
Cervix, schwannoma malignant | – | – | – | 1 (2%)
Vagina | (1) | (2) | (0) | (0)
Adenocarcinoma, metastatic, uterus | – | 1 (50%) | – | –
Polyp | 1 (100%) | – | – | –
Sarcoma stromal | – | 1 (50%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (3) | (1) | (4) | (6)
Iliac, adenocarcinoma, metastatic, uterus | 1 (33%) | – | – | –
Renal, carcinoma, metastatic, uncertain primary site | – | – | – | 1 (17%)
Lymph node, mandibular | (49) | (48) | (50) | (46)
Carcinoma, metastatic, Zymbal’s gland | – | – | 1 (2%) | –
Lymph node, mesenteric | (50) | (49) | (48) | (45)
Adenocarcinoma, metastatic, uterus | 1 (2%) | 1 (2%) | 1 (2%) | –
Hemangiosarcoma | 1 (2%) | – | – | –
Spleen | (50) | (49) | (48) | (43)
Adenocarcinoma, metastatic, uterus | – | 2 (4%) | 2 (4%) | –
Carcinoma, metastatic, pancreas | – | – | – | 1 (2%)
Thymus | (49) | (47) | (50) | (47)
Sarcoma, metastatic, uterus | – | – | 1 (2%) | –
Thymoma benign | 3 (6%) | 3 (6%) | 5 (10%) | –
Integumentary System
Mammary gland | (50) | (49) | (49) | (47)
Adenoma | 2 (4%) | – | 1 (2%) | –
Carcinoma | 5 (10%) | – | 4 (8%) | –
Carcinoma, multiple | 1 (2%) | 3 (6%) | 1 (2%) | –
Fibroadenoma | 10 (20%) | 7 (14%) | 5 (10%) | 1 (2%)
Fibroadenoma, multiple | 1 (2%) | 1 (2%) | – | –
Skin | (50) | (50) | (50) | (50)
Basal cell carcinoma | – | 1 (2%) | – | –
Trichoepithelioma | – | 1 (2%) | – | –
Subcutaneous tissue, lipoma | – | 1 (2%) | 1 (2%) | –
Subcutaneous tissue, schwannoma malignant | 2 (4%) | – | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (49)
Skeletal muscle | (0) | (0) | (3) | (2)
Adenocarcinoma, metastatic, uterus | – | – | 2 (67%) | –
Carcinoma, metastatic, pancreas | – | – | – | 2 (100%)
Carcinoma, metastatic, Zymbal’s gland | – | – | 1 (33%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Glioma malignant | – | 1 (2%) | – | –
Granular cell tumor benign | – | – | – | 1 (2%)
Oligodendroglioma malignant | – | 1 (2%) | – | –
Meninges, schwannoma malignant, metastatic, pituitary gland | – | – | – | 1 (2%)
Peripheral nerve | (1) | (2) | (0) | (0)
Spinal cord | (1) | (2) | (0) | (0)
Respiratory System
Lung | (50) | (49) | (50) | (48)
Adenocarcinoma, metastatic, uterus | 1 (2%) | 3 (6%) | 2 (4%) | 1 (2%)
Carcinoma, metastatic, mammary gland | – | – | 1 (2%) | –
Carcinoma, metastatic, pancreas | – | – | – | 1 (2%)
Carcinoma, metastatic, uterus | 1 (2%) | – | – | –
Sarcoma stromal, metastatic, uterus | – | – | 2 (4%) | –
Nose | (49) | (49) | (50) | (49)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (48) | (50) | (50) | (49)
Sarcoma, stromal, metastatic, uterus | – | – | 1 (2%) | –
Harderian gland | (48) | (50) | (50) | (49)
Zymbal’s gland | (0) | (0) | (1) | (0)
Carcinoma | – | – | 1 (100%) | –
Urinary System
Kidney | (50) | (49) | (49) | (45)
Adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Lipoma | 1 (2%) | – | – | –
Capsule, adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Urinary bladder | (49) | (49) | (49) | (44)
Adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Carcinoma, metastatic, pancreas | – | – | – | 1 (2%)
Carcinoma, metastatic, uterus | – | 1 (2%) | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | – | – | 1 (2%)
Lymphoma malignant | 1 (2%) | – | – | –
Neoplasm Summary
Total animals with primary neoplasms^c^
Two-year study | 43 | 37 | 31 | 18
Total primary neoplasms
Two-year study | 81 | 64 | 58 | 29
Total animals with benign neoplasms
Two-year study | 38 | 31 | 25 | 15
Total benign neoplasms
Two-year study | 61 | 44 | 40 | 18
Total animals with malignant neoplasms
Two-year study | 16 | 19 | 17 | 8
Total malignant neoplasms
Two-year study | 20 | 20 | 18 | 11
Total animals with metastatic neoplasms
Two-year study | 2 | 3 | 6 | 5
Total metastatic neoplasms
Two-year study | 7 | 22 | 37 | 12
Total animals with malignant neoplasms of uncertain primary site
Two-year study | – | – | – | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Rats in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | 100 mg/kg | 300 mg/kg | 1,000 mg/kg
Mammary Gland: Fibroadenoma
Overall rate^a^ | 11/50 (22%) | 8/50 (16%) | 5/50 (10%) | 1/50 (2%)
Adjusted rate^b^ | 26.2% | 19.8% | 14.6% | 6.0%
Terminal rate^c^ | 7/26 (27%) | 5/28 (18%) | 1/23 (4%) | 0/4 (0%)
First incidence (days) | 561 | 628 | 506 | 533
Poly-3 test^d^ | P = 0.070N | P = 0.336N | P = 0.171N | P = 0.123N
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 11/50 (22%) | 8/50 (16%) | 6/50 (12%) | 1/50 (2%)
Adjusted rate | 26.2% | 19.8% | 17.5% | 6.0%
Terminal rate | 7/26 (27%) | 5/28 (18%) | 1/23 (4%) | 0/4 (0%)
First incidence (days) | 561 | 628 | 506 | 533
Poly-3 test | P = 0.092N | P = 0.336N | P = 0.265N | P = 0.123N
Mammary Gland: Carcinoma
Overall rate | 6/50 (12%) | 3/50 (6%) | 5/50 (10%) | 0/50 (0%)
Adjusted rate | 14.5% | 7.5% | 14.3% | 0.0%
Terminal rate | 4/26 (15%) | 2/28 (7%) | 1/23 (4%) | 0/4 (0%)
First incidence (days) | 667 | 694 | 275 | –^e^
Poly-3 test | P = 0.236N | P = 0.257N | P = 0.615N | P = 0.173N
Mammary Gland: Adenoma or Carcinoma
Overall rate | 8/50 (16%) | 3/50 (6%) | 5/50 (10%) | 0/50 (0%)
Adjusted rate | 19.4% | 7.5% | 14.3% | 0.0%
Terminal rate | 6/26 (23%) | 2/28 (7%) | 1/23 (4%) | 0/4 (0%)
First incidence (days) | 667 | 694 | 275 | –
Poly-3 test | P = 0.127N | P = 0.106N | P = 0.388N | P = 0.108N
Mammary Gland: Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 15/50 (30%) | 11/50 (22%) | 9/50 (18%) | 1/50 (2%)
Adjusted rate | 35.5% | 27.1% | 24.9% | 6.0%
Terminal rate | 10/26 (39%) | 7/28 (25%) | 2/23 (9%) | 0/4 (0%)
First incidence (days) | 561 | 628 | 275 | 533
Poly-3 test | P = 0.040N | P = 0.279N | P = 0.220N | P = 0.045N
Pancreas: Carcinoma
Overall rate | 0/50 (0%) | 0/49 (0%) | 0/48 (0%) | 2/44 (5%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 12.0%
Terminal rate | 0/26 (0%) | 0/28 (0%) | 0/23 (0%) | 0/4 (0%)
First incidence (days) | – | – | – | 540
Poly-3 test | P = 0.017 | –^f^ | – | P = 0.102
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 32/50 (64%) | 21/50 (42%) | 13/50 (26%) | 8/50 (16%)
Adjusted rate | 68.9% | 50.4% | 38.1% | 40.5%
Terminal rate | 16/26 (62%) | 14/28 (50%) | 8/23 (35%) | 0/4 (0%)
First incidence (days) | 495 | 506 | 530 | 513
Poly-3 test | P = 0.018N | P = 0.054N | P = 0.004N | P = 0.042N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 32/50 (64%) | 21/50 (42%) | 14/50 (28%) | 8/50 (16%)
Adjusted rate | 68.9% | 50.4% | 41.0% | 40.5%
Terminal rate | 16/26 (62%) | 14/28 (50%) | 9/23 (39%) | 0/4 (0%)
First incidence (days) | 495 | 506 | 530 | 513
Poly-3 test | P = 0.022N | P = 0.054N | P = 0.009N | P = 0.042N
Thymus: Benign Thymoma
Overall rate | 3/49 (6%) | 3/47 (6%) | 5/50 (10%) | 0/47 (0%)
Adjusted rate | 7.4% | 7.9% | 15.0% | 0.0%
Terminal rate | 3/26 (12%) | 3/28 (11%) | 4/23 (17%) | 0/4 (0%)
First incidence (days) | 729 (T) | 729 (T) | 530 | –
Poly-3 test | P = 0.493N | P = 0.630 | P = 0.254 | P = 0.357N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 3/50 (6%) | 4/49 (8%) | 4/50 (8%) | 1/47 (2%)
Adjusted rate | 7.3% | 10.2% | 12.0% | 6.5%
Terminal rate | 3/26 (12%) | 3/28 (11%) | 3/23 (13%) | 0/4 (0%)
First incidence (days) | 729 (T) | 719 | 584 | 714
Poly-3 test | P = 0.531 | P = 0.478 | P = 0.388 | P = 0.649N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 4/49 (8%) | 4/50 (8%) | 1/47 (2%)
Adjusted rate | 9.8% | 10.2% | 12.0% | 6.5%
Terminal rate | 4/26 (15%) | 3/28 (11%) | 3/23 (13%) | 0/4 (0%)
First incidence (days) | 729 (T) | 719 | 584 | 714
Poly-3 test | P = 0.508N | P = 0.623 | P = 0.526 | P = 0.543N
Thyroid Gland (Follicular Cell): Adenoma
Overall rate | 1/50 (2%) | 0/49 (0%) | 4/50 (8%) | 1/47 (2%)
Adjusted rate | 2.4% | 0.0% | 12.1% | 6.2%
Terminal rate | 1/26 (4%) | 0/28 (0%) | 3/23 (13%) | 0/4 (0%)
First incidence (days) | 729 (T) | – | 675 | 513
Poly-3 test | P = 0.146 | P = 0.508N | P = 0.120 | P = 0.534
Uterus: Stromal Polyp
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 7.2% | 2.5% | 3.1% | 17.3%
Terminal rate | 1/26 (4%) | 1/28 (4%) | 1/23 (4%) | 1/4 (25%)
First incidence (days) | 561 | 729 (T) | 729 (T) | 509
Poly-3 test | P = 0.201 | P = 0.321N | P = 0.394N | P = 0.278
Uterus: Stromal Polyp or Stromal Sarcoma
Overall rate | 4/50 (8%) | 2/50 (4%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 9.5% | 5.0% | 9.0% | 17.3%
Terminal rate | 1/26 (4%) | 2/28 (7%) | 2/23 (9%) | 1/4 (25%)
First incidence (days) | 561 | 729 (T) | 584 | 509
Poly-3 test | P = 0.253 | P = 0.364N | P = 0.626N | P = 0.366
Uterus: Adenocarcinoma
Overall rate | 3/50 (6%) | 9/50 (18%) | 5/50 (10%) | 4/50 (8%)
Adjusted rate | 7.3% | 21.9% | 14.9% | 23.0%
Terminal rate | 1/26 (4%) | 4/28 (14%) | 2/23 (9%) | 1/4 (25%)
First incidence (days) | 688 | 484 | 610 | 533
Poly-3 test | P = 0.202 | P = 0.056 | P = 0.248 | P = 0.141
All Organs: Benign Neoplasms
Overall rate | 38/50 (76%) | 31/50 (62%) | 25/50 (50%) | 15/50 (30%)
Adjusted rate | 81.6% | 73.2% | 69.1% | 67.5%
Terminal rate | 21/26 (81%) | 20/28 (71%) | 14/23 (61%) | 2/4 (50%)
First incidence (days) | 495 | 506 | 506 | 509
Poly-3 test | P = 0.139N | P = 0.232N | P = 0.135N | P = 0.163N
All Organs: Malignant Neoplasms
Overall rate | 16/50 (32%) | 19/50 (38%) | 17/50 (34%) | 9/50 (18%)
Adjusted rate | 36.3% | 44.0% | 44.3% | 44.2%
Terminal rate | 6/26 (23%) | 9/28 (32%) | 6/23 (26%) | 1/4 (25%)
First incidence (days) | 506 | 484 | 275 | 434
Poly-3 test | P = 0.347 | P = 0.301 | P = 0.302 | P = 0.385
All Organs: Benign or Malignant Neoplasms
Overall rate | 43/50 (86%) | 37/50 (74%) | 31/50 (62%) | 19/50 (38%)
Adjusted rate | 89.2% | 83.0% | 78.8% | 79.6%
Terminal rate | 21/26 (81%) | 22/28 (79%) | 16/23 (70%) | 3/4 (75%)
First incidence (days) | 495 | 484 | 275 | 434
Poly-3 test | P = 0.188N | P = 0.282N | P = 0.145N | P = 0.227N

T = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for pancreas, pituitary gland, thymus, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table B-3 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Two-year Gavage Study of Green Tea Extract^a^

| Vehicle Control | 100 mg/kg | 300 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation | 10 | – | – | 10
Early deaths
Accidental deaths | – | – | 1 | 3
Moribund | 14 | 12 | 17 | 8
Natural deaths | 10 | 10 | 9 | 35
Survivors
Terminal kill | 26 | 28 | 23 | 4
Animals examined microscopically | 60 | 50 | 50 | 60
Three-month interim evaluation
Alimentary System
Liver | (10) | (0) | (0) | (10)
Basophilic focus | – | – | – | 1 (10%)
Inflammation | – | – | – | 3 (30%)
Necrosis | – | – | – | 1 (10%)
Bile duct, hyperplasia | – | – | – | 1 (10%)
Hepatocyte, hypertrophy | – | – | – | 1 (10%)
Oval cell, hyperplasia | – | – | – | 1 (10%)
Salivary glands | (10) | (0) | (0) | (10)
Inflammation | 1 (10%) | – | – | –
Cardiovascular System
Heart | (10) | (0) | (0) | (10)
Cardiomyopathy | – | – | – | 1 (10%)
Genital System
Clitoral gland | (10) | (0) | (0) | (10)
Inflammation | 2 (20%) | – | – | 2 (20%)
Uterus | (10) | (0) | (0) | (10)
Endometrium, hyperplasia, cystic | 1 (10%) | – | – | 1 (10%)
Hematopoietic System
Lymph node, mandibular | (10) | (0) | (0) | (10)
Atrophy | – | – | – | 1 (10%)
Hyperplasia, plasma cell | 6 (60%) | – | – | 5 (50%)
Respiratory System
Lung | (10) | (0) | (0) | (10)
Inflammation, chronic active | 2 (20%) | – | – | 2 (20%)
Nose | (10) | (0) | (0) | (10)
Inflammation, suppurative | – | – | – | 1 (10%)
Inflammation, acute | – | – | – | 1 (10%)
Epithelium, nasopharyngeal duct, degeneration | – | – | – | 1 (10%)
Epithelium, nasopharyngeal duct, regeneration | – | – | – | 1 (10%)
Lamina propria, pigmentation | – | – | – | 1 (10%)
Nasopharyngeal duct, inflammation, acute | – | – | – | 1 (10%)
Nerve, atrophy | – | – | – | 1 (10%)
Olfactory epithelium, accumulation, hyaline droplet | – | – | – | 1 (10%)
Olfactory epithelium, atrophy | – | – | – | 2 (20%)
Olfactory epithelium, metaplasia, respiratory | 1 (10%) | – | – | 4 (40%)
Olfactory epithelium, pigmentation | – | – | – | 4 (40%)
Respiratory epithelium, accumulation, hyaline droplet | – | – | – | 1 (10%)
Respiratory epithelium, degeneration | 1 (10%) | – | – | –
Respiratory epithelium, hyperplasia | – | – | – | 2 (20%)
Turbinate, malformation | – | – | – | 1 (10%)
Trachea | (10) | (0) | (0) | (10)
Glands, cyst | 1 (10%) | – | – | –
Urinary System
Kidney | (10) | (0) | (0) | (10)
Cyst | 1 (10%) | – | – | –
Pelvis, dilatation | 1 (10%) | – | – | –
Systems examined at 3 months with no lesions observed
Endocrine System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | –
Perforation | – | – | – | 1 (2%)
Muscularis, degeneration | 1 (2%) | – | – | –
Intestine large, cecum | (49) | (49) | (48) | (44)
Inflammation | 1 (2%) | – | 1 (2%) | 1 (2%)
Lymphoid tissue, hyperplasia | 1 (2%) | 1 (2%) | – | –
Intestine large, colon | (49) | (49) | (48) | (44)
Hyperplasia, lymphoid | – | – | 1 (2%) | –
Inflammation | – | – | – | 1 (2%)
Parasite, metazoan | 1 (2%) | – | 1 (2%) | –
Intestine large, rectum | (49) | (49) | (50) | (45)
Inflammation | – | – | 1 (2%) | –
Parasite metazoan | 1 (2%) | – | – | 1 (2%)
Thrombosis | – | – | – | 1 (2%)
Intestine small, duodenum | (47) | (48) | (48) | (39)
Mucosa, necrosis | – | – | 1 (2%) | 5 (13%)
Intestine small, ileum | (45) | (46) | (47) | (36)
Mucosa, necrosis | – | – | – | 5 (14%)
Serosa, hemorrhage | – | – | 1 (2%) | –
Serosa, inflammation | – | – | 1 (2%) | –
Intestine small, jejunum | (45) | (43) | (45) | (40)
Necrosis, hemorrhagic | – | 1 (2%) | – | –
Mucosa, necrosis | – | – | 1 (2%) | 6 (15%)
Liver | (50) | (48) | (49) | (46)
Angiectasis | 1 (2%) | 4 (8%) | – | –
Basophilic focus | 38 (76%) | 38 (79%) | 35 (71%) | 15 (33%)
Clear cell focus | 14 (28%) | 8 (17%) | 6 (12%) | 5 (11%)
Degeneration, cystic | 1 (2%) | – | – | –
Eosinophilic focus | 3 (6%) | 4 (8%) | 1 (2%) | 4 (9%)
Fatty change | 7 (14%) | 1 (2%) | – | –
Hematopoietic cell proliferation | – | 4 (8%) | 5 (10%) | –
Hematopoietic cell proliferation, granulocytic | – | 3 (6%) | 2 (4%) | 1 (2%)
Hepatodiaphragmatic nodule | – | – | 1 (2%) | –
Inflammation | 5 (10%) | 3 (6%) | 4 (8%) | 4 (9%)
Mixed cell focus | 7 (14%) | 4 (8%) | 1 (2%) | 2 (4%)
Necrosis | 3 (6%) | 2 (4%) | 5 (10%) | 24 (52%)
Pigmentation | 1 (2%) | 1 (2%) | 2 (4%) | 5 (11%)
Vacuolization, cytoplasmic, focal | 6 (12%) | 2 (4%) | 4 (8%) | 1 (2%)
Bile duct, concretion | – | – | 1 (2%) | –
Bile duct, cyst | – | 2 (4%) | 2 (4%) | –
Bile duct, dilatation | – | – | 1 (2%) | –
Bile duct, hyperplasia | 21 (42%) | 11 (23%) | 13 (27%) | 17 (37%)
Bile duct, hyperplasia, cystic | 1 (2%) | – | – | –
Hepatocyte, hyperplasia, regenerative | – | – | – | 2 (4%)
Hepatocyte, regeneration | 1 (2%) | – | – | –
Oval cell, hyperplasia | 1 (2%) | 2 (4%) | 3 (6%) | 16 (35%)
Portal infiltration cellular, mononuclear cell | 2 (4%) | 1 (2%) | – | –
Serosa, fibrosis | – | – | 1 (2%) | –
Serosa, inflammation | – | – | 1 (2%) | –
Mesentery | (6) | (3) | (3) | (2)
Degeneration, cystic | – | – | 1 (33%) | –
Necrosis | 4 (67%) | – | – | –
Oral mucosa | (1) | (0) | (0) | (0)
Pancreas | (50) | (49) | (48) | (44)
Inflammation | 1 (2%) | 1 (2%) | 2 (4%) | –
Lipomatosis | – | – | 1 (2%) | –
Acinus, atrophy | 3 (6%) | 4 (8%) | 2 (4%) | 2 (5%)
Acinus, cytoplasmic alteration | – | 1 (2%) | – | –
Duct, cyst | – | 1 (2%) | – | –
Salivary glands | (49) | (48) | (50) | (46)
Duct, cyst | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (49) | (44)
Erosion | 2 (4%) | 2 (4%) | – | 1 (2%)
Inflammation | 5 (10%) | 1 (2%) | – | 2 (5%)
Mineralization | – | 1 (2%) | 1 (2%) | 2 (5%)
Ulcer | 2 (4%) | 1 (2%) | 2 (4%) | 2 (5%)
Epithelium, hyperkeratosis | 1 (2%) | – | – | –
Epithelium, hyperplasia | 3 (6%) | 2 (4%) | 1 (2%) | 2 (5%)
Stomach, glandular | (50) | (49) | (49) | (44)
Inflammation | 4 (8%) | 1 (2%) | 1 (2%) | 2 (5%)
Mineralization | 1 (2%) | 2 (4%) | 2 (4%) | 2 (5%)
Necrosis | – | 1 (2%) | – | –
Epithelium, degeneration | 1 (2%) | – | – | –
Epithelium, hyperplasia | 1 (2%) | – | 2 (4%) | –
Glands, hyperplasia | – | – | – | 1 (2%)
Mucosa, necrosis | – | 1 (2%) | 7 (14%) | 20 (45%)
Cardiovascular System
Blood vessel | (50) | (48) | (50) | (46)
Adventitia, aorta, hemorrhage | – | – | 2 (4%) | 1 (2%)
Heart | (50) | (48) | (50) | (48)
Cardiomyopathy | 20 (40%) | 24 (50%) | 18 (36%) | 11 (23%)
Inflammation | 1 (2%) | – | 1 (2%) | 2 (4%)
Mineralization | – | – | – | 1 (2%)
Endocardium, fibrosis | – | – | – | 1 (2%)
Endocardium, hyperplasia | – | – | – | 1 (2%)
Epicardium, inflammation | – | 2 (4%) | 2 (4%) | 4 (8%)
Endocrine System
Adrenal cortex | (50) | (49) | (49) | (47)
Angiectasis | – | – | 2 (4%) | –
Atrophy | – | – | 1 (2%) | –
Degeneration, cystic | 1 (2%) | – | – | 1 (2%)
Hemorrhage | – | – | 1 (2%) | 1 (2%)
Hyperplasia | 21 (42%) | 25 (51%) | 27 (55%) | 7 (15%)
Hypertrophy | 13 (26%) | 15 (31%) | 10 (20%) | 4 (9%)
Mineralization | – | – | 1 (2%) | –
Necrosis | 3 (6%) | – | – | 3 (6%)
Adrenal medulla | (50) | (49) | (49) | (47)
Hyperplasia | 2 (4%) | – | – | –
Vacuolization, cytoplasmic | – | 2 (4%) | – | –
Islets, pancreatic | (50) | (49) | (48) | (44)
Parathyroid gland | (47) | (46) | (48) | (44)
Pituitary gland | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Pars distalis, angiectasis | – | – | – | 1 (2%)
Pars distalis, cyst | 1 (2%) | – | –
Pars distalis, hyperplasia | 12 (24%) | 13 (26%) | 17 (34%) | 13 (26%)
Pars intermedia, angiectasis | – | 1 (2%) | – | 1 (2%)
Pars intermedia, hyperplasia | 1 (2%) | – | – | –
Thyroid gland | (50) | (49) | (50) | (47)
C-cell, hyperplasia | 29 (58%) | 14 (29%) | 6 (12%) | 4 (9%)
Follicle cell, hyperplasia | 2 (4%) | 1 (2%) | – | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (49) | (49) | (50) | (46)
Inflammation | 2 (4%) | 2 (4%) | – | –
Duct, cyst | – | – | 1 (2%) | –
Ovary | (50) | (49) | (49) | (44)
Cyst | 8 (16%) | 12 (24%) | 10 (20%) | 6 (14%)
Inflammation | 1 (2%) | 5 (10%) | 3 (6%) | 6 (14%)
Oviduct | (1) | (0) | (0) | (0)
Uterus | (50) | (49) | (49) | (44)
Congestion | – | – | – | 1 (2%)
Decidual reaction | – | 1 (2%) | – | –
Hemorrhage | 1 (2%) | – | – | –
Infiltration cellular, plasma cell | – | – | – | 1 (2%)
Inflammation | 3 (6%) | 4 (8%) | 2 (4%) | 5 (11%)
Cervix, fibrosis | 1 (2%) | – | – | –
Endometrium, hyperplasia, cystic | 9 (18%) | 14 (29%) | 15 (31%) | 9 (20%)
Vagina | (1) | (2) | (0) | (0)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hyperplasia | 6 (12%) | 14 (28%) | 16 (32%) | 13 (26%)
Lymph node | (3) | (1) | (4) | (6)
Bronchial hyperplasia, plasma cell | – | – | – | 1 (17%)
Bronchial inflammation | – | – | 1 (25%) | –
Iliac, hyperplasia, lymphoid | – | – | 1 (25%) | –
Lumbar, hyperplasia, lymphoid | – | – | – | 1 (17%)
Mediastinal, degeneration, cystic | – | – | 1 (25%) | –
Mediastinal, hemorrhage | – | 1 (100%) | – | –
Mediastinal, hyperplasia | 1 (33%) | – | – | –
Mediastinal, hyperplasia, plasma cell | – | – | 1 (25%) | –
Mediastinal, infiltration cellular, histiocyte | – | – | – | 1 (17%)
Mediastinal, pigmentation, hemosiderin | – | – | 1 (25%) | 1 (17%)
Renal, hyperplasia, plasma cell | – | – | – | 2 (33%)
Renal, inflammation | | | 1 (25%) | –
Lymph node, mandibular | (49) | (48) | (50) | (46)
Atrophy | – | – | 1 (2%) | –
Congestion | – | – | – | 1 (2%)
Degeneration, cystic | 2 (4%) | 4 (8%) | 5 (10%) | 2 (4%)
Hyperplasia, plasma cell | 6 (12%) | 3 (6%) | 3 (6%) | 4 (9%)
Inflammation | – | – | – | 1 (2%)
Lymph node, mesenteric | (50) | (49) | (48) | (45)
Atrophy | – | – | – | 1 (2%)
Congestion | – | – | – | 1 (2%)
Hyperplasia, plasma cell | – | – | 1 (2%) | 1 (2%)
Infiltration cellular, histiocyte | – | – | – | 1 (2%)
Spleen | (50) | (49) | (48) | (43)
Depletion lymphoid | – | 7 (14%) | 5 (10%) | 17 (40%)
Fibrosis | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 11 (22%) | 7 (14%) | 10 (21%) | 5 (12%)
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | 3 (6%) | 1 (2%)
Inflammation | – | – | 1 (2%) | –
Lymphoid follicle, hyperplasia | 1 (2%) | – | – | –
Thymus | (49) | (47) | (50) | (47)
Cyst | – | – | – | 1 (2%)
Hemorrhage | – | – | – | 1 (2%)
Inflammation | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (50) | (49) | (49) | (47)
Hyperplasia | 3 (6%) | 3 (6%) | 1 (2%) | –
Duct, dilatation | – | – | – | 1 (2%)
Epithelium, cytoplasmic alteration | – | 1 (2%) | – | –
Skin | (50) | (50) | (50) | (50)
Hyperkeratosis | 1 (2%) | – | – | –
Hyperplasia | – | – | – | 1 (2%)
Inflammation | – | – | – | 1 (2%)
Ulcer | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (49)
Skeletal muscle | (0) | (0) | (3) | (2)
Nervous System
Brain | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | 2 (4%)
Cerebellum, vacuolization cytoplasmic | – | 1 (2%) | – | –
Peripheral nerve | (1) | (2) | (0) | (0)
Spinal cord | (1) | (2) | (0) | (1)
Degeneration | 1 (100%) | – | – | –
Respiratory System
Lung | (50) | (49) | (50) | (48)
Congestion | – | 1 (2%) | 2 (4%) | 3 (6%)
Edema | – | 2 (4%) | 2 (4%) | 1 (2%)
Fibrosis | – | 1 (2%) | – | –
Hemorrhage | – | 1 (2%) | – | 2 (4%)
Inflammation, suppurative | 1 (2%) | 3 (6%) | 2 (4%) | 9 (19%)
Inflammation, chronic active | 12 (24%) | 11 (22%) | 13 (26%) | 8 (17%)
Alveolar epithelium, hyperplasia | 3 (6%) | 7 (14%) | 7 (14%) | 3 (6%)
Alveolus, infiltration cellular, histiocyte | 23 (46%) | 31 (63%) | 18 (36%) | 17 (35%)
Serosa, inflammation | – | – | 1 (2%) | –
Nose | (49) | (49) | (50) | (49)
Foreign body | 3 (6%) | 2 (4%) | 4 (8%) | 8 (16%)
Inflammation, suppurative | 5 (10%) | 3 (6%) | 17 (34%) | 35 (71%)
Epithelium, goblet cell, nasopharyngeal duct, hyperplasia | 4 (8%) | 4 (8%) | – | –
Epithelium, nasopharyngeal duct, accumulation, hyaline droplet | 1 (2%) | 5 (10%) | 3 (6%) | –
Epithelium, nasopharyngeal duct, degeneration | – | – | 1 (2%) | 3 (6%)
Epithelium, nasopharyngeal duct, hyperplasia | – | 1 (2%) | 4 (8%) | 1 (2%)
Epithelium, nasopharyngeal duct, inflammation, suppurative | – | – | 1 (2%) | –
Epithelium, nasopharyngeal duct, necrosis | – | 1 (2%) | 2 (4%) | 7 (14%)
Epithelium, nasopharyngeal duct, regeneration | – | – | – | 8 (16%)
Lamina propria, mineralization | 3 (6%) | 23 (47%) | 30 (60%) | 22 (45%)
Lamina propria, pigmentation | 1 (2%) | – | 6 (12%) | 14 (29%)
Nasopharyngeal duct, foreign body | 1 (2%) | – | 1 (2%) | 2 (4%)
Nasopharyngeal duct, inflammation, suppurative | – | 2 (4%) | 5 (10%) | 15 (31%)
Nasopharyngeal duct, mineralization | – | – | 1 (2%) | –
Nerve, atrophy | – | 38 (78%) | 41 (82%) | 38 (78%)
Olfactory epithelium, accumulation, hyaline droplet | 33 (67%) | 31 (63%) | 17 (34%) | 4 (8%)
Olfactory epithelium, atrophy | 2 (4%) | 35 (71%) | 42 (84%) | 34 (69%)
Olfactory epithelium, hyperplasia, basal cell | – | – | 8 (16%) | 20 (41%)
Olfactory epithelium, metaplasia, respiratory | 1 (2%) | 42 (86%) | 43 (86%) | 36 (73%)
Olfactory epithelium, necrosis | – | 3 (6%) | 1 (2%) | 18 (37%)
Olfactory epithelium, pigmentation | – | 11 (22%) | 7 (14%) | 5 (10%)
Olfactory epithelium, regeneration | – | – | – | 1 (2%)
Olfactory epithelium, squamous metaplasia | – | 2 (4%) | 1 (2%) | 5 (10%)
Respiratory epithelium, accumulation, hyaline droplet | 28 (57%) | 31 (63%) | 19 (38%) | 7 (14%)
Respiratory epithelium, atrophy | – | 8 (16%) | 9 (18%) | 3 (6%)
Respiratory epithelium, hyperplasia | 1 (2%) | 1 (2%) | 2 (4%) | 2 (4%)
Respiratory epithelium, hyperplasia, basal cell | 1 (2%) | – | – | –
Respiratory epithelium, metaplasia, squamous | 1 (2%) | 1 (2%) | 1 (2%) | 4 (8%)
Respiratory epithelium, necrosis | – | 1 (2%) | 2 (4%) | 17 (35%)
Respiratory epithelium, pigmentation | – | 1 (2%) | 5 (10%) | 5 (10%)
Respiratory epithelium, regeneration | – | – | – | 2 (4%)
Squamous epithelium, hyperplasia | – | – | – | 1 (2%)
Turbinate, deformity | – | 6 (12%) | 20 (40%) | 15 (31%)
Turbinate, hyperostosis | – | 18 (37%) | 32 (64%) | 36 (73%)
Trachea | (50) | (50) | (50) | (50)
Hemorrhage | – | – | – | 1 (2%)
Inflammation | – | – | – | 1 (2%)
Special Senses System
Eye | (48) | (50) | (50) | (49)
Cataract | – | 1 (2%) | 1 (2%) | –
Synechia | – | – | – | 2 (4%)
Anterior chamber, hemorrhage | 1 (2%) | – | – | –
Anterior chamber, posterior chamber, exudate | – | – | 1 (2%) | –
Cornea, inflammation | 1 (2%) | – | 1 (2%) | –
Optic nerve, degeneration | 1 (2%) | – | – | –
Posterior chamber, hemorrhage | – | – | 1 (2%) | –
Retina, atrophy | – | 1 (2%) | – | –
Retina, dysplasia | – | – | 1 (2%) | 1 (2%)
Harderian gland | (48) | (50) | (50) | (49)
Hyperplasia | – | – | 1 (2%) | –
Inflammation | 2 (4%) | 3 (6%) | – | –
Zymbal’s gland | (0) | (0) | (1) | (0)
Urinary System
Kidney | (50) | (49) | (49) | (45)
Atrophy | – | – | 1 (2%) | –
Cyst | 1 (2%) | 1 (2%) | 2 (4%) | –
Hydronephrosis | 2 (4%) | – | 2 (4%) | 3 (7%)
Infarct | – | 1 (2%) | – | –
Inflammation | 11 (22%) | 7 (14%) | 5 (10%) | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Nephropathy | 21 (42%) | 16 (33%) | 17 (35%) | 4 (9%)
Papilla, mineralization | – | – | – | 1 (2%)
Papilla, necrosis | 1 (2%) | – | 1 (2%) | 1 (2%)
Transitional epithelium, hyperplasia | 7 (14%) | 3 (6%) | 6 (12%) | –
Urinary bladder | (49) | (49) | (49) | (44)
Inflammation | 1 (2%) | 1 (2%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table B-4 Incidences of Neoplasms and Nonneoplastic Lesions of the Uterus in Female Rats in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | 100 mg/kg | 300 mg/kg | 1,000 mg/kg
Original Evaluation
Number microscopically examined | 50 | 49 | 49 | 44
Adenoma^a^ | 0 | 0 | 0 | 1 (2%)
Adenocarcinoma | 3 (6%) | 9 (18%) | 5 (10%) | 3 (7%)
Adenocarcinoma, squamous differentiation | 0 | 0 | 0 | 1 (2%)
Adenocarcinoma (includes squamous differentiation)^b^
Overall rate^c^ | 3/50 (6%) | 9/50 (18%) | 5/50 (10%) | 4/50 (8%)
Adjusted rate^d^ | 7.3% | 21.9% | 14.9% | 23.0%
Terminal rate^e^ | 1/26 (4%) | 4/28 (14%) | 2/23 (9%) | 1/4 (25%)
First incidence (days) | 688 | 484 | 610 | 533
Poly-3 test^f^ | P = 0.202 | P = 0.056 | P = 0.248 | P = 0.141
Residual Tissue Evaluation
Number microscopically examined | 44 | 49 | 49 | 44
Endometrium, hyperplasia, atypical | 2 (5%) | 4 (8%) | 4 (8%) | 3 (7%)
Adenoma | 0 | 1 (2%) | 1 (2%) | 2 (5%)
Adenocarcinoma | 7 (16%) | 12 (24%) | 10 (20%) | 7 (16%)
Adenocarcinoma, squamous differentiation | 0 | 0 | 0 | 1 (2%)
Original and Residual Tissue Evaluations (Combined)
Number microscopically examined | 44 | 49 | 49 | 44
Endometrium, hyperplasia, atypical | 2 (5%) | 4 (8%) | 4 (8%) | 3 (7%)
Adenoma | 0 | 1 (2%) | 1 (2%) | 2 (5%)
Adenocarcinoma | 8 (18%) | 13 (27%) | 10 (20%) | 7 (16%)
Adenocarcinoma, squamous differentiation | 0 | 0 | 0 | 1 (2%)

^a^ Number of animals with neoplasm.

^b^ Historical control incidence for 2-year studies in Wistar Han rats (all routes): 7/150 (includes one endometrium carcinoma).

^c^ Number of animals with neoplasm per number of animals necropsied.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at terminal kill.

^f^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.