# Appendix A Summary of Lesions in Male Wistar Han Rats in the Two-year Gavage Study of Green Tea Extract

Table A-1 Summary of the Incidence of Neoplasms in Male Rats in the Two-year Gavage Study of Green Tea Extract^a^

| Vehicle Control | 100 mg/kg | 300 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation | 10 | – | – | 10
Early deaths
Accidental deaths | – | – | – | 2
Moribund | 12 | 7 | 5 | 5
Natural deaths | 3 | 6 | 2 | 19
Survivors
Died last week of study | – | – | 1 | –
Terminal kill | 35 | 37 | 42 | 24
Animals examined microscopically | 60 | 50 | 50 | 60
Systems Examined at Three Months with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Leiomyosarcoma, metastatic, stomach, forestomach | 1 (2%) | – | – | –
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (47) | (49) | (48)
Intestine small, ileum | (50) | (48) | (49) | (45)
Intestine small, jejunum | (49) | (47) | (48) | (46)
Liver | (50) | (50) | (50) | (50)
Hepatocellular adenoma | – | – | – | 1 (2%)
Mesentery | (3) | (2) | (1) | (1)
Schwannoma malignant | 1 (33%) | – | 1 (100%) | –
Oral mucosa | (1) | (0) | (0) | (0)
Gingival, squamous cell carcinoma | 1 (100%) | – | – | –
Pancreas | (50) | (50) | (50) | (50)
Carcinoma, metastatic, prostate | – | 1 (2%) | – | –
Leiomyosarcoma, metastatic, stomach, forestomach | 1 (2%) | – | – | –
Salivary glands | (50) | (50) | (50) | (48)
Stomach, forestomach | (50) | (50) | (50) | (50)
Leiomyosarcoma | 1 (2%) | – | – | –
Stomach, glandular | (49) | (50) | (50) | (50)
Tooth | (1) | (1) | (0) | (0)
Odontoma | – | 1 (100%) | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Adventitia, aorta, leiomyosarcoma, metastatic, stomach, forestomach | 1 (2%) | – | – | –
Heart | (50) | (50) | (50) | (50)
Leiomyosarcoma, metastatic, stomach, forestomach | 1 (2%) | – | – | –
Schwannoma malignant | – | 1 (2%) | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | 2 (4%)
Osteosarcoma, metastatic, bone | 1 (2%) | – | – | –
Adrenal medulla | (50) | (50) | (50) | (50)
Osteosarcoma, metastatic, bone | 1 (2%) | – | – | –
Pheochromocytoma benign | 1 (2%) | 1 (2%) | 1 (2%) | –
Pheochromocytoma complex | – | 1 (2%) | – | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | 1 (2%)
Parathyroid gland | (47) | (44) | (49) | (45)
Adenoma | – | – | – | 1 (2%)
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, adenoma | 16 (32%) | 15 (30%) | 14 (28%) | 10 (20%)
Pars distalis, adenoma, multiple | 1 (2%) | 2 (4%) | 3 (6%) | –
Pars distalis, carcinoma | – | – | 2 (4%) | –
Pars intermedia, adenoma | 1 (2%) | 2 (4%) | – | 1 (2%)
Pars nervosa, adenoma | – | – | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (49)
Bilateral, C-cell, adenoma | – | 1 (2%) | 1 (2%) | –
C-cell, adenoma | 4 (8%) | 3 (6%) | 5 (10%) | 5 (10%)
C-cell, carcinoma | – | – | 1 (2%) | –
Follicular cell, adenoma | – | 3 (6%) | 1 (2%) | 2 (4%)
Follicular cell, adenoma, multiple | – | – | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Preputial gland | (50) | (50) | (50) | (50)
Carcinoma | 1 (2%) | – | – | –
Prostate | (50) | (50) | (50) | (50)
Carcinoma | – | 1 (2%) | – | –
Seminal vesicle | (50) | (50) | (50) | (50)
Carcinoma, metastatic, prostate | – | 1 (2%) | – | –
Testes | (50) | (50) | (50) | (50)
Interstitial cell, adenoma | 2 (4%) | 1 (2%) | 1 (2%) | –
Interstitial cell, adenoma, multiple | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (4) | (0) | (1) | (1)
Lymph node, mandibular | (49) | (50) | (50) | (48)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hemangioma | – | – | 1 (2%) | –
Hemangiosarcoma | – | 1 (2%) | – | –
Spleen | (50) | (50) | (50) | (50)
Hemangiosarcoma, metastatic, Lymph node, mesenteric | – | 1 (2%) | – | –
Thymus | (49) | (49) | (50) | (50)
Thymoma benign | 2 (4%) | 1 (2%) | 3 (6%) | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Fibroadenoma | – | 1 (2%) | – | –
Skin | (50) | (50) | (50) | (50)
Basal cell adenoma | 2 (4%) | 3 (6%) | – | –
Basosquamous tumor malignant | – | 1 (2%) | – | –
Hamartoma | 1 (2%) | – | – | –
Keratoacanthoma | 2 (4%) | – | 2 (4%) | –
Squamous cell carcinoma | 1 (2%) | – | – | –
Squamous cell papilloma | 1 (2%) | – | 3 (6%) | –
Trichoepithelioma | – | 1 (2%) | 1 (2%) | –
Sebaceous gland, adenoma | 1 (2%) | – | – | –
Subcutaneous tissue, fibroma | 1 (2%) | 2 (4%) | – | –
Subcutaneous tissue, lipoma | 1 (2%) | – | 1 (2%) | –
Subcutaneous tissue, sarcoma, metastatic, bone | 1 (2%) | – | – | –
Subcutaneous tissue, schwannoma malignant | 2 (4%) | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteoma | 1 (2%) | – | – | –
Osteosarcoma | 1 (2%) | – | – | –
Joint, sarcoma | 1 (2%) | – | – | –
Skeletal muscle | (0) | (0) | (0) | (1)
Nervous System
Brain | (50) | (50) | (50) | (50)
Glioma malignant | 1 (2%) | – | 2 (4%) | 1 (2%)
Granular cell tumor benign | 2 (4%) | 2 (4%) | 1 (2%) | –
Meningioma benign | – | – | 1 (2%) | –
Squamous cell carcinoma, metastatic, oral mucosa | 1 (2%) | – | – | –
Peripheral nerve | (0) | (1) | (0) | (1)
Spinal cord | (0) | (1) | (0) | (1)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | – | 1 (2%) | –
Carcinoma, metastatic, prostate | – | 1 (2%) | – | –
Carcinoma, metastatic, thyroid gland | – | – | 1 (2%) | –
Leiomyosarcoma, metastatic, stomach, forestomach | 1 (2%) | – | – | –
Osteosarcoma, metastatic, bone | 1 (2%) | – | – | –
Schwannoma, malignant, metastatic, skin | 1 (2%) | – | – | –
Squamous cell carcinoma, metastatic, skin | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Squamous cell carcinoma, metastatic, oral mucosa | 1 (2%) | – | – | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Squamous cell carcinoma, metastatic, oral mucosa | 1 (2%) | – | – | –
Zymbal’s gland | (1) | (0) | (0) | (0)
Carcinoma | 1 (100%) | – | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Lipoma | – | – | 1 (2%) | –
Liposarcoma | 1 (2%) | – | – | –
Osteosarcoma, metastatic, bone | 1 (2%) | – | – | –
Renal tubule, carcinoma | – | 1 (2%) | – | –
Ureter | (1) | (0) | (0) | (0)
Liposarcoma, metastatic, kidney | 1 (100%) | – | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Lymphoma malignant | – | – | 1 (2%) | –
Mesothelioma malignant | 2 (4%) | – | – | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^
Two-year study | 36 | 34 | 32 | 18
Total primary neoplasms
Two-year study | 54 | 47 | 52 | 26
Total animals with benign neoplasms
Two-year study | 26 | 31 | 30 | 17
Total benign neoplasms
Two-year study | 40 | 41 | 44 | 23
Total animals with malignant neoplasms
Two-year study | 12 | 6 | 6 | 2
Total malignant neoplasms
Two-year study | 14 | 6 | 8 | 3
Total animals with metastatic neoplasms
Two-year study | 6 | 2 | 1 | –
Total metastatic neoplasms
Two-year study | 16 | 4 | 1 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Rats in the Two-year Gavage Study of Green Tea Extract

| Vehicle Control | 100 mg/kg | 300 mg/kg | 1,000 mg/kg
Pituitary Gland (Pars Distalis): Adenoma
Overall rate^a^ | 17/50 (34%) | 17/50 (34%) | 17/50 (34%) | 10/50 (20%)
Adjusted rate^b^ | 37.4% | 35.8% | 35.5% | 27.9%
Terminal rate^c^ | 12/35 (34%) | 9/37 (24%) | 15/43 (35%) | 5/24 (21%)
First incidence (days) | 505 | 541 | 585 | 554
Poly-3 test^d^ | P = 0.231N | P = 0.524N | P = 0.512N | P = 0.256N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 17/50 (34%) | 17/50 (34%) | 19/50 (38%) | 10/50 (20%)
Adjusted rate | 37.4% | 35.8% | 39.6% | 27.9%
Terminal rate | 12/35 (34%) | 9/37 (24%) | 16/43 (37%) | 5/24 (21%)
First incidence (days) | 505 | 541 | 585 | 554
Poly-3 test | P = 0.239N | P = 0.524N | P = 0.496 | P = 0.256N
Skin: Squamous Cell Papilloma
Overall rate | 1/50 (2%) | 0/50 (0%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 2.3% | 0.0% | 6.4% | 0.0%
Terminal rate | 1/35 (3%) | 0/37 (0%) | 3/43 (7%) | 0/24 (0%)
First incidence (days) | 727 (T) | –^e^ | 727 (T) | –
Poly-3 test | P = 0.541N | P = 0.493N | P = 0.334 | P = 0.549N
Skin: Basal Cell Adenoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 4.6% | 6.6% | 0.0% | 0.0%
Terminal rate | 2/35 (6%) | 2/37 (5%) | 0/43 (0%) | 0/24 (0%)
First incidence (days) | 727 (T) | 636 | – | –
Poly-3 test | P = 0.123N | P = 0.518 | P = 0.220N | P = 0.296N
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 5/50 (10%) | 0/50 (0%)
Adjusted rate | 6.9% | 0.0% | 10.6% | 0.0%
Terminal rate | 3/35 (9%) | 0/37 (0%) | 5/43 (12%) | 0/24 (0%)
First incidence (days) | 727 (T) | – | 727 (T) | –
Poly-3 test | P = 0.312N | P = 0.113N | P = 0.400 | P = 0.170N
Skin: Trichoepithelioma or Basal Cell Adenoma
Overall rate | 2/50 (4%) | 4/50 (8%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 4.6% | 8.7% | 2.1% | 0.0%
Terminal rate | 2/35 (6%) | 2/37 (5%) | 1/43 (2%) | 0/24 (0%)
First incidence (days) | 727 (T) | 513 | 727 (T) | –
Poly-3 test | P = 0.121N | P = 0.363 | P = 0.473N | P = 0.296N
Skin: Trichoepithelioma, Basal Cell Adenoma, or Malignant Basosquamous Tumor
Overall rate | 2/50 (4%) | 5/50 (10%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 4.6% | 10.9% | 2.1% | 0.0%
Terminal rate | 2/35 (6%) | 3/37 (8%) | 1/43 (2%) | 0/24 (0%)
First incidence (days) | 727 (T) | 513 | 727 (T) | –
Poly-3 test | P = 0.095N | P = 0.239 | P = 0.473N | P = 0.296N
Skin: Squamous Cell Papilloma, Keratoacanthoma, or Squamous Cell Carcinoma
Overall rate | 4/50 (8%) | 0/50 (0%) | 5/50 (10%) | 0/50 (0%)
Adjusted rate | 9.1% | 0.0% | 10.6% | 0.0%
Terminal rate | 3/35 (9%) | 0/37 (0%) | 5/43 (12%) | 0/24 (0%)
First incidence (days) | 519 | – | 727 (T) | –
Poly-3 test | P = 0.226N | P = 0.058N | P = 0.539 | P = 0.102N
Skin: Squamous Cell Papilloma, Keratoacanthoma, Trichoepithelioma, Basal Cell Adenoma, Malignant Basosquamous Tumor, or Squamous Cell Carcinoma
Overall rate | 6/50 (12%) | 5/50 (10%) | 6/50 (12%) | 0/50 (0%)
Adjusted rate | 13.6% | 10.9% | 12.8% | 0.0%
Terminal rate | 5/35 (14%) | 3/37 (8%) | 6/43 (14%) | 0/24 (0%)
First incidence (days) | 519 | 513 | 727 (T) | –
Poly-3 test | P = 0.048N | P = 0.472N | P = 0.576N | P = 0.035N
Thymus: Benign Thymoma
Overall rate | 2/49 (4%) | 1/49 (2%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 4.7% | 2.3% | 6.4% | 0.0%
Terminal rate | 2/34 (6%) | 0/36 (0%) | 2/43 (5%) | 0/24 (0%)
First incidence (days) | 727 (T) | 661 | 646 | –
Poly-3 test | P = 0.303N | P = 0.486N | P = 0.549 | P = 0.291N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 6/50 (12%) | 5/49 (10%)
Adjusted rate | 9.1% | 8.8% | 12.8% | 14.6%
Terminal rate | 3/35 (9%) | 3/37 (8%) | 6/43 (14%) | 3/24 (13%)
First incidence (days) | 505 | 513 | 727 (T) | 611
Poly-3 test | P = 0.261 | P = 0.626N | P = 0.409 | P = 0.346
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 7/50 (14%) | 5/49 (10%)
Adjusted rate | 9.1% | 8.8% | 14.9% | 14.6%
Terminal rate | 3/35 (9%) | 3/37 (8%) | 6/43 (14%) | 3/24 (13%)
First incidence (days) | 505 | 513 | 701 | 611
Poly-3 test | P = 0.260 | P = 0.626N | P = 0.299 | P = 0.346
Thyroid Gland (Follicular Cell): Adenoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 2/50 (4%) | 2/49 (4%)
Adjusted rate | 0.0% | 6.7% | 4.3% | 5.9%
Terminal rate | 0/35 (0%) | 3/37 (8%) | 2/43 (5%) | 2/24 (8%)
First incidence (days) | – | 727 (T) | 727 (T) | 727 (T)
Poly-3 test | P = 0.336 | P = 0.124 | P = 0.255 | P = 0.186
All Organs: Benign Neoplasms
Overall rate | 26/50 (52%) | 31/50 (62%) | 30/50 (60%) | 17/50 (34%)
Adjusted rate | 56.7% | 63.4% | 61.1% | 46.0%
Terminal rate | 20/35 (57%) | 20/37 (54%) | 26/43 (61%) | 9/24 (38%)
First incidence (days) | 505 | 513 | 224 | 525
Poly-3 test | P = 0.119N | P = 0.322 | P = 0.411 | P = 0.226N
All Organs: Malignant Neoplasms
Overall rate | 12/50 (24%) | 6/50 (12%) | 6/50 (12%) | 2/50 (4%)
Adjusted rate | 25.2% | 13.1% | 12.5% | 5.8%
Terminal rate | 3/35 (9%) | 4/37 (11%) | 4/43 (9%) | 1/24 (4%)
First incidence (days) | 519 | 513 | 224 | 611
Poly-3 test | P = 0.034N | P = 0.110N | P = 0.091N | P = 0.023N
All Organs: Benign or Malignant Neoplasms
Overall rate | 36/50 (72%) | 34/50 (68%) | 32/50 (64%) | 18/50 (36%)
Adjusted rate | 72.0% | 69.2% | 65.0% | 48.7%
Terminal rate | 21/35 (60%) | 22/37 (60%) | 27/43 (63%) | 10/24 (42%)
First incidence (days) | 505 | 513 | 224 | 525
Poly-3 test | P = 0.016N | P = 0.468N | P = 0.296N | P = 0.022N

T = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for pituitary gland, thymus, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Two-year Gavage Study of Green Tea Extract^a^

| Vehicle Control | 100 mg/kg | 300 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation | 10 | – | – | 10
Early deaths
Accidental deaths | – | – | – | 2
Moribund | 12 | 7 | 5 | 5
Natural deaths | 3 | 6 | 2 | 19
Survivors
Died last week of study | – | – | 1 | –
Terminal kill | 35 | 37 | 42 | 24
Animals examined microscopically | 60 | 50 | 50 | 60
Three-month interim evaluation
Alimentary System
Intestine large, cecum | (10) | (0) | (0) | (10)
Epithelium, hyperplasia | – | – | – | 1 (10%)
Liver | (10) | (0) | (0) | (10)
Hematopoietic cell proliferation | 1 (10%) | – | – | –
Cardiovascular System
Heart | (10) | (0) | (0) | (10)
Cardiomyopathy | 2 (20%) | – | – | –
Genital System
Preputial gland | (10) | (0) | (0) | (10)
Inflammation | 1 (10%) | – | – | 1 (10%)
Prostate | (10) | (0) | (0) | (10)
Inflammation | 2 (20%) | – | – | –
Hematopoietic System
Lymph node, mandibular | (10) | (0) | (0) | (10)
Hyperplasia, plasma cell | 5 (50%) | – | – | 6 (60%)
Respiratory System
Lung | (10) | (0) | (0) | (10)
Inflammation, chronic active | 1 (10%) | – | – | 3 (30%)
Alveolus, infiltration cellular, histiocyte | 2 (20%) | – | – | 2 (20%)
Nose | (10) | (0) | (0) | (10)
Foreign body | – | – | – | 1 (10%)
Inflammation, suppurative | – | – | – | 2 (20%)
Inflammation, acute | – | – | – | 1 (10%)
Epithelium, nasopharyngeal duct, hyperplasia | – | – | – | 1 (10%)
Epithelium, nasopharyngeal duct, necrosis | – | – | – | 1 (10%)
Epithelium, nasopharyngeal duct, pigmentation | – | – | – | 1 (10%)
Goblet cell, hyperplasia | 1 (10%) | – | – | 2 (20%)
Lamina propria, mineralization | – | – | – | 1 (10%)
Nasopharyngeal duct, foreign body | – | – | – | 1 (10%)
Nasopharyngeal duct, inflammation, suppurative | – | – | – | 2 (20%)
Nerve, atrophy | – | – | – | 5 (50%)
Olfactory epithelium, atrophy | – | – | – | 5 (50%)
Olfactory epithelium, metaplasia, respiratory | – | – | – | 3 (30%)
Olfactory epithelium, necrosis | – | – | – | 2 (20%)
Olfactory epithelium, pigmentation | – | – | – | 3 (30%)
Respiratory epithelium, hyperplasia | 2 (20%) | – | – | 3 (30%)
Respiratory epithelium, metaplasia, squamous | – | – | – | 2 (20%)
Urinary System
Kidney | (10) | (0) | (0) | (10)
Inflammation | 1 (10%) | – | – | –
Nephropathy | – | – | – | 1 (10%)
Systems Examined at Three Months with No Lesions Observed
Endocrine System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | 1 (2%) | – | –
Perforation | – | – | – | 2 (4%)
Muscularis, degeneration | – | – | 1 (2%) | –
Intestine large, cecum | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | 3 (6%)
Ulcer | – | – | – | 1 (2%)
Intestine large, colon | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)
Parasite metazoan | – | 1 (2%) | 1 (2%) | –
Epithelium, necrosis | – | – | 1 (2%) | 1 (2%)
Intestine large, rectum | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)
Parasite metazoan | 5 (10%) | 1 (2%) | 4 (8%) | –
Muscularis, hyperplasia | – | 1 (2%) | – | –
Intestine small, duodenum | (50) | (47) | (49) | (48)
Epithelium, regeneration | – | – | 1 (2%) | –
Mucosa, necrosis | – | 1 (2%) | 1 (2%) | 10 (21%)
Intestine small, ileum | (50) | (48) | (49) | (45)
Mucosa, necrosis | – | 1 (2%) | 2 (4%) | 6 (13%)
Intestine small, jejunum | (49) | (47) | (48) | (46)
Mucosa, necrosis | – | – | 2 (4%) | 9 (20%)
Muscularis, hyperplasia | – | – | 1 (2%) | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | 2 (4%) | 1 (2%) | 3 (6%) | –
Basophilic focus | 20 (40%) | 20 (40%) | 33 (66%) | 11 (22%)
Clear cell focus | 28 (56%) | 36 (72%) | 34 (68%) | 20 (40%)
Deformity | 1 (2%) | – | – | –
Degeneration, cystic | – | – | – | 1 (2%)
Eosinophilic focus | 5 (10%) | 5 (10%) | 5 (10%) | –
Fatty change | 2 (4%) | 2 (4%) | 1 (2%) | 1 (2%)
Hematopoietic cell proliferation | 3 (6%) | – | 1 (2%) | –
Hematopoietic cell proliferation, granulocytic | – | 1 (2%) | – | –
Hepatodiaphragmatic nodule | 1 (2%) | – | 1 (2%) | 1 (2%)
Inflammation | 3 (6%) | 7 (14%) | 5 (10%) | 2 (4%)
Inflammation, chronic active | – | – | 1 (2%) | –
Mixed cell focus | 10 (20%) | 9 (18%) | 12 (24%) | 7 (14%)
Necrosis | 1 (2%) | 2 (4%) | 2 (4%) | 13 (26%)
Pigmentation | – | 2 (4%) | 1 (2%) | 1 (2%)
Vacuolization, cytoplasmic, focal | 3 (6%) | 15 (30%) | 9 (18%) | 1 (2%)
Bile duct, hyperplasia | 11 (22%) | 14 (28%) | 6 (12%) | 10 (20%)
Bile duct, hyperplasia, cystic | – | – | – | 1 (2%)
Hepatocyte, atrophy | 1 (2%) | – | – | –
Hepatocyte, regeneration | 1 (2%) | – | – | –
Oval cell, hyperplasia | – | – | – | 2 (4%)
Portal fibrosis | – | 1 (2%) | – | –
Portal, infiltration cellular, mononuclear cell | – | – | 2 (4%) | –
Mesentery | (3) | (2) | (1) | (1)
Inflammation | – | 1 (50%) | – | –
Necrosis | 2 (67%) | 1 (50%) | – | 1 (100%)
Oral mucosa | (1) | (0) | (0) | (0)
Pancreas | (50) | (50) | (50) | (50)
Basophilic focus | 1 (2%) | – | – | –
Lipomatosis | – | 1 (2%) | – | –
Pigmentation, hemosiderin | – | – | 1 (2%) | –
Acinus, atrophy | 7 (14%) | 6 (12%) | 9 (18%) | 5 (10%)
Acinus, hyperplasia | 3 (6%) | – | – | –
Acinus, necrosis | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (48)
Amyloid deposition | 1 (2%) | – | – | –
Atrophy | 1 (2%) | – | – | –
Necrosis | – | – | – | 1 (2%)
Duct, cyst | – | – | 1 (2%) | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Erosion | 2 (4%) | – | – | –
Inflammation | 3 (6%) | 2 (4%) | – | –
Ulcer | – | 3 (6%) | – | 2 (4%)
Epithelium, degeneration, hydropic | – | – | 1 (2%) | –
Epithelium, hyperkeratosis | 1 (2%) | 1 (2%) | – | –
Epithelium, hyperplasia | 7 (14%) | 6 (12%) | 7 (14%) | 8 (16%)
Stomach, glandular | (49) | (50) | (50) | (50)
Cyst, squamous | – | – | 1 (2%) | –
Inflammation | 2 (4%) | – | – | 1 (2%)
Mineralization | 1 (2%) | – | – | 1 (2%)
Mucosa, hyalinization | – | – | 1 (2%) | –
Mucosa, necrosis | – | 3 (6%) | 3 (6%) | 21 (42%)
Mucosa, pigmentation | – | 1 (2%) | – | –
Tooth | (1) | (1) | (0) | (0)
Inflammation | 1 (100%) | – | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Adventitia, aorta, hemorrhage | – | – | 1 (2%) | 1 (2%)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 45 (90%) | 43 (86%) | 40 (80%) | 28 (56%)
Inflammation | – | – | 1 (2%) | 1 (2%)
Endocardium, hyperplasia | – | 1 (2%) | – | –
Epicardium, inflammation | – | – | 1 (2%) | 5 (10%)
Myocardium, necrosis | – | – | – | 3 (6%)
Pericardium, inflammation | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Degeneration, cystic | 2 (4%) | 1 (2%) | 1 (2%) | –
Hematopoietic cell proliferation, granulocytic | 1 (2%) | – | – | –
Hyperplasia | 22 (44%) | 22 (44%) | 25 (50%) | 8 (16%)
Hypertrophy | 20 (40%) | 24 (48%) | 14 (28%) | 6 (12%)
Infiltration cellular, lipocyte | – | 1 (2%) | – | –
Necrosis | 2 (4%) | – | – | 5 (10%)
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | – | 1 (2%) | 2 (4%) | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Parathyroid gland | (47) | (44) | (49) | (45)
Hyperplasia | 2 (4%) | – | 1 (2%) | 1 (2%)
Inflammation | – | – | – | 1 (2%)
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, atrophy | – | 1 (2%) | – | –
Pars distalis, hyperplasia | 12 (24%) | 10 (20%) | 13 (26%) | 8 (16%)
Pars intermedia, hyperplasia | – | – | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (49)
Amyloid deposition | – | – | 1 (2%) | –
Hemorrhage | – | – | – | 1 (2%)
C-cell, hyperplasia | 37 (74%) | 30 (60%) | 30 (60%) | 15 (31%)
Follicle, cyst | 1 (2%) | – | – | –
Follicular cell, hyperplasia | – | 1 (2%) | 3 (6%) | –
General Body System
None | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Granuloma sperm | 1 (2%) | – | 1 (2%) | –
Spermatocele | 1 (2%) | – | – | –
Preputial gland | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | –
Prostate | (50) | (50) | (50) | (50)
Inflammation | 3 (6%) | 4 (8%) | – | 2 (4%)
Epithelium, hyperplasia | 6 (12%) | 13 (26%) | 6 (12%) | 8 (16%)
Seminal vesicle | (50) | (50) | (50) | (50)
Inflammation | 2 (4%) | 5 (10%) | – | 2 (4%)
Epithelium, hyperplasia | 1 (2%) | 2 (4%) | – | –
Testes | (50) | (50) | (50) | (50)
Atrophy | 9 (18%) | 13 (26%) | 13 (26%) | 5 (10%)
Degeneration, cystic | 3 (6%) | 7 (14%) | 7 (14%) | –
Mineralization | – | – | – | 2 (4%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hyperplasia | 10 (20%) | 9 (18%) | 11 (22%) | 13 (26%)
Hyperplasia, histiocyte | – | 1 (2%) | – | –
Lymph node | (4) | (0) | (1) | (1)
Mediastinal, degeneration, cystic | 1 (25%) | – | – | –
Mediastinal, hemorrhage | 1 (25%) | – | – | –
Mediastinal, hyperplasia, lymphoid | 2 (50%) | – | – | 1 (100%)
Lymph node, mandibular | (49) | (50) | (50) | (48)
Degeneration, cystic | 5 (10%) | 8 (16%) | 4 (8%) | 3 (6%)
Hemorrhage | – | – | 1 (2%) | –
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Hyperplasia, plasma cell | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Atrophy | – | – | – | 1 (2%)
Degeneration, cystic | 2 (4%) | – | 1 (2%) | 1 (2%)
Hemorrhage | – | – | 1 (2%) | –
Spleen | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Depletion lymphoid | 1 (2%) | 2 (4%) | 1 (2%) | 13 (26%)
Hematopoietic cell proliferation | 7 (14%) | 1 (2%) | 1 (2%) | 1 (2%)
Hyperplasia, lymphoid | 1 (2%) | – | 1 (2%) | –
Thymus | (49) | (49) | (50) | (50)
Atrophy | – | – | – | 1 (2%)
Hemorrhage | 1 (2%) | – | – | –
Hyperplasia | – | – | – | 1 (2%)
Inflammation | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Duct, dilatation | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 3 (6%) | 3 (6%) | 1 (2%) | –
Hyperplasia | 2 (4%) | 1 (2%) | – | –
Inflammation | 2 (4%) | – | – | –
Ulcer | 8 (16%) | 4 (8%) | 2 (4%) | –
Hair follicle, cyst epithelial inclusion, multiple | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (0) | (0) | (0) | (1)
Cyst | – | – | – | 1 (100%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Ventricle, developmental malformation | – | 1 (2%) | – | –
Peripheral nerve | (0) | (1) | (0) | (1)
Spinal cord | (0) | (1) | (0) | (1)
Degeneration | – | 1 (100%) | – | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Hemorrhage | – | – | – | 2 (4%)
Inflammation, suppurative | – | 1 (2%) | 3 (6%) | 10 (20%)
Inflammation, chronic active | 10 (20%) | 6 (12%) | 7 (14%) | 11 (22%)
Mineralization | 1 (2%) | – | – | –
Alveolar epithelium, hyperplasia | 2 (4%) | 4 (8%) | 5 (10%) | 5 (10%)
Alveolar epithelium, metaplasia | – | – | – | 1 (2%)
Alveolus, infiltration cellular, histiocyte | 23 (46%) | 21 (42%) | 28 (56%) | 25 (50%)
Bronchiole, hyperplasia | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Foreign body | 8 (16%) | 5 (10%) | 4 (8%) | 5 (10%)
Inflammation, suppurative | 11 (22%) | 12 (24%) | 20 (40%) | 42 (84%)
Epithelium, goblet cell, nasopharyngeal duct, hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | –
Epithelium, nasopharyngeal duct, degeneration | – | 1 (2%) | – | 3 (6%)
Epithelium, nasopharyngeal duct, hyperplasia | – | – | 2 (4%) | 4 (8%)
Epithelium, nasopharyngeal duct, metaplasia, squamous | – | 1 (2%) | – | 1 (2%)
Epithelium, nasopharyngeal duct, necrosis | – | – | – | 2 (4%)
Epithelium, nasopharyngeal duct, pigmentation | – | – | – | 1 (2%)
Epithelium, nasopharyngeal duct, regeneration | – | – | 2 (4%) | 2 (4%)
Goblet cell, nasopharyngeal duct, hyperplasia | – | 1 (2%) | – | –
Lamina propria, mineralization | – | 33 (66%) | 34 (68%) | 44 (88%)
Lamina propria, pigmentation | – | 4 (8%) | 11 (22%) | 25 (50%)
Lumen, pigmentation, histiocyte | – | 1 (2%) | – | –
Nasopharyngeal duct, foreign body | – | 2 (4%) | 1 (2%) | 2 (4%)
Nasopharyngeal duct, inflammation, suppurative | – | 6 (12%) | 8 (16%) | 20 (40%)
Nasopharyngeal duct, mineralization | – | – | – | 1 (2%)
Nerve, atrophy | – | 33 (66%) | 44 (88%) | 44 (88%)
Olfactory epithelium, accumulation, hyaline droplet | 31 (62%) | 30 (60%) | 22 (44%) | 4 (8%)
Olfactory epithelium, atrophy | 1 (2%) | 38 (76%) | 41 (82%) | 41 (82%)
Olfactory epithelium, hyperplasia, basal cell | – | 1 (2%) | 9 (18%) | 28 (56%)
Olfactory epithelium, metaplasia, respiratory | 4 (8%) | 40 (80%) | 43 (86%) | 47 (94%)
Olfactory epithelium, necrosis | 1 (2%) | 3 (6%) | – | 12 (24%)
Olfactory epithelium, pigmentation | 6 (12%) | 18 (36%) | 12 (24%) | 21 (42%)
Olfactory epithelium, squamous metaplasia | – | – | 1 (2%) | 4 (8%)
Olfactory epithelium, ulcer | – | – | – | 1 (2%)
Respiratory epithelium, accumulation, hyaline droplet | 23 (46%) | 30 (60%) | 29 (58%) | 10 (20%)
Respiratory epithelium, atrophy | – | 2 (4%) | 5 (10%) | 6 (12%)
Respiratory epithelium, degeneration | – | – | – | 3 (6%)
Respiratory epithelium, hyperplasia | 1 (2%) | 1 (2%) | 4 (8%) | 5 (10%)
Respiratory epithelium, metaplasia, squamous | – | 1 (2%) | 3 (6%) | 7 (14%)
Respiratory epithelium, necrosis | – | – | – | 4 (8%)
Respiratory epithelium, pigmentation | 2 (4%) | 6 (12%) | 7 (14%) | 7 (14%)
Turbinate, deformity | – | 16 (32%) | 22 (44%) | 35 (70%)
Turbinate, hyperostosis | – | 18 (36%) | 27 (54%) | 40 (80%)
Trachea | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 3 (6%)
Epithelium, hyperplasia | – | – | 1 (2%) | –
Special Senses System
Eye | (50) | (50) | (50) | (50)
Cataract | – | – | 1 (2%) | 1 (2%)
Synechia | – | 1 (2%) | 1 (2%) | –
Ciliary body, inflammation | – | 1 (2%) | – | –
Cornea, inflammation | 1 (2%) | – | – | –
Retina, atrophy | 1 (2%) | – | 2 (4%) | 1 (2%)
Retina, dysplasia | – | 1 (2%) | – | –
Retina, hyperplasia, reticulum cell | 1 (2%) | – | – | –
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | – | – | 1 (2%) | –
Inflammation | 1 (2%) | 1 (2%) | – | 1 (2%)
Zymbal’s gland | (1) | (0) | (0) | (0)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Accumulation, hyaline droplet | – | – | – | 1 (2%)
Casts granular | – | – | – | 1 (2%)
Cyst | 1 (2%) | 3 (6%) | 2 (4%) | 2 (4%)
Hydronephrosis | 2 (4%) | 2 (4%) | 2 (4%) | 4 (8%)
Infarct | – | – | – | 2 (4%)
Infiltration cellular, lipocyte | – | – | – | 1 (2%)
Inflammation | 14 (28%) | 10 (20%) | 13 (26%) | 10 (20%)
Nephropathy | 47 (94%) | 40 (80%) | 44 (88%) | 28 (56%)
Papilla, necrosis | 2 (4%) | – | – | 1 (2%)
Renal tubule, hyperplasia | – | – | 2 (4%) | –
Transitional epithelium, hyperplasia | 1 (2%) | 4 (8%) | 1 (2%) | 2 (4%)
Ureter | (1) | (0) | (0) | (0)
Urinary bladder | (50) | (50) | (50) | (50)
Transitional epithelium, hyperplasia | – | – | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.