# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-584

Report Series: NTP Technical Report Series

Report Series Number: 584

Official citation: National Toxicology Program (NTP). 2017. NTP technical report on the toxicology studies of indole-3-carbinol (CASRN 700-06-1) in F344/N Rats and B6C3F1/N mice and toxicology and carcinogenesis studies of indole-3-carbinol in Harlan Sprague Dawley rats and B6C3F1/N mice (gavage studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 584.