# Peer Review

The members of the Peer Review Panel who evaluated the draft NTP Technical Report on the Toxicology Studies of Indole-3-carbinol (CASRN 700-06-1) in F344/N Rats and B6C3F1/N Mice and Toxicology and Carcinogenesis Studies of Indole-3-carbinol in Harlan Sprague Dawley Rats and B6C3F1/N Mice (Gavage Studies) on May 22, 2014, are listed below. Panel members served as independent scientists, not as representatives of any institution, company, or governmental agency.

In this capacity, panel members had five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

## Peer Reviewers

- Hillary M. Carpenter, III, Ph.D., Chairperson
  Minnesota Department of Health
  Maplewood, Minnesota, USA
- Michael W. Conner, D.V.M.
  Theravance, Inc.
  San Francisco, California, USA
- Michelle V. Fanucchi, Ph.D.
  School of Public Health
  University of Alabama
  Birmingham, Alabama, USA
- Charles R. Mahrt, D.V.M., M.S., Ph.D.
  Eli Lilly and Company
  Indianapolis, Indiana, USA
- Jon C. Mirsalis, Ph.D., Primary Reviewer
  SRI International
  Menlo Park, California, USA
- Gary H. Perdew, Ph.D., Primary Reviewer
  College of Agricultural Sciences
  Pennsylvania State University
  State College, Pennsylvania, USA
- Karen Regan, D.V.M., Primary Reviewer
  Regan Pathology/Toxicology Services, Inc.
  Ashland, Ohio, USA