# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  M.E. Wyde, Ph.D., Study Scientist
  M.C. Boyle, D.V.M., Study Pathologist
  R.A. Herbert, D.V.M., Ph.D., Study Pathologist
  C.R. Blystone, M.S., Ph.D.
  P.M. Foster, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A. Nyska, D.V.M., Study Pathologist
- Coordinated NTP Pathology Working Groups for 2-year rats (July 24, 2012) and 2-year mice (December 13, 2011)
  G.D. Hill, D.V.M., Ph.D.
- Southern Research Institute, Birmingham, Alabama, USA
  Conducted 3-month studies and evaluated pathology findings
  C.D. Hébert, Ph.D., Principal Investigator
  J.E. Heath, D.V.M.
  J.F. Mann, D.V.M.
- Battelle Columbus Operations, Columbus, Ohio, USA
  Conducted 2-year studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  C.M. Briscoe, D.V.M., Ph.D.
  M.J. Ryan, D.V.M., Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  E.T. Adams, D.V.M., Ph.D.
  A.E. Brix, D.V.M., Ph.D.
  R.A. Miller, D.V.M., Ph.D.
- Gene Logic Laboratories, Inc., Gaithersburg, Maryland, USA
  Provided SMVCE analysis
  B.J.T. Muir, Ph.D., Principal Investigator
  B. Atkinson, M.Sc.
  Y. Wang, M.S.